# APPENDIX C GENETIC TOXICOLOGY

## Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al. (1990). At the end of the 3- and 6-month studies, peripheral blood samples were obtained from male and female B6C3F_1_ (3-month study) or Tg.AC hemizygous (6-month study) mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were sent to SITEK Research Laboratories, Inc. (Rockville, MD), where they were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs) in each of 10 (3-month study) or up to 15 (6-month study) animals per dose group. In addition, the percentage of normochromatic erythrocytes in 1,000 total erythrocytes per animal was determined to provide a measure of chemical-induced bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over dose groups with a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dosed group and the control group (ILS, 1990). In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single dosed group is less than or equal to 0.025 divided by the number of dose groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Results of the 3- and 6-month studies were accepted without repeat tests, because additional test data could not be obtained. Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

## Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocol. There have been instances, however, in which multiple aliquots of a chemical were tested in the same assay, and different results were obtained among aliquots and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Report presents a result that represents a scientific judgement of the overall evidence for activity of the chemical in an assay.

## Results

No increase in the frequency of micronucleated NCEs was observed in peripheral blood samples from male or female mice administered dermal applications of 0.75 to 12 mg trimethylolpropane triacrylate/kg body weight for 3 (Table C1) or 6 (Table C2) months. In the 3-month study, ratios of micronucleated polychromatic erythrocytes to NCEs in peripheral blood were unaltered by chemical treatment, indicating an absence of induced bone marrow toxicity. However, in the 6-month study, decreases in the percentages of circulating NCEs among total erythrocytes were noted in 12 mg/kg male and female mice, indicating a stimulation of erythropoiesis and the presence of increased numbers of immature erythrocytes in circulating blood.

TABLE C1 Frequency of Micronuclei in Peripheral Blood Normochromatic Erythrocytes of B6C3F1 Mice Following Dermal Application of Trimethylolpropane Triacrylate for 3 Months^a^

Compound | Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | NCEs^b^ (%)
Male
Acetone^d^ | | 10 | 1.25 ± 0.27 | | 98.0 ± 0.1
Trimethylolpropane triacrylate
Trimethylolpropane triacrylate | 0.75 | 10 | 1.55 ± 0.17 | 0.2112 | 97.4 ± 0.2
Trimethylolpropane triacrylate | 1.5 | 10 | 0.95 ± 0.19 | 0.8173 | 97.8 ± 0.2
Trimethylolpropane triacrylate | 3 | 10 | 1.20 ± 0.31 | 0.5568 | 97.5 ± 0.2
Trimethylolpropane triacrylate | 6 | 10 | 1.10 ± 0.19 | 0.6693 | 98.0 ± 0.2
Trimethylolpropane triacrylate | 12 | 10 | 0.60 ± 0.10 | 0.9837 | 97.8 ± 0.1
| | | P=0.993^e^
Female
Acetone | | 10 | 0.60 ± 0.15 | | 97.9 ± 0.2
Trimethylolpropane triacrylate
Trimethylolpropane triacrylate | 0.75 | 10 | 0.50 ± 0.17 | 0.6651 | 98.0 ± 0.2
Trimethylolpropane triacrylate | 1.5 | 10 | 0.85 ± 0.18 | 0.1765 | 98.3 ± 0.1
Trimethylolpropane triacrylate | 3 | 10 | 0.70 ± 0.21 | 0.3474 | 98.1 ± 0.1
Trimethylolpropane triacrylate | 6 | 10 | 0.65 ± 0.22 | 0.4207 | 97.8 ± 0.2
Trimethylolpropane triacrylate | 12 | 10 | 0.80 ± 0.17 | 0.2248 | 97.9 ± 0.2
| | | P=0.232

a Study was performed at SITEK Research Laboratories, Inc. The detailed protocol is presented by MacGregor et al. (1990). NCE=normochromatic erythrocyte

b Mean ± standard error

c Pairwise comparison with the controls, significant at P≤0.005 (ILS, 1990)

d Vehicle control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)

TABLE C2 Frequency of Micronuclei in Peripheral Blood Normochromatic Erythrocytes of Tg.AC Hemizygous Mice Following Dermal Application of Trimethylolpropane Triacrylate for 6 Months^a^

Compound | Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | NCEs^b^ (%)
Male
Acetone^d^ | | 14 | 2.82 ± 0.28 | | 97.4 ± 0.1
Trimethylolpropane triacrylate
Trimethylolpropane triacrylate | 0.75 | 15 | 3.23 ± 0.55 | 0.1837 | 97.3 ± 0.2
Trimethylolpropane triacrylate | 1.5 | 12 | 3.17 ± 0.35 | 0.2358 | 97.2 ± 0.1
Trimethylolpropane triacrylate | 3 | 14 | 2.11 ± 0.17 | 0.9559 | 97.5 ± 0.1
Trimethylolpropane triacrylate | 6 | 13 | 1.88 ± 0.30 | 0.9874 | 97.2 ± 0.2
Trimethylolpropane triacrylate | 12 | 11 | 2.36 ± 0.24 | 0.8399 | 93.7 ± 1.2
| | | P=0.990^e^
Female
Acetone | | 15 | 1.00 ± 0.18 | | 97.6 ± 0.1
Trimethylolpropane triacrylate
Trimethylolpropane triacrylate | 0.75 | 14 | 1.32 ± 0.18 | 0.1274 | 97.4 ± 0.1
Trimethylolpropane triacrylate | 1.5 | 12 | 1.25 ± 0.22 | 0.1931 | 97.8 ± 0.1
Trimethylolpropane triacrylate | 3 | 14 | 1.21 ± 0.21 | 0.2187 | 97.5 ± 0.3
Trimethylolpropane triacrylate | 6 | 14 | 1.14 ± 0.16 | 0.2994 | 97.7 ± 0.1
Trimethylolpropane triacrylate | 12 | 12 | 1.67 ± 0.28 | 0.0162 | 90.7 ± 2.2
| | | P=0.041

a Study was performed at SITEK Research Laboratories, Inc. The detailed protocol is presented by MacGregor et al. (1990). NCE=normochromatic erythrocyte

b Mean ± standard error

c Pairwise comparison with the controls, significant at P≤0.005 (ILS, 1990)

d Vehicle control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)