# APPENDIX B SUMMARY OF LESIONS IN FEMALE Tg.AC HEMIZYGOUS MICE IN THE 6-MONTH DERMAL STUDY OF TRIMETHYLOLPROPANE TRIACRYLATE

TABLE B1 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | | | 1
Natural deaths | | 1 | 2 | 1 | 1 | 3
Survivors
Terminal sacrifice | 15 | 14 | 12 | 14 | 14 | 12
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (15) | (15)
Salivary glands | (1) | | | | | (1)
Carcinoma | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15) | (15) | (15)
Squamous cell papilloma | 3 (20%) | 4 (27%) | 3 (20%) | 1 (7%) | 4 (27%) | 6 (40%)
Squamous cell papilloma, multiple | 1 (7%) | 1 (7%) | 1 (7%) | 1 (7%) | 1 (7%) | 3 (20%)
Tooth | (1) | (4) | (3) | (1) | (3) | (2)
Odontogenic tumor | 1 (100%) | 4 (100%) | 2 (67%) | | 3 (100%) | 1 (50%)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15) | (15)
Endocrine System
Pituitary gland | (15) | (15) | (15) | (15) | (15) | (15)
General Body System
None
Genital System
Ovary | (15) | (15) | (15) | (15) | (15) | (15)
Uterus | (15) | (15) | (15) | (15) | (15) | (15)
Vagina | | (1)
Squamous cell papilloma | | 1 (100%)
Hematopoietic System
Lymph node | (11) | (14) | (13) | (10) | (13) | (12)
Lymph node, mandibular | (15) | (15) | (15) | (15) | (15) | (15)
Lymph node, mesenteric | (15) | (14) | (14) | (15) | (15) | (15)
Spleen | (15) | (15) | (15) | (15) | (15) | (15)
Thymus | (15) | (15) | (15) | (15) | (15) | (15)
Integumentary System
Skin | (15) | (15) | (15) | (15) | (15) | (15)
Squamous cell papilloma | | 1 (7%) | | 1 (7%)
Skin, site of application, squamous cell carcinoma | | | 1 (7%) | | 1 (7%) | 1 (7%)
Skin, site of application, squamous cell papilloma | | | | 1 (7%) | 6 (40%)
Skin, site of application, squamous cell papilloma, multiple | | | | | 5 (33%) | 15 (100%)
Vulva, squamous cell papilloma | | | | | 1 (7%)
Musculoskeletal System
Bone | | (1)
Osteosarcoma | | 1 (100%)
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15) | (15)
Alveolar/bronchiolar adenoma | 1 (7%) | | | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15) | (15)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15) | (15)
Leukemia erythrocytic | | 1 (7%) | | 1 (7%) | | 2 (13%)
Lymphoma malignant | | | | | | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 6 | 9 | 6 | 5 | 12 | 15
Total primary neoplasms | 7 | 13 | 7 | 6 | 21 | 29
Total animals with benign neoplasms | 5 | 5 | 4 | 4 | 11 | 15
Total benign neoplasms | 5 | 7 | 4 | 5 | 17 | 24
Total animals with malignant neoplasms | 1 | 2 | 1 | 1 | 1 | 3
Total malignant neoplasms | 1 | 2 | 1 | 1 | 1 | 4
Total animals with uncertain neoplasms-benign or malignant | 1 | 4 | 2 | | 3 | 1
Total uncertain neoplasms | 1 | 4 | 2 | | 3 | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B2

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate: Vehicle Control

Number of Days on Study | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9
Number of Days on Study | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 7 | 7 | 7 | 8 | 8 | 8 | 8 | 7 | 7 | 7 | 7 | 7 | 7 | 8 | 8 | Total Tissues/Tumors
Carcass ID Number | 2 | 3 | 8 | 1 | 2 | 3 | 5 | 1 | 4 | 5 | 6 | 7 | 9 | 0 | 4 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | | | | | | | | | | | | + | | | | 1
Carcinoma | | | | | | | | | | | | X | | | | 1
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | X | X | | | X | | | | | | | | 3
Squamous cell papilloma, multiple | | | | | | X | | | | | | | | | | 1
Tooth | | | | | | | | | | | | + | | | | 1
Odontogenic tumor | | | | | | | | | | | | X | | | | 1
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | + | M | + | + | + | + | + | M | M | M | + | + | + | + | 11
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Alveolar/bronchiolar adenoma | | | | | | | | | | | | | | | X | 1
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate: 0.75 mg/kg

Number of Days on Study | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 8 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9
Number of Days on Study | 3 | 3 | 3 | 3 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 3 | Total Tissues/Tumors
Carcass ID Number | 8 | 9 | 9 | 9 | 8 | 8 | 8 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 0 | Total Tissues/Tumors
Carcass ID Number | 6 | 2 | 6 | 9 | 7 | 8 | 9 | 0 | 1 | 3 | 4 | 5 | 7 | 8 | 0 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | X | | | | X | X | | X | | | | 4
Squamous cell papilloma, multiple | | | | | | | X | | | | | | | | | 1
Tooth | | | + | | | + | | | | + | | + | | | | 4
Odontogenic tumor | | | X | | | X | | | | X | | X | | | | 4
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Vagina | | | | | | | | | | | | + | | | | 1
Squamous cell papilloma | | | | | | | | | | | | X | | | | 1
Hematopoietic System
Lymph node | + | + | + | + | + | + | M | + | + | + | + | + | + | + | + | 14
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | M | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | X | | | | | | | | | | | 1
Musculoskeletal System
Bone | + | | | | | | | | | | | | | | | 1
Osteosarcoma | X | | | | | | | | | | | | | | | 1
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | | | | | | | | X | | | | | | | | 1

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate: 1.5 mg/kg

Number of Days on Study | 0 | 0 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 6 | 6 | 2 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9
Number of Days on Study | 3 | 3 | 2 | 3 | 3 | 3 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | Total Tissues/Tumors
Carcass ID Number | 0 | 0 | 1 | 0 | 1 | 1 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 4 | 7 | 0 | 2 | 2 | 5 | 1 | 3 | 5 | 6 | 8 | 9 | 1 | 3 | 4 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | X | | | | | | X | | | | | X | 3
Squamous cell papilloma, multiple | | | | | | | | | | | | | X | | | 1
Tooth | + | | | | + | | | | | | | | | | + | 3
Odontogenic tumor | | | | | X | | | | | | | | | | X | 2
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | + | + | + | + | + | M | + | + | M | + | + | + | + | + | 13
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | M | + | + | + | + | + | + | + | + | + | + | + | + | 14
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skin, site of application, squamous cell carcinoma | | | | | | | | | | | X | | | | | 1
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate: 3 mg/kg

Number of Days on Study | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 2 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9
Number of Days on Study | 4 | 3 | 3 | 3 | 3 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | Total Tissues/Tumors
Carcass ID Number | 2 | 1 | 1 | 2 | 2 | 1 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 3 | Total Tissues/Tumors
Carcass ID Number | 2 | 6 | 8 | 0 | 1 | 7 | 9 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | | | | | | | | | | X | | 1
Squamous cell papilloma, multiple | | | X | | | | | | | | | | | | | 1
Tooth | | | | + | | | | | | | | | | | | 1
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | M | M | + | + | + | + | M | + | + | M | + | + | + | M | 10
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | X | | | | | | | | | | | | | 1
Skin, site of application, squamous cell papilloma | | | | | | X | | | | | | | | | | 1
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Alveolar/bronchiolar adenoma | | | | | | | | | X | | | | | | | 1
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | | | | | | | | | | | | X | | | | 1

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate: 6 mg/kg

Number of Days on Study | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 6 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9
Number of Days on Study | 2 | 3 | 3 | 3 | 3 | 3 | 3 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | Total Tissues/Tumors
Carcass ID Number | 4 | 3 | 3 | 3 | 3 | 3 | 4 | 3 | 3 | 3 | 3 | 4 | 4 | 4 | 4 | Total Tissues/Tumors
Carcass ID Number | 5 | 1 | 6 | 7 | 8 | 9 | 0 | 2 | 3 | 4 | 5 | 1 | 2 | 3 | 4 | Total Tissues/Tumors
Alimentary System
Esophagus | | | + | | | + | | | + | | | | | | | 3
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | X | | | | | | | | X | | X | X | | | 4
Squamous cell papilloma, multiple | | | | | | X | | | | | | | | | | 1
Tooth | + | + | | | | | | + | | | | | | | | 3
Odontogenic tumor | X | X | | | | | | X | | | | | | | | 3
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | M | + | + | + | + | + | + | + | + | M | + | + | + | + | 13
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skin, site of application, squamous cell carcinoma | | | | | | | | | | X | | | | | | 1
Skin, site of application, squamous cell papilloma | | X | | X | | | X | | X | X | | | X | | | 6
Skin, site of application, squamous cell papilloma, multiple | X | | X | | | X | | | | | X | X | | | | 5
Vulva, squamous cell papilloma | | | | | | | | | | | | X | | | | 1
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate: 12 mg/kg

Number of Days on Study | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 1 | 7 | 8 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9
Number of Days on Study | 8 | 6 | 9 | 3 | 3 | 3 | 3 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | Total Tissues/Tumors
Carcass ID Number | 5 | 5 | 5 | 4 | 4 | 4 | 5 | 4 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | Total Tissues/Tumors
Carcass ID Number | 3 | 5 | 8 | 7 | 8 | 9 | 1 | 6 | 0 | 2 | 4 | 6 | 7 | 9 | 0 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | | | | | | + | | | | | | | | | | 1
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | X | | X | | | X | X | | X | X | | 6
Squamous cell papilloma, multiple | | | | | | X | | | X | | | X | | | | 3
Tooth | | | + | | | | | + | | | | | | | | 2
Odontogenic tumor | | | | | | | | X | | | | | | | | 1
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | + | + | M | M | + | + | + | + | + | + | M | + | + | + | 12
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skin, site of application, squamous cell carcinoma | X | | | | | | | | | | | | | | | 1
Skin, site of application, squamous cell papilloma, multiple | X | X | X | X | X | X | X | X | X | X | X | X | X | X | X | 15
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
Eye | | | | | | | | | + | | | | | | | 1
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | X | X | | | | | | | | | | | | | | 2
Lymphoma malignant | | | | | | | | | | X | | | | | | 1

+: Tissue examined microscopically | M: Missing tissue | X: Lesion present
A: Autolysis precludes examination | I: Insufficient tissue | Blank: Not examined

TABLE B3 Statistical Analysis of Primary Neoplasms in Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Skin: Squamous Cell Papilloma
Overall rate^a^ | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 1/15 (7%) | 11/15 (73%) | 15/15 (100%)
Adjusted rate^b^ | 0.0% | 0.0% | 0.0% | 7.0% | 73.3% | 100.0%
Terminal rate^c^ | 0/15 (0%) | 0/14 (0%) | 0/12 (0%) | 1/14 (7%) | 10/14 (71%) | 12/12 (100%)
First incidence (days) | —^e^ | — | — | 193 (T) | 162 | 118
Poly-3 test^d^ | P<0.001 | —^f^ | — | P=0.490 | P<0.001 | P<0.001
Skin: Squamous Cell Papilloma or Squamous Cell Carcinoma
Overall rate | 0/15 (0%) | 1/15 (7%) | 1/15 (7%) | 2/15 (13%) | 11/15 (73%) | 15/15 (100%)
Adjusted rate | 0.0% | 6.7% | 8.1% | 14.0% | 73.3% | 100.0%
Terminal rate | 0/15 (0%) | 1/14 (7%) | 1/12 (8%) | 2/14 (14%) | 10/14 (71%) | 12/12 (100%)
First incidence (days) | — | 193 (T) | 193 (T) | 193 (T) | 162 | 118
Poly-3 test | P<0.001 | P=0.498 | P=0.461 | P=0.220 | P<0.001 | P<0.001
Stomach (Forestomach): Squamous Cell Papilloma
Overall rate | 4/15 (27%) | 5/15 (33%) | 4/15 (27%) | 2/15 (13%) | 5/15 (33%) | 9/15 (60%)
Adjusted rate | 26.7% | 33.7% | 32.5% | 14.0% | 34.3% | 64.6%
Terminal rate | 4/15 (27%) | 5/14 (36%) | 4/12 (33%) | 2/14 (14%) | 5/14 (36%) | 9/12 (75%)
First incidence (days) | 193 (T) | 193 (T) | 193 (T) | 193 (T) | 193 (T) | 193 (T)
Poly-3 test | P=0.014 | P=0.493 | P=0.535 | P=0.352N | P=0.481 | P=0.040
Tooth: Odontogenic Tumor
Overall rate | 1/15 (7%) | 4/15 (27%) | 2/15 (13%) | 0/15 (0%) | 3/15 (20%) | 1/15 (7%)
Adjusted rate | 6.7% | 26.9% | 16.2% | 0.0% | 20.0% | 7.2%
Terminal rate | 1/15 (7%) | 4/14 (29%) | 2/12 (17%) | 0/14 (0%) | 2/14 (14%) | 1/12 (8%)
First incidence (days) | 193 (T) | 193 (T) | 193 (T) | — | 162 | 193 (T)
Poly-3 test | P=0.397N | P=0.160 | P=0.431 | P=0.510N | P=0.298 | P=0.744
All Organs: Erythrocytic Leukemia
Overall rate | 0/15 (0%) | 1/15 (7%) | 0/15 (0%) | 1/15 (7%) | 0/15 (0%) | 2/15 (13%)
Adjusted rate | 0.0% | 6.7% | 0.0% | 7.0% | 0.0% | 13.4%
Terminal rate | 0/15 (0%) | 1/14 (7%) | 0/12 (0%) | 1/14 (7%) | 0/14 (0%) | 0/12 (0%)
First incidence (days) | — | 193 (T) | — | 193 (T) | — | 118
Poly-3 test | P=0.137 | P=0.498 | — | P=0.490 | — | P=0.231
All Organs: Malignant Lymphoma
Overall rate | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 3/15 (20%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 0.0% | 0.0% | 20.1%
Terminal rate | 0/15 (0%) | 0/14 (0%) | 0/12 (0%) | 0/14 (0%) | 0/14 (0%) | 1/12 (8%)
First incidence (days) | — | — | — | — | — | 118
Poly-3 test | P<0.001 | — | — | — | — | P=0.105
All Organs: Benign Neoplasms
Overall rate | 5/15 (33%) | 5/15 (33%) | 4/15 (27%) | 4/15 (27%) | 11/15 (73%) | 15/15 (100%)
Adjusted rate | 33.3% | 33.7% | 32.5% | 28.0% | 73.3% | 100.0%
Terminal rate | 5/15 (33%) | 5/14 (36%) | 4/12 (33%) | 4/14 (29%) | 10/14 (71%) | 12/12 (100%)
First incidence (days) | 193 (T) | 193 (T) | 193 (T) | 193 (T) | 162 | 118
Poly-3 test | P<0.001 | P=0.639 | P=0.635N | P=0.535N | P=0.027 | P<0.001
All Organs: Malignant Neoplasms
Overall rate | 1/15 (7%) | 2/15 (13%) | 1/15 (7%) | 1/15 (7%) | 1/15 (7%) | 3/15 (20%)
Adjusted rate | 6.7% | 13.3% | 8.1% | 7.0% | 6.9% | 20.1%
Terminal rate | 1/15 (7%) | 1/14 (7%) | 1/12 (8%) | 1/14 (7%) | 1/14 (7%) | 1/12 (8%)
First incidence (days) | 193 (T) | 183 | 193 (T) | 193 (T) | 193 (T) | 118
Poly-3 test | P=0.213 | P=0.500 | P=0.715 | P=0.749 | P=0.754 | P=0.297
All Organs: Benign or Malignant Neoplasms
Overall rate | 6/15 (40%) | 9/15 (60%) | 6/15 (40%) | 5/15 (33%) | 12/15 (80%) | 15/15 (100%)
Adjusted rate | 40.0% | 60.0% | 48.7% | 35.1% | 80.0% | 100.0%
Terminal rate | 6/15 (40%) | 8/14 (57%) | 6/12 (50%) | 5/14 (36%) | 11/14 (79%) | 12/12 (100%)
First incidence (days) | 193 (T) | 183 | 193 (T) | 193 (T) | 162 | 118
Poly-3 test | P<0.001 | P=0.236 | P=0.474 | P=0.541N | P=0.024 | P<0.001

(T)Terminal sacrifice

a Number of neoplasm-bearing animals/number of animals examined microscopically for skin; for other tissues, denominator is number of animals necropsied.

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal sacrifice. A negative trend or a lower incidence in a dosed group is indicated by N.

e Not applicable; no neoplasms in animal group

f Value of statistic cannot be computed.

TABLE B4 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | | | 1
Natural deaths | | 1 | 2 | 1 | 1 | 3
Survivors
Terminal sacrifice | 15 | 14 | 12 | 14 | 14 | 12
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | | 1 (7%) | | | 6 (40%)
Infiltration cellular | | | 1 (7%) | | | 1 (7%)
Inflammation, chronic active | 15 (100%) | 14 (93%) | 13 (87%) | 13 (87%) | 14 (93%) | 8 (53%)
Myelodysplasia | | | | | | 2 (13%)
Pigmentation | 12 (80%) | 15 (100%) | 12 (80%) | 13 (87%) | 14 (93%) | 4 (27%)
Hepatocyte, necrosis | 4 (27%) | 2 (13%) | 1 (7%) | 2 (13%) | 1 (7%) | 1 (7%)
Salivary glands | (1) | | | | | (1)
Parotid gland, infiltration cellular | | | | | | 1 (100%)
Tooth | (1) | (4) | (3) | (1) | (3) | (2)
Fibrosis | | | | | | 1 (50%)
Inflammation, chronic active | | | | 1 (100%)
Malformation | | | 1 (33%)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic active | | | | | | 1 (7%)
Atrium, thrombosis | | | | | | 1 (7%)
Endocrine System
Pituitary gland | (15) | (15) | (15) | (15) | (15) | (15)
Pars distalis, angiectasis | | | | 1 (7%)
Pars distalis, cyst | 1 (7%) | | 2 (13%) | 1 (7%) | 2 (13%) | 2 (13%)
Thyroid gland | (15) | (15) | (15) | (15) | (15) | (15)
Infiltration cellular | | | | | | 1 (7%)
Inflammation, chronic active | | | | | | 2 (13%)
General Body System
None
Genital System
Ovary | (15) | (15) | (15) | (15) | (15) | (15)
Cyst | 1 (7%) | | | 1 (7%) | | 1 (7%)
Inflammation, chronic active | | | | 1 (7%) | 1 (7%)
Pigmentation | 1 (7%) | 1 (7%)
Uterus | (15) | (15) | (15) | (15) | (15) | (15)
Hydrometra | | 1 (7%) | | 1 (7%) | 1 (7%) | 1 (7%)
Inflammation, chronic active | 1 (7%)
Cervix, inflammation, chronic active | | 1 (7%)
Endometrium, hyperplasia, cystic | 10 (67%) | 11 (73%) | 7 (47%) | 8 (53%) | 8 (53%) | 9 (60%)
Hematopoietic System
Lymph node | (11) | (14) | (13) | (10) | (13) | (12)
Hematopoietic cell proliferation | | | | | | 2 (17%)
Hyperplasia | | | | | | 2 (17%)
Inguinal, hematopoietic cell proliferation | | | | | | 1 (8%)
Inguinal, hyperplasia | | | | | | 1 (8%)
Inguinal, infiltration cellular, plasma cell | | | | | | 2 (17%)
Inguinal, myelodysplasia | | | | | | 2 (17%)
Mediastinal, hematopoietic cell proliferation | | | | | | 5 (42%)
Mediastinal, infiltration cellular | | | 1 (8%) | | | 2 (17%)
Mediastinal, infiltration cellular, plasma cell | | | | | | 2 (17%)
Lymph node, mandibular | (15) | (15) | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | | 1 (7%) | | | 6 (40%)
Hyperplasia | 1 (7%) | 3 (20%) | 2 (13%) | | 2 (13%) | 3 (20%)
Hyperplasia, plasma cell | | | 1 (7%) | | 1 (7%)
Infiltration cellular | | | 1 (7%) | | | 1 (7%)
Infiltration cellular, plasma cell | | | 1 (7%) | | | 2 (13%)
Inflammation, chronic active | | | 1 (7%)
Myelodysplasia | | | | | | 1 (7%)
Lymph node, mesenteric | (15) | (14) | (14) | (15) | (15) | (15)
Hematopoietic cell proliferation | | | | | | 4 (27%)
Infiltration cellular | | | | | | 2 (13%)
Spleen | (15) | (15) | (15) | (15) | (15) | (15)
Atrophy | | 1 (7%) | 3 (20%) | 1 (7%) | 2 (13%) | 1 (7%)
Hematopoietic cell proliferation | 7 (47%) | 13 (87%) | 9 (60%) | 6 (40%) | 8 (53%) | 10 (67%)
Hyperplasia, lymphoid | 2 (13%) | 2 (13%) | 2 (13%)
Infiltration cellular | | | | | | 1 (7%)
Myelodysplasia | | | | | | 2 (13%)
Thymus | (15) | (15) | (15) | (15) | (15) | (15)
Atrophy | | 1 (7%) | 3 (20%) | 2 (13%) | 2 (13%) | 3 (20%)
Thymocyte, necrosis | | | 2 (13%) | 1 (7%) | | 1 (7%)
Integumentary System
Skin | (15) | (15) | (15) | (15) | (15) | (15)
Epidermis, site of application, hyperplasia | | | 1 (7%) | 4 (27%) | 15 (100%) | 15 (100%)
Epidermis, site of application, hyperplasia, focal | | | | 1 (7%) | 1 (7%) | 8 (53%)
Site of application, hyperkeratosis | | | 1 (7%) | 7 (47%) | 14 (93%) | 13 (87%)
Site of application, hyperplasia | | | | | 1 (7%)
Site of application, inflammation, chronic active | | | | 3 (20%) | 14 (93%) | 12 (80%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic active | | | 1 (7%)
Mediastinum, infiltration cellular | | | | | | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic active | | | 2 (13%) | | | 3 (20%)
Mineralization | | | | | | 1 (7%)
Nephropathy | 4 (27%) | | | | | 1 (7%)
Renal tubule, cyst | | | | | | 1 (7%)
Renal tubule, regeneration | | 1 (7%) | | | 2 (13%) | 1 (7%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE B5

In-Life Observation of Skin Papilloma at the Site of Application in Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate: 6 mg/kg^a^

Carcass ID Number | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | Total Tumors | Animals with Tumors
Carcass ID Number | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 4 | 4 | 4 | 4 | 4 | 4 | Total Tumors | Animals with Tumors
Carcass ID Number | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | Total Tumors | Animals with Tumors
Week
9 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 1 | 1
10 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 1 | 1
11 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 1 | 1
12 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0
13 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 0 | 1 | 1
14 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 0 | 1 | 1
15 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 0 | 2 | 2
16 | 0 | 0 | 0 | 0 | 2 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 0 | 3 | 2
17 | 0 | 0 | 0 | 0 | 2 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 0 | 3 | 2
18 | 0 | 0 | 0 | 0 | 3 | 0 | 0 | 0 | 0 | | 0 | 0 | 0 | 0 | 0 | 5 | 2
19 | 0 | 0 | 0 | 0 | 3 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 0 | 4 | 2
20 | 0 | 0 | 0 | 0 | 3 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 0 | 4 | 2
21 | 0 | 0 | 0 | 0 | 3 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 0 | 4 | 2
22 | 0 | 0 | 0 | 0 | 3 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 0 | 4 | 2
23 | 0 | 0 | 3 | 0 | 5 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 0 | 9 | 3
24 | 0 | 0 | 2 | 0 | 7 | 3 | 0 | 0 | 0 | 1 | 3 | 0 | 0 | 0 | 0 | 16 | 5
25 | 0 | 0 | 2 | 0 | 7 | 4 | 0 | 0 | 3 | 1 | 3 | 1 | 0 | 0 | X | 21 | 7
26 | 0 | 1 | 2 | 0 | 7 | 4 | 0 | 0 | 3 | 1 | 3 | 1 | 0 | 0 | | 22 | 8
27 | 0 | 0 | 2 | 0 | 12 | 4 | 0 | 0 | 2 | 1 | 3 | 1 | 0 | 0 | | 25 | 7
28 | 0 | 0 | 2 | 3 | 10 | 4 | 3 | 0 | 3 | 2 | 4 | 2 | 0 | 0 | | 33 | 9
Necropsy | 1 | 0 | 3 | 2 | 12 | 5 | 3 | 0 | 4 | 1 | 4 | 1 | 0 | 0 | 0 | 36 | 10

In-Life Observation of Skin Papilloma at the Site of Application in Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate: 12 mg/kg

Carcass ID Number | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | Total Tumors | Animals with Tumors
Carcass ID Number | 4 | 4 | 4 | 4 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | Total Tumors | Animals with Tumors
Carcass ID Number | 6 | 7 | 8 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | Total Tumors | Animals with Tumors
Week
10 | 0 | 0 | 1 | 0 | 3 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 5 | 3
11 | 0 | 0 | 1 | 0 | 5 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 7 | 3
12 | 0 | 0 | 3 | 2 | 7 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 13 | 4
13 | 7 | 0 | 3 | 3 | 8 | 0 | 0 | 3 | 0 | 0 | 0 | 0 | 2 | 0 | 0 | 26 | 6
14 | 9 | 5 | 4 | 3 | 11 | 0 | 3 | 7 | 0 | 0 | 8 | 7 | 1 | 0 | 0 | 58 | 10
15 | 10 | 7 | 10 | 6 | 13 | 0 | 7 | 9 | 0 | 0 | 10 | 7 | 9 | 0 | 15 | 103 | 11
16 | 9 | 6 | 10 | 8 | 14 | 7 | 7 | 11 | 7 | 14 | 11 | 10 | 5 | 0 | 17 | 136 | 14
17 | 15 | 7 | 15 | 8 | 20 | 10 | 10 | 17 | 7 | 17 | 20 | 16 | 13 | 8 | 20 | ≥203 | 15
18 | 20 | 7 | 20 | 20 | 20 | 10 | 20 | X | 7 | 15 | 20 | 20 | 20 | 10 | 20 | ≥229 | 14
19 | 20 | 7 | 20 | 20 | 20 | 10 | 20 | | 15 | 20 | 20 | 20 | 20 | 15 | 20 | ≥247 | 14
20 | 20 | 8 | 20 | 20 | 20 | 13 | 20 | | 15 | 20 | 20 | 20 | 20 | 15 | 15 | ≥246 | 14
21 | 20 | 9 | 20 | 20 | 20 | 10 | 20 | | 12 | 20 | 20 | 20 | 20 | 20 | 20 | ≥251 | 14
22 | 20 | 10 | 20 | 20 | 20 | 12 | 20 | | 20 | 20 | 20 | 20 | 20 | 20 | 20 | ≥262 | 14
23 | 20 | 13 | 20 | 20 | 20 | 16 | 20 | | 20 | 20 | 20 | 20 | 20 | 20 | 20 | ≥269 | 14
24 | 20 | 11 | 20 | 20 | 20 | 20 | 20 | | 20 | 20 | 20 | 20 | 20 | 20 | 20 | ≥271 | 14
25 | 20 | 9 | 20 | 20 | 20 | 20 | 20 | | 20 | 20 | 20 | 20 | 20 | 20 | 20 | ≥269 | 14
26 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | | 20 | X | 20 | 20 | 20 | 20 | 20 | ≥260 | 13
27 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | | 20 | | 20 | 20 | 20 | 20 | 20 | ≥260 | 13
28 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | | 20 | | 20 | 20 | X | 20 | 20 | ≥240 | 12
Necropsy | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 15 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | ≥295 | 15

X=animal died

a No papillomas occurred in the vehicle control or 0.75 mg/kg groups. In the 1.5 mg/kg group, animal 308 had a single papilloma observed from week 19 through necropsy. In the 3 mg/kg group, animals 317 and 318 each had a single papilloma first observed at necropsy. The maximum number of papillomas reported in the 12 mg/kg group was 20, although some mice in this group had more than 20 papillomas.