# APPENDIX A SUMMARY OF LESIONS IN MALE Tg.AC HEMIZYGOUS MICE IN THE 6-MONTH DERMAL STUDY OF TRIMETHYLOLPROPANE TRIACRYLATE

TABLE A1 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Natural deaths | 1 | | 3 | 1 | 2 | 4
Survivors
Terminal sacrifice | 14 | 15 | 12 | 14 | 13 | 11
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (15) | (15)
Salivary glands | | | (1) | (1) | | (2)
Carcinoma | | | 1 (100%) | 1 (100%) | | 1 (50%)
Stomach, forestomach | (15) | (15) | (15) | (15) | (15) | (15)
Squamous cell papilloma | 3 (20%) | 4 (27%) | 1 (7%) | 2 (13%) | 2 (13%) | 2 (13%)
Squamous cell papilloma, multiple | 2 (13%) | 3 (20%) | | 2 (13%) | 1 (7%)
Tooth | (1) | (3) | (1) | (2) | (1) | (1)
Odontogenic tumor | 1 (100%) | 3 (100%) | 1 (100%) | | 1 (100%) | 1 (100%)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15) | (15)
Endocrine System
Pituitary gland | (15) | (15) | (15) | (14) | (15) | (15)
General Body System
None
Genital System
None
Hematopoietic System
Lymph node | (13) | (13) | (14) | (15) | (14) | (14)
Lymph node, mandibular | (15) | (14) | (15) | (15) | (14) | (13)
Lymph node, mesenteric | (15) | (14) | (14) | (15) | (15) | (12)
Spleen | (15) | (15) | (15) | (15) | (15) | (15)
Thymus | (15) | (15) | (14) | (15) | (15) | (15)
Integumentary System
Skin | (15) | (15) | (15) | (15) | (15) | (15)
Squamous cell papilloma | | | | | | 2 (13%)
Skin, site of application, squamous cell papilloma | | | | 2 (13%)
Skin, site of application, squamous cell papilloma, multiple | | | | | 12 (80%) | 13 (87%)
Subcutaneous tissue, fibrosarcoma | | | 1 (7%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15) | (14)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15) | (15)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15) | (15)
Leukemia erythrocytic | | | | | | 1 (7%)
Lymphoma malignant | | | | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 6 | 8 | 4 | 6 | 12 | 13
Total primary neoplasms | 6 | 10 | 4 | 8 | 16 | 20
Total animals with benign neoplasms | 5 | 7 | 1 | 5 | 12 | 13
Total benign neoplasms | 5 | 7 | 1 | 6 | 15 | 17
Total animals with malignant neoplasms | | | 2 | 1 | | 2
Total malignant neoplasms | | | 2 | 2 | | 2
Total animals with uncertain neoplasms-benign or malignant | 1 | 3 | 1 | | 1 | 1
Total uncertain neoplasms | 1 | 3 | 1 | | 1 | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A2

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate: Vehicle Control

Number of Days on Study | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 0 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9
Number of Days on Study | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 8 | 8 | 8 | 8 | 8 | 9 | 9 | 8 | 8 | 8 | 8 | 9 | 9 | 9 | 9 | Total Tissues/Tumors
Carcass ID Number | 1 | 2 | 4 | 5 | 6 | 1 | 3 | 3 | 7 | 8 | 9 | 0 | 2 | 4 | 5 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | | X | | | | | | X | | X | | 3
Squamous cell papilloma, multiple | X | | | | X | | | | | | | | | | | 2
Tooth | | | | | | | | + | | | | | | | | 1
Odontogenic tumor | | | | | | | | X | | | | | | | | 1
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Preputial gland | | | | | | | | | | + | | | | | | 1
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | + | + | + | + | + | + | + | + | + | + | M | + | M | + | 13
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate: 0.75 mg/kg

Number of Days on Study | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9
Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 3
Carcass ID Number | 1 | 1 | 1 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 9 | 9 | 9 | 9 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 0 | Total Tissues/Tumors
Carcass ID Number | 6 | 7 | 8 | 9 | 0 | 1 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | 2 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | X | | | X | | X | | | | | | | | X | 4
Squamous cell papilloma, multiple | | | | | | X | | X | X | | | | | | | 3
Tooth | | | | | | | + | + | | + | | | | | | 3
Odontogenic tumor | | | | | | | X | X | | X | | | | | | 3
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | M | + | + | + | + | + | + | + | M | + | + | + | + | + | + | 13
Lymph node, mandibular | + | + | + | + | + | + | M | + | + | + | + | + | + | + | + | 14
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | M | + | + | + | + | 14
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate: 1.5 mg/kg

Number of Days on Study | 0 | 0 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 7 | 9 | 5 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9
Number of Days on Study | 4 | 5 | 7 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 3 | 3 | 3 | 3 | 3
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 2 | 2 | 2 | 1 | 1 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 3 | 2 | 6 | 1 | 5 | 7 | 8 | 1 | 2 | 5 | 4 | 9 | 0 | 3 | 4 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | | + | | | | | | | | | | | | | | 1
Carcinoma | | X | | | | | | | | | | | | | | 1
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | | | | | | X | | | | | | 1
Tooth | | | + | | | | | | | | | | | | | 1
Odontogenic tumor | | | X | | | | | | | | | | | | | 1
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | + | + | + | + | + | + | + | + | + | M | + | + | + | + | 14
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | M | + | + | + | + | 14
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | M | + | + | + | + | 14
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Subcutaneous tissue, fibrosarcoma | | | | | | | | | | | X | | | | | 1
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | | | | | | | | | | | + | | | | | 1
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate: 3 mg/kg

Number of Days on Study | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 3 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9
Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 3 | 3 | 3 | 3 | 3
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 3 | 2 | 2 | 2 | 2 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 4 | Total Tissues/Tumors
Carcass ID Number | 5 | 6 | 7 | 8 | 9 | 0 | 1 | 3 | 7 | 9 | 2 | 4 | 6 | 8 | 0 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | + | | | | | | | | | | | | | | | 1
Carcinoma | X | | | | | | | | | | | | | | | 1
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | X | | | | | X | | | | | | | | 2
Squamous cell papilloma, multiple | | X | | | | X | | | | | | | | | | 2
Tooth | | | | | | | + | | | | | | | | + | 2
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | M | + | + | + | + | + | + | + | 14
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skin, site of application, squamous cell papilloma | | X | | | X | | | | | | | | | | | 2
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymphoma malignant | X | | | | | | | | | | | | | | | 1

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate: 6 mg/kg

Number of Days on Study | 0 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 9 | 8 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9
Number of Days on Study | 2 | 0 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 3 | 3 | 3 | 3 | 3
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 5 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 5 | 4 | 4 | 5 | 5 | 5 | Total Tissues/Tumors
Carcass ID Number | 3 | 3 | 1 | 2 | 5 | 7 | 8 | 9 | 2 | 5 | 4 | 6 | 0 | 1 | 4 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Mesentery | | | + | | | | | | | | | | | | | 1
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | X | | | | | | | | X | | | | 2
Squamous cell papilloma, multiple | | | | | | X | | | | | | | | | | 1
Tooth | | + | | | | | | | | | | | | | | 1
Odontogenic tumor | | X | | | | | | | | | | | | | | 1
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | + | + | + | + | + | + | + | + | + | + | + | M | + | + | 14
Lymph node, mandibular | I | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skin, site of application, squamous cell papilloma, multiple | | X | X | X | | X | X | X | X | X | | X | X | X | X | 12
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate: 12 mg/kg

Number of Days on Study | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 6 | 6 | 8 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9
Number of Days on Study | 1 | 1 | 2 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 3 | 3
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 5 | 6 | 6 | 6 | 5 | 5 | 5 | 6 | 6 | 6 | 6 | 6 | 7 | 6 | 6 | Total Tissues/Tumors
Carcass ID Number | 8 | 6 | 9 | 7 | 6 | 7 | 9 | 1 | 2 | 4 | 5 | 8 | 0 | 0 | 3 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Mesentery | | | | | | | | | | | | + | | | | 1
Salivary glands | | | | | + | | | | | | | | | | | 1
Carcinoma | | | | | X | | | | | | | | | | | 1
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | | | | | X | | | | | | X | 2
Tooth | | | | | | | | | | | | | | + | | 1
Odontogenic tumor | | | | | | | | | | | | | | X | | 1
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Preputial gland | | | | | + | | | | | | | | | | | 1
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | + | M | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mandibular | + | + | + | M | M | + | + | + | + | + | + | + | + | + | + | 13
Lymph node, mesenteric | + | M | + | M | + | + | + | + | M | + | + | + | + | + | + | 12
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | | | | | | | | X | | X | | 2
Skin, site of application, squamous cell papilloma, multiple | X | X | X | X | X | | X | X | X | | X | X | X | X | X | 13
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | M | + | + | + | 14
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | | | | | | | + | | + | | | | + | | | 3
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | | | | | | | | | | | X | | | | | 1

+: Tissue examined microscopically | M: Missing tissue | X: Lesion present
A: Autolysis precludes examination | I: Insufficient tissue | Blank: Not examined

TABLE A3 Statistical Analysis of Primary Neoplasms in Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Skin: Squamous Cell Papilloma
Overall rate^a^ | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 2/15 (13%) | 12/15 (80%) | 13/15 (87%)
Adjusted rate^b^ | 0.0% | 0.0% | 0.0% | 14.0% | 85.1% | 86.7%
Terminal rate^c^ | 0/14 (0%) | 0/15 (0%) | 0/12 (0%) | 2/14 (14%) | 11/13 (85%) | 9/11 (82%)
First incidence (days) | —^e^ | — | — | 192 (T) | 180 | 161
Poly-3 test^d^ | P<0.001 | —^f^ | — | P=0.234 | P<0.001 | P<0.001
Stomach (Forestomach): Squamous Cell Papilloma
Overall rate | 5/15 (33%) | 7/15 (47%) | 1/15 (7%) | 4/15 (27%) | 3/15 (20%) | 2/15 (13%)
Adjusted rate | 33.3% | 46.7% | 7.9% | 27.9% | 21.5% | 14.3%
Terminal rate | 4/14 (29%) | 7/15 (47%) | 1/12 (8%) | 4/14 (29%) | 3/13 (23%) | 2/11 (18%)
First incidence (days)101 | 101 | 192 (T) | 192 (T) | 192 (T) | 192 (T) | 192 (T)
Poly-3 test | P=0.095N | P=0.358 | P=0.121N | P=0.532N | P=0.387N | P=0.224N
Tooth: Odontogenic Tumor
Overall rate | 1/15 (7%) | 3/15 (20%) | 1/15 (7%) | 0/15 (0%) | 1/15 (7%) | 1/15 (7%)
Adjusted rate | 7.1% | 20.0% | 7.6% | 0.0% | 7.1% | 7.1%
Terminal rate | 1/14 (7%) | 3/15 (20%) | 0/12 (0%) | 0/14 (0%) | 0/13 (0%) | 1/11 (9%)
First incidence (days) | 192 (T) | 192 (T) | 157 | — | 180 | 192 (T)
Poly-3 test | P=0.403N | P=0.320 | P=0.745 | P=0.497N | P=0.760 | P=0.759
All Organs: Erythrocytic Leukemia
Overall rate | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 1/15 (7%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 0.0% | 0.0% | 7.1%
Terminal rate | 0/14 (0%) | 0/15 (0%) | 0/12 (0%) | 0/14 (0%) | 0/13 (0%) | 1/11 (9%)
First incidence (days) | — | — | — | — | — | 192 (T)
Poly-3 test | P=0.106 | — | — | — | — | P=0.498
All Organs: Malignant Lymphoma
Overall rate | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 1/15 (7%) | 0/15 (0%) | 0/15 (0%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 6.7% | 0.0% | 0.0%
Terminal rate | 0/14 (0%) | 0/15 (0%) | 0/12 (0%) | 0/14 (0%) | 0/13 (0%) | 0/11 (0%)
First incidence (days) | — | — | — | 132 | — | —
Poly-3 test | P=0.695N | — | — | P=0.512 | — | —
All Organs: Benign Neoplasms
Overall rate | 5/15 (33%) | 7/15 (47%) | 1/15 (7%) | 5/15 (33%) | 12/15 (80%) | 13/15 (87%)
Adjusted rate | 33.3% | 46.7% | 7.9% | 34.9% | 85.1% | 86.7%
Terminal rate | 4/14 (29%) | 7/15 (47%) | 1/12 (8%) | 5/14 (36%) | 11/13 (85%) | 9/11 (82%)
First incidence (days) | 101 | 192 (T) | 192 (T) | 192 (T) | 180 | 161
Poly-3 test | P<0.001 | P=0.358 | P=0.121N | P=0.614 | P=0.003 | P<0.001
All Organs: Malignant Neoplasms
Overall rate | 0/15 (0%) | 0/15 (0%) | 2/15 (13%) | 1/15 (7%) | 0/15 (0%) | 2/15 (13%)
Adjusted rate | 0.0% | 0.0% | 14.7% | 6.7% | 0.0% | 14.3%
Terminal rate | 0/14 (0%) | 0/15 (0%) | 1/12 (8%) | 0/14 (0%) | 0/13 (0%) | 2/11 (18%)
First incidence (days) | — | — | 95 | 132 | — | 192 (T)
Poly-3 test | P=0.182 | — | P=0.222 | P=0.512 | — | P=0.229
All Organs: Benign or Malignant Neoplasms
Overall rate | 6/15 (40%) | 8/15 (53%) | 4/15 (27%) | 6/15 (40%) | 12/15 (80%) | 13/15 (87%)
Adjusted rate | 40.0% | 53.3% | 28.5% | 40.0% | 85.1% | 86.7%
Terminal rate | 5/14 (36%) | 8/15 (53%) | 2/12 (17%) | 5/14 (36%) | 11/13 (85%) | 9/11 (82%)
First incidence (days) | 101 | 192 (T) | 95 | 132 | 180 | 161
Poly-3 test | P<0.001 | P=0.361 | P=0.399N | P=0.641 | P=0.011 | P<0.006

(T)Terminal sacrifice

a Number of neoplasm-bearing animals/number of animals examined microscopically for skin; for other tissues, denominator is number of animals necropsied.

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal sacrifice. A negative trend or a lower incidence in a dosed group is indicated by N.

e Not applicable; no neoplasms in animal group

f Value of statistic cannot be computed.

TABLE A4 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Natural deaths | 1 | | 3 | 1 | 2 | 4
Survivors
Terminal sacrifice | 14 | 15 | 12 | 14 | 13 | 11
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (15) | (15)
Basophilic focus | | 1 (7%)
Hematopoietic cell proliferation | 1 (7%) | | 1 (7%) | | | 6 (40%)
Infarct | | 1 (7%)
Infiltration cellular | | | | | | 5 (33%)
Inflammation, acute | | 1 (7%)
Inflammation, chronic active | 7 (47%) | 10 (67%) | 8 (53%) | 8 (53%) | 7 (47%) | 8 (53%)
Mineralization | | 1 (7%)
Myelodysplasia | | | | | | 1 (7%)
Pigmentation | | 2 (13%)
Hepatocyte, necrosis | 2 (13%) | 2 (13%) | 2 (13%) | | 1 (7%) | 1 (7%)
Mesentery | | | | | (1) | (1)
Fat, necrosis | | | | | 1 (100%) | 1 (100%)
Salivary glands | | | (1) | (1) | | (2)
Mandibular, infiltration cellular | | | | | | 1 (50%)
Stomach, forestomach | (15) | (15) | (15) | (15) | (15) | (15)
Hyperkeratosis | | | 1 (7%) | | 1 (7%) | 3 (20%)
Inflammation, chronic active | | | | | 1 (7%)
Epithelium, hyperplasia | | | | | 1 (7%)
Tooth | (1) | (3) | (1) | (2) | (1) | (1)
Inflammation, chronic active | | | | 1 (50%)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15) | (15)
Atrium, thrombosis | | | 1 (7%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15) | (15) | (15)
Hyperplasia | | | | | | 1 (7%)
Hypertrophy | 7 (47%) | 5 (33%) | 9 (60%) | 8 (53%) | 5 (33%) | 5 (33%)
Vacuolization cytoplasmic | | | | | | 1 (7%)
Pituitary gland | (15) | (15) | (15) | (14) | (15) | (15)
Pars distalis, cyst | 2 (13%) | 1 (7%) | 1 (7%) | 1 (7%) | 1 (7%) | 2 (13%)
Thyroid gland | (15) | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic active | | | | | | 1 (7%)
Follicle, cyst | | | 1 (7%)
General Body System
None
Genital System
Epididymis | (15) | (15) | (15) | (15) | (15) | (15)
Atrophy | | 1 (7%)
Inflammation, chronic active | | 2 (13%) | | | | 3 (20%)
Myelodysplasia | | | | | | 1 (7%)
Bilateral, hypospermia | | 1 (7%)
Unilateral, hypospermia | 4 (27%) | | 3 (20%) | 1 (7%) | 1 (7%) | 2 (13%)
Preputial gland | (1) | | | | | (1)
Inflammation, chronic active | | | | | | 1 (100%)
Duct, ectasia | 1 (100%)
Testes | (15) | (15) | (15) | (15) | (15) | (15)
Cyst | 2 (13%) | | 1 (7%) | | | 1 (7%)
Bilateral, germinal epithelium, degeneration | | 1 (7%)
Germinal epithelium, degeneration | | | | | | 1 (7%)
Unilateral, germinal epithelium, degeneration | 4 (27%) | | 3 (20%) | 1 (7%) | 1 (7%) | 2 (13%)
Hematopoietic System
Lymph node | (13) | (13) | (14) | (15) | (14) | (14)
Hyperplasia | | | | | | 4 (29%)
Inflammation, chronic active | | | | | | 3 (21%)
Axillary, infiltration cellular | | | | | | 1 (7%)
Axillary, infiltration cellular, plasma cell | | | | | | 1 (7%)
Inguinal, hyperplasia | | | | | | 1 (7%)
Inguinal, inflammation, chronic active | | | | | | 1 (7%)
Mediastinal, hematopoietic cell proliferation | | | | | | 1 (7%)
Mediastinal, hyperplasia | | | | | | 1 (7%)
Mediastinal, infiltration cellular | | | | | | 3 (21%)
Mediastinal, infiltration cellular, plasma cell | | | | | | 3 (21%)
Mediastinal, inflammation, chronic active | | | | | | 2 (14%)
Lymph node, mandibular | (15) | (14) | (15) | (15) | (14) | (13)
Hematopoietic cell proliferation | | | | | | 2 (15%)
Hyperplasia | | 1 (7%) | | | | 1 (8%)
Hyperplasia, plasma cell | | | 1 (7%) | | 1 (7%)
Infiltration cellular | | | | | | 4 (31%)
Infiltration cellular, plasma cell | | | | | | 1 (8%)
Lymph node, mesenteric | (15) | (14) | (14) | (15) | (15) | (12)
Infiltration cellular | | | | | | 1 (8%)
Spleen | (15) | (15) | (15) | (15) | (15) | (15)
Atrophy | | | 1 (7%) | | 1 (7%) | 4 (27%)
Depletion cellular | | | 1 (7%) | | 1 (7%)
Hematopoietic cell proliferation | 1 (7%) | 4 (27%) | 1 (7%) | 2 (13%) | 6 (40%) | 8 (53%)
Hyperplasia, lymphoid | | 1 (7%) | 1 (7%) | 1 (7%) | 1 (7%)
Thymus | (15) | (15) | (14) | (15) | (15) | (15)
Atrophy | 1 (7%) | | 1 (7%) | | 2 (13%) | 5 (33%)
Thymocyte, necrosis | | | | | | 1 (7%)
Integumentary System
Skin | (15) | (15) | (15) | (15) | (15) | (15)
Epidermis, skin, site of application, hyperplasia | | | | 6 (40%) | 14 (93%) | 15 (100%)
Epidermis, skin, site of application, hyperplasia, focal | | | 1 (7%) | | 1 (7%)
Skin, site of application, hyperkeratosis | | | 1 (7%) | 15 (100%) | 14 (93%) | 12 (80%)
Skin, site of application, hyperplasia | | | | | | 1 (7%)
Skin, site of application, inflammation, chronic active | | | 1 (7%) | 1 (7%) | 9 (60%) | 12 (80%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15) | (14)
Inflammation, chronic active | | 2 (13%) | | | | 2 (14%)
Thrombosis | | | | 1 (7%)
Interstitium, hyperplasia | 1 (7%)
Interstitium, inflammation, chronic active | | | 1 (7%)
Mediastinum, infiltration cellular | | | | | | 1 (7%)
Mediastinum, inflammation, chronic active | | | | | | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15) | (15)
Infarct | | | | | 1 (7%) | 1 (7%)
Infiltration cellular | | | | | | 1 (7%)
Infiltration cellular, mononuclear cell | 1 (7%) | 1 (7%) | | | | 1 (7%)
Inflammation, chronic active | | 2 (13%) | 1 (7%) | | 1 (7%) | 5 (33%)
Mineralization | | | | | 1 (7%)
Nephropathy | 3 (20%) | 6 (40%) | | | | 3 (20%)
Glomerulus, renal tubule, dilatation | | | | | 1 (7%)
Renal tubule, cyst | 1 (7%) | 1 (7%) | | | | 1 (7%)
Renal tubule, hyperplasia | 1 (7%) | | 1 (7%) | | 1 (7%) | 1 (7%)
Renal tubule, regeneration | 2 (13%) | 1 (7%) | 5 (33%) | 4 (27%) | 4 (27%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A5

In-Life Observation of Skin Papilloma at the Site of Application in Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate: 6 mg/kg^a^

Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tumors | Animals with Tumors
Carcass ID Number | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 5 | 5 | 5 | 5 | 5 | Total Tumors | Animals with Tumors
Carcass ID Number | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | Total Tumors | Animals with Tumors
Week
14 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 1
15 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | X | 0 | 0 | 1 | 1
16 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | | 7 | 0 | 8 | 2
17 | 2 | 0 | 0 | 0 | 0 | 1 | 0 | 1 | 0 | 0 | 0 | 0 | | 6 | 0 | 10 | 4
18 | 2 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | | 6 | 0 | 9 | 3
19 | 2 | 0 | 9 | 0 | 2 | 0 | 0 | 1 | 0 | 1 | 0 | 0 | | 6 | 0 | 21 | 6
20 | 2 | 0 | 11 | 0 | 1 | 0 | 0 | 1 | 0 | 1 | 0 | 4 | | 8 | 0 | 28 | 7
21 | 3 | 0 | 8 | 0 | 2 | 0 | 0 | 2 | 0 | 1 | 0 | 5 | | 14 | 0 | 35 | 7
22 | 3 | 0 | 13 | 0 | 2 | 0 | 1 | 2 | 0 | 2 | 0 | 9 | | 16 | 0 | 48 | 8
23 | 4 | 0 | 12 | 0 | 2 | 0 | 2 | 8 | 6 | 3 | 2 | 7 | | 20 | 0 | ≥66 | 10
24 | 4 | 0 | 13 | 0 | 2 | 0 | 2 | 8 | 5 | 4 | 2 | 9 | | 16 | 0 | 65 | 10
25 | 4 | 0 | 13 | 0 | 2 | 0 | 3 | 8 | 6 | 6 | 2 | 15 | | 20 | 4 | ≥83 | 11
26 | 4 | 0 | 20 | 0 | 0 | 3 | 3 | 8 | 7 | 7 | 3 | 15 | | 20 | 4 | ≥94 | 11
27 | 4 | 0 | X | 0 | 0 | 3 | 6 | 13 | 6 | 8 | 5 | 20 | | 20 | 6 | ≥91 | 10
28 | 3 | 0 | | 0 | 0 | 3 | 6 | 12 | 6 | 8 | 4 | 20 | | 20 | 8 | ≥90 | 10
Necropsy | 3 | 5 | 17 | 0 | 0 | 2 | 6 | 14 | 7 | 8 | 4 | 20 | 0 | 20 | 9 | ≥115 | 12

In-Life Observation of Skin Papilloma at the Site of Application in Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate: 12 mg/kg

Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tumors | Animals with Tumors
Carcass ID Number | 5 | 5 | 5 | 5 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 7 | Total Tumors | Animals with Tumors
Carcass ID Number | 6 | 7 | 8 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | Total Tumors | Animals with Tumors
Week
9 | 0 | 0 | 0 | 0 | 3 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 3 | 1
10 | 0 | 0 | 0 | 0 | 2 | 0 | 0 | 1 | 0 | 0 | 3 | 0 | 0 | 4 | 0 | 10 | 4
11 | 0 | 0 | 0 | 0 | 3 | 0 | 0 | 1 | 0 | 0 | 2 | 0 | 0 | 3 | 0 | 9 | 4
12 | 0 | 0 | 0 | 0 | 3 | 0 | 0 | 1 | 0 | 1 | 7 | 0 | 0 | 4 | 5 | 21 | 6
13 | 5 | 0 | 1 | 0 | 8 | 0 | 5 | 1 | 0 | 2 | 7 | 0 | 0 | 5 | 6 | 40 | 9
14 | 9 | 0 | 1 | 0 | 8 | 0 | 6 | 3 | 0 | 3 | 6 | 0 | 7 | 4 | 8 | 55 | 10
15 | 12 | 0 | 3 | 7 | 11 | 0 | 9 | 3 | 0 | 5 | 11 | 5 | 12 | 12 | 12 | 102 | 12
16 | 14 | 0 | 3 | 12 | 10 | 16 | 9 | 5 | 0 | 5 | 12 | 10 | 13 | 11 | 10 | 130 | 13
17 | 20 | 0 | 6 | 15 | 13 | 20 | 13 | 7 | 0 | 5 | 13 | 14 | 17 | 15 | 12 | ≥170 | 13
18 | 20 | 0 | 12 | 16 | 13 | 20 | 15 | 15 | 0 | 6 | 20 | 20 | 20 | 20 | 13 | ≥210 | 13
19 | 20 | 0 | 10 | 18 | 17 | 20 | 14 | 20 | 0 | 7 | 20 | 20 | 20 | 20 | 16 | ≥222 | 13
20 | 20 | 0 | 15 | 15 | 20 | 20 | 20 | 20 | 0 | 6 | 20 | 20 | 20 | 20 | 20 | ≥236 | 13
21 | 20 | 0 | 20 | 20 | 20 | 20 | 20 | 20 | 0 | 4 | 20 | 20 | 20 | 20 | 20 | ≥244 | 13
22 | 20 | 0 | 15 | 20 | 20 | 20 | 20 | 20 | 0 | 7 | 20 | 20 | 20 | 20 | 20 | ≥242 | 13
23 | 20 | 0 | 20 | 20 | 20 | 20 | 20 | 20 | 0 | 13 | 20 | 20 | 20 | 20 | 20 | ≥253 | 13
24 | 20 | 0 | X | 20 | 20 | 20 | 20 | 20 | 0 | 20 | X | 20 | 20 | 20 | 20 | ≥220 | 11
25 | 20 | 0 | | 20 | 20 | 20 | 20 | 20 | 0 | 20 | | 20 | 20 | 20 | 20 | ≥220 | 11
26 | 20 | 0 | | 20 | 20 | 20 | 20 | 20 | 0 | 20 | | 20 | 20 | 20 | 20 | ≥220 | 11
27 | 20 | 0 | | 20 | 20 | 20 | 20 | 20 | 0 | 20 | | 20 | 20 | X | 20 | ≥200 | 10
28 | 20 | 0 | | 20 | 20 | 20 | 20 | 20 | 0 | 20 | | 20 | 20 | | 20 | ≥200 | 10
Necropsy | 20 | 0 | 20 | 20 | 20 | 20 | 20 | 20 | 0 | 20 | 20 | 20 | 20 | 20 | 20 | ≥260 | 13

X=animal died

a No papillomas occurred in the vehicle control, 0.75, or 1.5 mg/kg groups. In the 3 mg/kg group, animal 226 had a single papilloma first observed at necropsy; animal 229 had a single papilloma observed at week 28 and at necropsy, and animal 232 had a single papilloma observed only at week 23. The maximum number of papillomas reported in the 6 and 12 mg/kg groups was 20, although some mice in these groups had more than 20 papillomas. Animal 268 in the 12 mg/kg group died between week 28 and scheduled necropsy.