# NATIONAL TOXICOLOGY PROGRAM BOARD OF SCIENTIFIC COUNSELORS TECHNICAL REPORTS REVIEW SUBCOMMITTEE

The members of the Technical Reports Review Subcommittee who evaluated the draft NTP Technical Report on acesulfame potassium on May 22, 2003, are listed below. Subcommittee members serve as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, subcommittee members have five major responsibilities in reviewing the NTP studies:

- to ascertain that all relevant literature data have been adequately cited and interpreted,
- to determine if the design and conditions of the NTP studies were appropriate,
- to ensure that the Technical Report presents the experimental results and conclusions fully and clearly,
- to judge the significance of the experimental results by scientific criteria, and
- to assess the evaluation of the evidence of carcinogenic activity and other observed toxic responses.

- Mary Anna Thrall, D.V.M., Chairperson
  Department of Pathology
  College of Veterinary Medicine and Biomedical Sciences
  Colorado State University
  Fort Collins, CO
- Kim Boekelheide, M.D., Ph.D.
  Division of Biology and Medicine
  Department of Pathology and Laboratory Medicine
  Brown University
  Providence, RI
- Hillary M. Carpenter, III, Ph.D.
  Minnesota Department of Health
  St. Paul, MN
- Samuel M. Cohen, M.D., Ph.D.^*^
  Department of Pathology and Microbiology
  University of Nebraska Medical Center
  Omaha, NE
- Michael R. Elwell, D.V.M., Ph.D., Principal Reviewer
  Pfizer Global Research and Development
  Groton, CT
- Walter W. Piegorsch, Ph.D., Principal Reviewer
  Department of Statistics
  University of South Carolina
  Columbia, SC
- Stephen M. Roberts, Ph.D.
  Department of Physiological Sciences
  College of Veterinary Medicine
  University of Florida
  Gainesville, FL
- Richard D. Storer, M.P.H., Ph.D., Principal Reviewer
  Department of Genetic and Cellular Toxicology
  Merck Research Laboratories
  West Point, PA
- Mary Vore, Ph.D.
  Graduate Center for Toxicology
  University of Kentucky
  Lexington, KY
- Cheryl Lyn Walker, Ph.D.
  M.D. Anderson Cancer Center
  The University of Texas
  Smithville, TX

* Did not attend