# DISCUSSION AND CONCLUSIONS

Acesulfame potassium is an oxathiazinone dioxide intense sweetener developed by Hoechst and currently marketed under the commercial names Sweet One and Sunett. Acesulfame is rapidly absorbed after oral administration but undergoes no biotransformation and is rapidly eliminated in the urine as parent compound within 24 hours of ingestion (Volz et al., 1991). The carcinogenicity of acesulfame potassium has been evaluated in Wistar rats (Sinkeldam et al., 1991a) and Swiss mice (Beems et al., 1991). Both studies yielded negative results.

In the current studies, acesulfame potassium was evaluated in Tg.AC hemizygous and p53 haploinsufficent mice as a presumptive negative control to provide additional information regarding the use of these mice as alternative models for evaluation of carcinogenic activity. Specifically, these studies were designed to examine whether extending the study duration to 39 weeks to increase the opportunity for a positive response would lead to a significant increase in background tumors in control mice and to evaluate the forestomach in Tg.AC hemizygous mice as a possible target organ for papilloma induction for studies that use the oral route of administration.

No prechronic studies of acesulfame potassium were conducted by the NTP. Prechronic studies in rats conducted by Hoechst and the 80-week study in Swiss mice were used as a basis for dose selection in the current studies. During the 80-week mouse study, mean body weights of males and females that received 30,000 ppm acesulfame potassium in the diet were reduced, and mean liver weights of all exposed groups were significantly lower than those of the controls at the end of the study (Beems et al., 1991). Based on these results, doses of 0.3%, 1%, and 3% (3,000, 10,000, or 30,000 ppm) administered in feed were selected for the current 9-month studies.

In the current studies, these exposure concentrations appeared to be well tolerated by both strains of mice. Survival and mean body weights of males and females were unaffected by exposure, and there were no exposure concentration-related clinical findings or other indications of toxicity. Therefore, it is possible that higher dietary concentrations may have been tolerated.

Cutaneous squamous cell papillomas occurred on the lip, prepuce, and pinna of exposed male Tg.AC hemizygous mice. Small epidermal squamous cell papillomas begin to occur at sites of chronic grooming (e.g., ears, nose, lips, paws, and the ano-urogenital areas) when the mice reach 20 to 26 weeks of age (Tenant et al., 2001); however, the incidence is low (0% to 2%) in Tg.AC hemizygous mice and higher (up to 17%) in Tg.AC homozygous mice. The incidences in 34-week old control Tg.AC hemizygous mice was 3.7% in males and 3.8% in female (Mahler et al., 1998). While historical control rates for 45-week old Tg.AC mice used in 39-week studies were not identified, they are expected to be higher; squamous cell papillomas occurred in 20% of the control males and females in the current study. Because spontaneous skin papillomas are relatively common in aging Tg.AC mice, especially in areas of grooming and/or licking, and the increase in the incidence of squamous cell papilloma occurred only in the 1% group of males with no increase in multiplicity, the slight increase was not considered related to acesulfame potassium.

The incidence of odontogenic tumors was slightly increased in Tg.AC hemizygous females that received 1% acesulfame potassium. The incidences of odontogenic tumors were not increased in any group of males or in females that received 3%. Therefore, the increase was not considered exposure related. Odontogenic tumors have occurred at incidences of 18% to 27% in control Tg.AC mice in 6-month studies (Tennant et al., 2001).

Pritchard et al. (2003) reported as part of a global review of transgenic cancer model findings that the Tg.AC model had an overall accuracy of 74% in correctly predicting chemicals that are either listed by the International Agency for Research on Cancer, and/or the NTP in their respective listings of chemicals as known or suspected human carcinogens. Chemicals studied in the Tg.AC line and found negative also contributed to this accuracy score if the chemicals were considered to be noncarcinogens by virtue of not appearing in these listings. The vast majority of the Tg.AC studies examined by Pritchard et al. (2003) used the dermal route of exposure and skin papillomas as the reporter phenotype. The pattern of incorrect assignments included both “false positives” and “false negatives.” This level of accuracy is not significantly different from that achieved by the p53 haploinsufficient model or the Hras2 model in the Pritchard analysis. However, based on discussions at a recent NTP workshop (NTP, 2003) there is a lack of acceptance within the scientific/regulatory community that a positive result in the Tg.AC model represents a true cancer response. Therefore, the confidence in this model to identify carcinogens appears to be less than that in either the p53 haploinsufficient or Hras2 model.

There were no increases in the incidences of neoplasms in p53 haploinsufficient mice exposed to acesulfame potassium. There was a significant increase in the frequency of micronucleated normochromatic erythrocytes at the end of the exposure period in males that received 1% or 3% acesulfame potassium. Although the increase was statistically significant, the actual magnitude of the increase was only 1 or 1.2 micronuclei/1,000 cells. Moreover, no increase was observed in females. In a review of the results of NTP prechronic and chronic studies in which peripheral blood micronuclei were evaluated in B6C3F_1_ mice, Witt et al. (2000) considered a small increase in magnitude of response and/or a response in only one sex as a weak response and concluded that weak responses did not correlate with rodent carcinogenicity and were of uncertain biological significance. By contrast, a strong response (determined by magnitude of increase in frequency and response in males and females) strongly correlated with rodent carcinogenicity. The small increase in magnitude of response observed in male p53 haploinsufficient mice in the current study and the lack of response in females would classify this as a weak response and, therefore, is of uncertain biological significance.

In a study that examined micronuclei formation after acute exposure, Jung et al. (1991) administered 0, 450, 1,500, or 4,500 mg acesulfame potassium/kg body weight in distilled water by gavage to groups of 10 NMRI mice. Mice were dosed twice during a 24-hour period and then sacrificed 6 hours after the second dose; bone marrow was collected, and smears were prepared. Examination of 2,000 polychromatic erythrocytes per mouse revealed no increase in the frequency of micronuclei. The positive control, cyclophosphamide, produced a strong response.

The review and analysis of the performance of the p53 haploinsufficient model by Pritchard et al. (2003) included data and conclusions as reported by the authors of studies published up to mid-2002. They compared the responses in the p53 haploinsufficient mouse model to a group of 12 known human carcinogens, 19 suspected human carcinogens, and 28 probable human noncarcinogens. In this analysis, the p53 haploinsufficient model had an overall accuracy of 81%. The high accuracy was in large part due to the lack of “false positives” (positive outcomes for probable human noncarcinogens). They concluded that the p53 haploinsufficient model correctly identified 10 of 12 (83%) known human carcinogens, 11 of 19 (58%) suspected carcinogens, and was correctly negative for 27 of 28 (96%) putative noncarcinogens under the conditions of these short-term cancer bioassays. Thus, two known and eight suspected human carcinogens were not detected by the p53 haploinsufficient model. These authors also acknowledged that a number of procedural decisions may have increased the apparent accuracy scores for the mouse models studied. These included such things as accepting a single positive study in a given model as representing a positive response even if other studies of the same chemical were negative or gave equivocal findings in that model. Clearly, the strength of the p53 haploinsufficient model is in its specificity for correctly identifying known or suspected carcinogens, but its sensitivity to detect carcinogens is a weakness. Because this model either did not identify or only equivocally identified a significant number of known or suspected human carcinogens, negative findings with this model as shown in the current study are of uncertain value.

In summary, there was no evidence of a positive response for papilloma formation in the forestomach or for tumors at other sites in male or female Tg.AC hemizygous mice administered acesulfame potassium in the diet at concentrations up to 3% for 9 months.

## Conclusions

Under the conditions of this 9-month feed study, there was no evidence of carcinogenic activity^*^ of acesulfame potassium in male or female p53 haploinsufficient mice exposed to 0.3%, 1%, or 3%.

* Explanation of Levels of Evidence of Carcinogenic Activity is on page 8. A summary of the Technical Report Review Subcommittee comments and public discussion on this technical report appears on page 9.