# RESULTS

## 9-Month Study in Tg.AC Hemizygous Mice

### Positive Control Tg.AC Hemizygous Mice

12-O-Tetradecanoylphorbol-13-acetate (TPA) (1.25 µg) was dermally administered to groups of 15 males and 15 females three times weekly for up to 16 weeks. All males and 87% of the females developed more than 20 papillomas each by week 16 (data not shown). This is consistent with historical rates found in other studies (Tennant et al., 2001).

### Survival

Estimates of 9-month survival probabilities for male and female mice are shown in Table 2 and in the Kaplan-Meier survival curves (Figure 1). Survival of all exposed groups was similar to that of the control groups.

TABLE 2 Survival of Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium

| 0% | 0.3% | 1% | 3%
Male
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 2 | 4 | 2 | 1
Animals surviving to study termination | 13 | 11 | 13 | 14
Percent probability of survival at end of study^a^ | 87 | 73 | 87 | 93
Mean survival (days)^b^ | 258 | 249 | 268 | 267
Survival analysis^c^ | P=0.430N | P=0.638 | P=1.000N | P=0.951N
Female
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 1 | 0 | 2 | 2
Natural deaths | 2 | 3 | 1 | 1
Animals surviving to study termination | 12 | 12 | 12 | 12
Percent probability of survival at end of study | 80 | 80 | 80 | 80
Mean survival (days) | 266 | 255 | 267 | 262
Survival analysis | P=1.000 | P=1.000 | P=1.000 | P=1.000

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice).

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns. A negative trend or lower mortality in an exposed group is indicated by N.

FIGURE 1 Kaplan-Meier Survival Curves for Male and Female Tg.AC Hemizygous Mice Exposed to Acesulfame Potassium in Feed for 9 Months

### Body Weights, Feed and Compound Consumption, and Clinical Findings

Mean body weights of all exposed groups of males were similar to those of the control group throughout the study; mean body weights of all exposed groups of females were less than the control group after week 35 (Tables 3 and 4; Figure 2). Because the body weights of females did not decrease with increasing exposure concentration, the body weight effect was not considered to be treatment related. Feed consumption by the exposed groups was similar to that by the control groups (Tables G1 and G2). Dietary concentrations of 0.3%, 1%, and 3% acesulfame potassium delivered average daily doses 420, 1,400, or 4,500 mg acesulfame potassium/kg body weight to males and 520, 1,700, or 5,400 mg/kg to females. Clinical findings included jaw masses, malocclusions, and cutaneous papillomas, but these findings did not occur in a pattern that would suggest a relationship to acesulfame potassium exposure.

TABLE 3 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium

Weeks on Study | 0% | | 0.3% | | | 1% | | | 3%
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 21.2 | 15 | 21.2 | 100 | 15 | 21.3 | 101 | 15 | 21.3 | 101 | 15
2 | 22.6 | 15 | 22.0 | 97 | 15 | 22.7 | 100 | 15 | 22.5 | 100 | 15
3 | 23.3 | 15 | 23.6 | 101 | 15 | 23.7 | 102 | 15 | 23.7 | 102 | 15
4 | 24.2 | 15 | 24.9 | 103 | 15 | 24.8 | 103 | 15 | 24.7 | 102 | 15
5 | 24.9 | 15 | 25.7 | 103 | 15 | 25.3 | 102 | 15 | 25.1 | 101 | 15
6 | 25.5 | 15 | 26.3 | 103 | 15 | 26.4 | 104 | 15 | 25.6 | 100 | 15
7 | 26.3 | 15 | 26.5 | 101 | 15 | 26.8 | 102 | 15 | 26.9 | 102 | 15
8 | 25.9 | 15 | 27.2 | 105 | 15 | 27.5 | 106 | 15 | 27.4 | 106 | 15
9 | 27.4 | 15 | 27.6 | 101 | 15 | 27.7 | 101 | 15 | 27.7 | 101 | 15
10 | 27.5 | 15 | 27.6 | 100 | 15 | 28.0 | 102 | 15 | 27.7 | 101 | 15
11 | 27.0 | 15 | 28.2 | 104 | 14 | 28.4 | 105 | 15 | 27.6 | 102 | 15
12 | 28.0 | 15 | 29.0 | 104 | 14 | 29.2 | 104 | 15 | 28.8 | 103 | 15
13 | 28.2 | 15 | 28.9 | 103 | 14 | 29.4 | 104 | 15 | 29.0 | 103 | 15
14 | 28.8 | 15 | 29.8 | 104 | 14 | 29.7 | 103 | 15 | 29.3 | 102 | 15
15 | 29.3 | 15 | 29.9 | 102 | 14 | 30.0 | 102 | 15 | 29.9 | 102 | 15
16 | 29.5 | 15 | 29.8 | 101 | 14 | 30.3 | 103 | 15 | 30.1 | 102 | 15
17 | 29.6 | 15 | 29.8 | 101 | 14 | 30.5 | 103 | 15 | 30.4 | 103 | 15
18 | 29.2 | 15 | 30.5 | 105 | 14 | 30.7 | 105 | 15 | 30.6 | 105 | 15
19 | 29.4 | 15 | 30.4 | 103 | 14 | 30.5 | 104 | 15 | 30.7 | 104 | 15
20 | 29.5 | 15 | 29.7 | 101 | 14 | 30.5 | 103 | 15 | 30.6 | 104 | 15
21 | 29.5 | 15 | 30.1 | 102 | 14 | 31.2 | 106 | 15 | 31.1 | 105 | 15
22 | 29.5 | 15 | 30.9 | 105 | 14 | 31.6 | 107 | 15 | 31.5 | 107 | 15
23 | 30.4 | 14 | 32.0 | 105 | 13 | 31.4 | 103 | 15 | 31.8 | 105 | 15
24 | 31.5 | 13 | 31.1 | 99 | 13 | 31.8 | 101 | 15 | 31.9 | 101 | 15
25 | 31.6 | 13 | 32.2 | 102 | 13 | 32.2 | 102 | 15 | 32.1 | 102 | 15
26 | 31.8 | 13 | 32.2 | 101 | 13 | 32.2 | 101 | 15 | 32.8 | 103 | 14
27 | 32.0 | 13 | 32.2 | 101 | 13 | 32.2 | 101 | 15 | 32.3 | 101 | 14
28 | 32.0 | 13 | 32.6 | 102 | 13 | 32.9 | 103 | 15 | 32.8 | 103 | 14
29 | 32.4 | 13 | 32.8 | 101 | 13 | 33.1 | 102 | 14 | 32.5 | 100 | 14
30 | 32.5 | 13 | 33.3 | 103 | 13 | 33.4 | 103 | 14 | 33.0 | 102 | 14
31 | 32.5 | 13 | 33.3 | 103 | 13 | 33.1 | 102 | 14 | 33.0 | 102 | 14
32 | 32.5 | 13 | 33.2 | 102 | 13 | 33.6 | 103 | 14 | 33.7 | 104 | 14
33 | 32.3 | 13 | 32.5 | 101 | 13 | 33.2 | 103 | 14 | 33.0 | 102 | 14
34 | 32.2 | 13 | 32.7 | 102 | 13 | 33.4 | 104 | 14 | 33.4 | 104 | 14
35 | 32.6 | 13 | 32.8 | 101 | 12 | 33.4 | 103 | 14 | 33.4 | 103 | 14
36 | 33.0 | 13 | 32.7 | 99 | 12 | 33.7 | 102 | 14 | 33.4 | 101 | 14
37 | 32.7 | 13 | 33.5 | 102 | 12 | 34.1 | 104 | 14 | 33.3 | 102 | 14
38 | 32.9 | 13 | 33.5 | 102 | 12 | 33.4 | 102 | 14 | 33.2 | 101 | 14
39 | 33.2 | 13 | 32.9 | 99 | 12 | 34.4 | 104 | 13 | 33.9 | 102 | 14
40 | 33.2 | 13 | 33.6 | 101 | 11 | 34.1 | 103 | 13 | 33.5 | 101 | 14
Mean for weeks
1–13 | 25.5 | | 26.1 | 102 | | 26.2 | 103 | | 26.0 | 102
14–40 | 31.3 | | 31.9 | 102 | | 32.2 | 103 | | 32.1 | 103

TABLE 4 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium

Weeks on Study | 0% | | 0.3% | | | 1% | | | 3%
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 17.9 | 15 | 17.8 | 99 | 15 | 18.0 | 101 | 15 | 17.8 | 99 | 15
2 | 17.5 | 15 | 18.2 | 104 | 15 | 18.2 | 104 | 15 | 18.1 | 103 | 15
3 | 17.8 | 15 | 18.5 | 104 | 15 | 18.3 | 103 | 15 | 18.3 | 103 | 15
4 | 19.6 | 15 | 19.5 | 100 | 15 | 19.3 | 99 | 15 | 19.7 | 101 | 15
5 | 19.7 | 15 | 19.6 | 100 | 15 | 19.8 | 101 | 15 | 19.7 | 100 | 15
6 | 19.7 | 15 | 19.5 | 99 | 15 | 19.6 | 100 | 15 | 19.4 | 99 | 15
7 | 20.3 | 15 | 20.1 | 99 | 15 | 20.5 | 101 | 15 | 20.6 | 102 | 15
8 | 20.7 | 15 | 20.8 | 101 | 15 | 21.2 | 102 | 15 | 20.8 | 101 | 15
9 | 21.3 | 15 | 21.6 | 101 | 15 | 21.5 | 101 | 15 | 21.2 | 100 | 15
10 | 21.7 | 15 | 21.6 | 100 | 15 | 21.9 | 101 | 15 | 21.4 | 99 | 15
11 | 22.1 | 15 | 21.9 | 99 | 15 | 22.2 | 101 | 15 | 22.3 | 101 | 15
12 | 22.5 | 15 | 22.1 | 98 | 14 | 22.6 | 100 | 15 | 21.9 | 97 | 15
13 | 22.2 | 15 | 22.4 | 101 | 14 | 22.7 | 102 | 15 | 21.9 | 99 | 15
14 | 22.3 | 15 | 22.7 | 102 | 14 | 22.7 | 102 | 15 | 22.1 | 99 | 15
15 | 22.5 | 15 | 23.1 | 103 | 14 | 22.9 | 102 | 15 | 22.6 | 100 | 15
16 | 23.5 | 15 | 23.3 | 99 | 14 | 23.2 | 99 | 15 | 23.4 | 100 | 15
17 | 23.7 | 15 | 23.6 | 100 | 14 | 23.2 | 98 | 15 | 23.0 | 97 | 15
18 | 24.0 | 15 | 23.4 | 98 | 14 | 23.7 | 99 | 15 | 23.3 | 97 | 15
19 | 23.8 | 15 | 23.3 | 98 | 14 | 23.9 | 100 | 15 | 23.3 | 98 | 15
20 | 24.4 | 15 | 23.5 | 96 | 14 | 23.9 | 98 | 15 | 23.7 | 97 | 15
21 | 24.6 | 15 | 23.8 | 97 | 14 | 24.4 | 99 | 15 | 23.5 | 96 | 15
22 | 24.9 | 15 | 24.0 | 96 | 14 | 24.6 | 99 | 15 | 23.3 | 94 | 15
23 | 25.0 | 15 | 24.1 | 96 | 14 | 24.2 | 97 | 15 | 24.0 | 96 | 15
24 | 25.4 | 15 | 24.5 | 97 | 14 | 24.8 | 98 | 15 | 24.7 | 97 | 14
25 | 25.3 | 15 | 24.5 | 97 | 14 | 24.7 | 98 | 15 | 25.1 | 99 | 14
26 | 25.4 | 15 | 24.8 | 98 | 14 | 25.0 | 98 | 15 | 25.2 | 99 | 14
27 | 26.7 | 15 | 25.3 | 95 | 14 | 25.2 | 94 | 15 | 25.1 | 94 | 14
28 | 26.5 | 15 | 25.5 | 96 | 14 | 25.1 | 95 | 15 | 25.1 | 95 | 14
29 | 26.8 | 15 | 25.2 | 94 | 13 | 25.1 | 94 | 15 | 24.8 | 93 | 14
30 | 27.1 | 15 | 25.6 | 95 | 13 | 25.4 | 94 | 15 | 25.7 | 95 | 14
31 | 26.7 | 15 | 25.5 | 96 | 13 | 25.5 | 96 | 14 | 26.1 | 98 | 14
32 | 26.4 | 15 | 25.7 | 97 | 13 | 26.0 | 99 | 14 | 26.1 | 99 | 14
33 | 25.9 | 14 | 25.8 | 100 | 13 | 25.5 | 99 | 14 | 25.8 | 100 | 14
34 | 26.0 | 14 | 26.1 | 100 | 13 | 25.4 | 98 | 14 | 25.6 | 99 | 14
35 | 26.0 | 13 | 24.9 | 96 | 13 | 25.9 | 100 | 13 | 26.4 | 102 | 13
36 | 28.3 | 12 | 25.9 | 92 | 13 | 26.3 | 93 | 13 | 26.2 | 93 | 13
37 | 28.4 | 12 | 26.4 | 93 | 13 | 26.6 | 94 | 13 | 26.3 | 93 | 13
38 | 27.8 | 12 | 26.7 | 96 | 12 | 26.6 | 96 | 13 | 26.6 | 96 | 12
39 | 28.5 | 12 | 26.6 | 93 | 12 | 26.8 | 94 | 13 | 26.7 | 94 | 12
40 | 28.5 | 12 | 26.3 | 92 | 12 | 27.0 | 95 | 12 | 26.6 | 93 | 12
Mean for weeks
1–13 | 20.2 | | 20.3 | 100 | | 20.4 | 101 | | 20.2 | 100
14–40 | 25.7 | | 24.8 | 96 | | 24.9 | 97 | | 24.8 | 96

FIGURE 2 Growth Curves for Male and Female Tg.AC Hemizygous Mice Exposed to Acesulfame Potassium in Feed for 9 Months

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms of the jaw and skin. Summaries of the incidences of neoplasms and nonneoplastic lesions, individual animal tumor diagnoses, and statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group are presented in Appendix A for males and Appendix B for females.

Jaw: Gross observations at necropsy included jaw masses in females. The incidence of odontogenic tumor in 1% females was slightly increased (0%, 2/15; 0.3%, 0/15; 1%, 6/15; 3%, 3/15; Table B3); however, the increased incidence was considered due to biologic variability and not to acesulfame potassium exposure.

Skin: Gross observations at necropsy included skin masses (papillomas) at several locations, particularly the face, head, and genital region; most masses occurred on the lip. Based on the microscopic evaluation, there were no significant increases in the incidences of squamous cell papilloma at any specific site in males or females (Tables A1 and B1). However, when papillomas at all sites were combined, there was an increase in the incidence of squamous cell papilloma in 1% males (3/15, 4/15, 8/15, 5/15; Table A3). With the exception of one male in the 3% group and one female in the 1% group, each of which had two papillomas at different locations, all other animals had a single papilloma (Tables A2 and B2).

## 9-Month Study in p53 Haploinsufficient Mice

### Survival

Estimates of 9-month survival probabilities for male and female mice are shown in Table 5 and in the Kaplan-Meier survival curves (Figure 3). Survival of all exposed groups was similar to that of the control groups.

### Body Weights, Feed and Compound Consumption, and Clinical Findings

Mean body weights of 1% males were greater than those of the controls after week 26; however, this trend likely reflected biologic variability and sample size rather than a treatment effect (Table 6 and Figure 4). Mean body weights of 0.3% and 3% males and of all exposed groups of females were similar to those of the control groups (Table 7 and Figure 4). Feed consumption by the exposed groups was similar to that by the control groups (Tables G3 and G4). Dietary concentrations of 0.3%, 1%, and 3% acesulfame potassium delivered average daily doses of approximately 475, 1,500, or 4,700 mg/kg to males and 570, 1,800, or 5,700 mg/kg to females. There were no clinical findings related to acesulfame potassium exposure.

TABLE 5 Survival of p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium

| 0% | 0.3% | 1% | 3%
Male
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 1 | 0 | 0 | 1
Animals surviving to study termination | 14 | 15 | 15 | 14
Percent probability of survival at end of study^a^ | 93 | 100 | 100 | 93
Mean survival (days)^b^ | 268 | 274 | 274 | 271
Survival analysis^c^ | P=1.000 | P=1.000N | P=1.000N | P=1.000N
Female
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 1 | 0 | 1 | 0
Natural deaths | 0 | 1 | 0 | 1
Animals surviving to study termination | 14 | 14 | 14 | 14
Percent probability of survival at end of study | 93 | 93 | 93 | 93
Mean survival (days) | 267 | 268 | 264 | 272
Survival analysis | P=1.000N | P=1.000N | P=1.000 | P=1.000N

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice).

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns. A negative trend or lower mortality in an exposed group is indicated by N.

FIGURE 3 Kaplan-Meier Survival Curves for Male and Female p53 Haploinsufficient Mice Exposed to Acesulfame Potassium in Feed for 9 Months

TABLE 6 Mean Body Weights and Survival of Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium

Weeks on Study | 0% | | 0.3% | | | 1% | | | 3%
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 20.9 | 15 | 20.5 | 98 | 15 | 20.5 | 98 | 15 | 21.1 | 101 | 15
2 | 21.9 | 15 | 21.7 | 99 | 15 | 22.0 | 101 | 15 | 22.0 | 101 | 15
3 | 22.1 | 15 | 21.9 | 99 | 15 | 22.3 | 101 | 15 | 22.1 | 100 | 15
4 | 22.9 | 15 | 22.5 | 98 | 15 | 22.8 | 100 | 15 | 22.7 | 99 | 15
5 | 23.6 | 15 | 23.6 | 100 | 15 | 23.9 | 101 | 15 | 24.1 | 102 | 15
6 | 24.1 | 15 | 23.9 | 99 | 15 | 24.4 | 101 | 15 | 24.4 | 101 | 15
7 | 24.5 | 15 | 24.2 | 99 | 15 | 25.0 | 102 | 15 | 24.7 | 101 | 15
8 | 25.3 | 15 | 24.8 | 98 | 15 | 25.5 | 101 | 15 | 25.2 | 100 | 15
9 | 25.4 | 15 | 24.9 | 98 | 15 | 25.6 | 101 | 15 | 25.4 | 100 | 15
10 | 25.6 | 15 | 25.1 | 98 | 15 | 26.1 | 102 | 15 | 25.6 | 100 | 15
11 | 25.9 | 15 | 25.4 | 98 | 15 | 26.8 | 104 | 15 | 25.7 | 99 | 15
12 | 26.5 | 15 | 25.6 | 97 | 15 | 27.1 | 102 | 15 | 26.3 | 99 | 15
13 | 26.6 | 15 | 25.9 | 97 | 15 | 26.9 | 101 | 15 | 26.5 | 100 | 15
14 | 27.0 | 15 | 26.7 | 99 | 15 | 27.2 | 101 | 15 | 27.0 | 100 | 15
15 | 27.5 | 15 | 27.2 | 99 | 15 | 28.3 | 103 | 15 | 27.9 | 102 | 15
16 | 28.0 | 15 | 27.9 | 100 | 15 | 28.4 | 101 | 15 | 28.1 | 100 | 15
17 | 28.5 | 15 | 27.7 | 97 | 15 | 28.9 | 101 | 15 | 28.2 | 99 | 15
18 | 29.4 | 15 | 28.8 | 98 | 15 | 30.1 | 102 | 15 | 29.1 | 99 | 15
19 | 29.2 | 15 | 28.3 | 97 | 15 | 29.8 | 102 | 15 | 28.9 | 99 | 15
20 | 29.4 | 15 | 28.6 | 97 | 15 | 29.2 | 99 | 15 | 29.1 | 99 | 15
21 | 29.7 | 15 | 28.8 | 97 | 15 | 30.0 | 101 | 15 | 29.4 | 99 | 15
22 | 29.5 | 15 | 29.0 | 98 | 15 | 29.9 | 101 | 15 | 29.5 | 100 | 15
23 | 29.2 | 15 | 28.5 | 98 | 15 | 29.6 | 101 | 15 | 29.5 | 101 | 15
24 | 29.6 | 15 | 29.2 | 99 | 15 | 30.3 | 102 | 15 | 30.3 | 102 | 15
25 | 29.6 | 15 | 28.9 | 98 | 15 | 30.5 | 103 | 15 | 29.9 | 101 | 15
26 | 29.6 | 15 | 29.4 | 99 | 15 | 30.5 | 103 | 15 | 30.3 | 102 | 15
27 | 29.0 | 15 | 29.0 | 100 | 15 | 30.9 | 107 | 15 | 30.4 | 105 | 15
28 | 29.3 | 15 | 29.8 | 102 | 15 | 31.9 | 109 | 15 | 31.0 | 106 | 15
29 | 30.3 | 14 | 30.2 | 100 | 15 | 32.1 | 106 | 15 | 30.5 | 101 | 15
30 | 30.4 | 14 | 30.5 | 100 | 15 | 32.4 | 107 | 15 | 31.1 | 102 | 15
31 | 30.1 | 14 | 30.0 | 100 | 15 | 32.2 | 107 | 15 | 31.1 | 103 | 15
32 | 29.9 | 14 | 29.3 | 98 | 15 | 32.0 | 107 | 15 | 30.9 | 103 | 15
33 | 29.6 | 14 | 29.5 | 100 | 15 | 31.1 | 105 | 15 | 30.4 | 103 | 14
34 | 29.2 | 14 | 29.2 | 100 | 15 | 31.3 | 107 | 15 | 30.2 | 103 | 14
35 | 29.2 | 14 | 29.3 | 100 | 15 | 30.8 | 106 | 15 | 29.6 | 101 | 14
36 | 29.1 | 14 | 29.3 | 101 | 15 | 31.0 | 107 | 15 | 29.4 | 101 | 14
37 | 29.1 | 14 | 29.7 | 102 | 15 | 31.1 | 107 | 15 | 29.7 | 102 | 14
38 | 29.1 | 14 | 29.5 | 101 | 15 | 31.3 | 108 | 15 | 29.9 | 103 | 14
39 | 29.2 | 14 | 29.9 | 102 | 15 | 31.7 | 109 | 15 | 30.1 | 103 | 14
40 | 29.5 | 14 | 30.1 | 102 | 15 | 31.6 | 107 | 15 | 29.9 | 101 | 14
Mean for weeks
1–13 | 24.3 | | 23.8 | 98 | | 24.5 | 101 | | 24.3 | 100
14–40 | 29.2 | | 29.0 | 99 | | 30.5 | 104 | | 29.7 | 102

TABLE 7 Mean Body Weights and Survival of Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium

Weeks on Study | 0% | | 0.3% | | | 1% | | | 3%
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 16.4 | 15 | 17.0 | 104 | 15 | 17.0 | 104 | 15 | 16.4 | 100 | 15
2 | 18.5 | 15 | 17.9 | 97 | 15 | 18.4 | 100 | 15 | 17.8 | 96 | 15
3 | 18.4 | 15 | 18.7 | 102 | 15 | 19.2 | 104 | 15 | 18.5 | 101 | 15
4 | 19.6 | 15 | 19.5 | 100 | 15 | 19.9 | 102 | 15 | 19.1 | 97 | 15
5 | 20.2 | 15 | 20.7 | 103 | 15 | 20.6 | 102 | 15 | 20.1 | 100 | 15
6 | 20.9 | 15 | 21.1 | 101 | 15 | 21.2 | 101 | 15 | 21.0 | 101 | 15
7 | 21.0 | 15 | 21.2 | 101 | 15 | 21.5 | 102 | 15 | 21.1 | 101 | 15
8 | 21.4 | 15 | 21.5 | 101 | 15 | 21.5 | 101 | 15 | 20.8 | 97 | 15
9 | 21.4 | 15 | 21.5 | 101 | 15 | 21.7 | 101 | 15 | 21.3 | 100 | 15
10 | 21.8 | 15 | 21.6 | 99 | 15 | 21.9 | 101 | 15 | 21.6 | 99 | 15
11 | 22.4 | 15 | 22.4 | 100 | 15 | 22.4 | 100 | 15 | 21.8 | 97 | 15
12 | 22.6 | 15 | 22.3 | 99 | 15 | 22.6 | 100 | 15 | 22.3 | 99 | 15
13 | 23.0 | 15 | 23.1 | 100 | 15 | 23.2 | 101 | 15 | 22.8 | 99 | 15
14 | 23.2 | 15 | 23.6 | 102 | 15 | 23.5 | 101 | 15 | 22.9 | 99 | 15
15 | 23.6 | 15 | 24.2 | 103 | 15 | 23.7 | 100 | 15 | 22.9 | 97 | 15
16 | 24.1 | 15 | 25.2 | 105 | 15 | 24.2 | 100 | 15 | 23.6 | 98 | 15
17 | 24.3 | 15 | 25.1 | 103 | 15 | 24.2 | 100 | 15 | 23.7 | 98 | 15
18 | 24.7 | 15 | 25.6 | 104 | 15 | 25.0 | 101 | 15 | 24.1 | 98 | 15
19 | 24.8 | 15 | 25.8 | 104 | 15 | 24.9 | 100 | 14 | 24.6 | 99 | 15
20 | 25.1 | 15 | 26.1 | 104 | 15 | 25.5 | 102 | 14 | 24.9 | 99 | 15
21 | 25.4 | 15 | 26.4 | 104 | 15 | 25.7 | 101 | 14 | 25.3 | 100 | 15
22 | 25.6 | 15 | 26.8 | 105 | 15 | 26.1 | 102 | 14 | 25.5 | 100 | 15
23 | 26.1 | 15 | 27.0 | 103 | 15 | 26.3 | 101 | 14 | 25.6 | 98 | 15
24 | 26.1 | 15 | 26.9 | 103 | 15 | 26.6 | 102 | 14 | 26.0 | 100 | 15
25 | 26.4 | 14 | 26.9 | 102 | 15 | 26.7 | 101 | 14 | 26.3 | 100 | 15
26 | 26.5 | 14 | 27.1 | 102 | 14 | 26.5 | 100 | 14 | 26.3 | 99 | 15
27 | 26.7 | 14 | 27.3 | 102 | 14 | 27.2 | 102 | 14 | 26.9 | 101 | 15
28 | 26.9 | 14 | 27.8 | 103 | 14 | 27.4 | 102 | 14 | 27.4 | 102 | 15
29 | 27.0 | 14 | 28.0 | 104 | 14 | 28.0 | 104 | 14 | 27.1 | 100 | 15
30 | 28.2 | 14 | 28.6 | 101 | 14 | 28.5 | 101 | 14 | 28.0 | 99 | 15
31 | 27.8 | 14 | 28.6 | 103 | 14 | 28.5 | 103 | 14 | 27.9 | 100 | 15
32 | 28.1 | 14 | 27.9 | 99 | 14 | 28.5 | 101 | 14 | 27.5 | 98 | 15
33 | 27.5 | 14 | 28.0 | 102 | 14 | 28.4 | 103 | 14 | 27.9 | 102 | 15
34 | 27.7 | 14 | 27.8 | 100 | 14 | 28.3 | 102 | 14 | 27.5 | 99 | 15
35 | 27.6 | 14 | 27.3 | 99 | 14 | 27.7 | 100 | 14 | 26.8 | 97 | 15
36 | 27.3 | 14 | 28.1 | 103 | 14 | 28.2 | 103 | 14 | 27.1 | 99 | 14
37 | 27.5 | 14 | 28.0 | 102 | 14 | 28.0 | 102 | 14 | 27.6 | 100 | 14
38 | 27.7 | 14 | 28.1 | 101 | 14 | 27.9 | 101 | 14 | 27.6 | 100 | 14
39 | 27.5 | 14 | 28.3 | 103 | 14 | 28.2 | 103 | 14 | 28.0 | 102 | 14
40 | 28.3 | 14 | 28.8 | 102 | 14 | 28.8 | 102 | 14 | 28.3 | 100 | 14
Mean for weeks
1–13 | 20.6 | | 20.7 | 100 | | 20.9 | 101 | | 20.4 | 99
14–40 | 26.4 | | 27.0 | 102 | | 26.8 | 102 | | 26.2 | 99

FIGURE 4 Growth Curves for Male and Female p53 Haploinsufficient Mice Exposed to Acesulfame Potassium in Feed for 9 Months

### Pathology and Statistical Analyses

There were no neoplasms or nonneoplastic lesions in p53 haploinsufficient mice that were attributed to exposure to acesulfame potassium. Summaries of the incidences of neoplasms and nonneoplastic lesions, individual animal tumor diagnoses, and statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group are presented in Appendix C for males and Appendix D for females.

## Genetic Toxicology

Acesulfame potassium did not increase the frequency of micronucleated normochromatic erythrocytes in peripheral blood of male or female Tg.AC hemizygous mice administered 0.3% to 3% of the chemical in feed for 9 months (Table E1). A similar study was conducted in p53 haploinsufficient mice, and in this study, a significant exposure-related increase in the frequency of micronucleated normochromatic erythrocytes was noted in males but not females; micronucleus frequencies in the 1% and 3% male groups were significantly elevated over the control group (Table E2). There was no significant alteration in the percentage of polychromatic erythrocytes among total erythrocytes in either Tg.AC hemizygous or p53 haploinsufficient mice.