# MATERIALS AND METHODS

## Procurement and Characterization of Acesulfame Potassium

Acesulfame potassium was obtained from Riedel-deHaen (St. Louis, MO) via Research Triangle Institute (RTI) (Research Triangle Park, NC) in one lot (8415-76-02 RTI), which was used in the 9-month studies. Identity and purity analyses were conducted by the analytical chemistry laboratory, RTI, and the study laboratory; the study laboratory (BioReliance Corporation, Rockville, MD) also conducted stability analyses (Appendix F). Reports on analyses performed in support of the acesulfame potassium studies are on file at the National Institute of Environmental Health Sciences.

Lot 8415-76-02 RTI, a white, odorless, crystalline powder, was identified as acesulfame potassium by infrared and proton nuclear magnetic resonance spectroscopy. All spectra were consistent with the structure of acesulfame potassium. The purity of lot 8415-76-02 RTI was determined using high-performance liquid chromatography (HPLC) and confirmed by the study laboratory using major peak comparisons versus a reference sample from the same lot (stored at −20° C); HPLC indicated one major peak and no impurities. The purity was found to be greater than 99%.

To ensure stability, the bulk chemical was stored at room temperature under a headspace of inert gas, protected from light, in polyethylene bags inside plastic pails. Stability of the bulk chemical was monitored during the study by the study laboratory using HPLC. No degradation of the bulk chemical was observed.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared once every two to four weeks by mixing acesulfame potassium with feed (Table F1). Homogeneity studies of the 0.1% and 5% acesulfame potassium formulations and stability studies of the 0.1% formulations were performed by the analytical chemistry laboratory with HPLC. Homogeneity studies of the 0.3% and 3% formulations were performed by the study laboratory using HPLC. Homogeneity was confirmed, and stability was confirmed for at least 35 days for dose formulations stored in amber glass bottles at −20° C, −5° C, and 25° C, and when exposed to light and air for 7 days.

Periodic analyses of the dose formulations of acesulfame potassium were conducted by the study laboratory using HPLC. During the 9-month studies, the dose formulations were analyzed five times; all 15 of the dose formulations analyzed were within 10% of the target concentrations (Table F2). Animal room samples of these dose formulations were also analyzed, and 12 of the 15 samples were within 10% of the target concentrations (Table F2).

## 9-Month Studies

### Study Design

Groups of 15 male and 15 female mice were fed diets containing 0%, 0.3%, 1%, or 3% (0, 3,000, 10,000, or 30,000 ppm) acesulfame potassium for 40 weeks.

### Source and Specification of Animals

Male and female FVB/N-TgN(v-Ha-ras)Led (Tg.AC) hemizygous and B6.129-Trp53^tm1Brd^ (N5) haploinsufficient mice were obtained from Taconic Farms, Inc. (Germantown, NY), for use in the 9-month studies. Tg.AC hemizygous mice were quarantined for 11 days and p53 haploinsufficient mice were quarantined for 13 days before the beginning of the studies. Five male and five female mice in the control and 3% groups were randomly selected for parasite evaluation and gross observation of disease. Tg.AC hemizygous mice were 5 to 6 weeks old and p53 haploinsufficient mice were 6 to 7 weeks old at the beginning of the studies. The health of the mice was monitored during the studies according to the protocols of the NTP Sentinel Animal Program; all results were negative.

### Animal Maintenance

Mice were housed individually. Feed and water were available ad libitum, and feed consumption was measured weekly. The feed was irradiated to reduce potential microbial contamination. Cages were changed weekly, and racks were changed and rotated every 2 weeks. Further details of animal maintenance are given in Table 1.

### Clinical Examinations and Pathology

All animals were observed twice daily. Clinical findings and body weights were recorded initially, weekly, and at the end of the studies.

Complete necropsies were performed on all mice, except the control positive mice treated with TPA. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Complete microscopic examinations were performed on the control and 3% groups; the lung was examined in all groups of male Tg.AC hemizygous mice. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. Upon completion of the laboratory pathologist’s histologic evaluation, the slides, paraffin blocks, and residual wet tissues were sent to the NTP Archives for inventory, slide/block match, and wet tissue audit. The slides, individual animal data records, and pathology tables were evaluated by an independent pathology laboratory where quality assessment (QA) was performed. The QA pathologist reviewed all neoplasms from all groups and all slides from all animals in the control and high dose groups in Tg.AC hemizygous and p53 haploinsufficient mice. Results were reviewed by the NTP Pathology Working Group (PWG) Chairperson and two NTP pathologists. Minimal discrepancies were identified and the final diagnoses represent a consensus of the three contractors and two NTP pathologists. Details of these review procedures have been described, in part, by Maronpot and Boorman (1982) and Boorman et al. (1985).

TABLE 1 Experimental Design and Materials and Methods in the 9-Month Feed Studies of Acesulfame Potassium

Tg.AC Hemizygous Mice | p53 Haploinsufficient Mice
Study Laboratory
BioReliance Corporation (Rockville, MD) | BioReliance Corporation (Rockville, MD)
Strain
FVB/N-TgN(v-Ha-ras)Led (Tg.AC) hemizygous | B6.129-Trp53^tm1Brd^ (N5) haploinsufficient
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
11 days | 13 days
Average Age When Studies Began
5 to 6 weeks | 6 to 7 weeks
Date of First Exposure
January 31, 2000 (males) | February 2, 2000 (males)
February 1, 2000 (females) | February 3, 2000 (females)
Duration of Exposure
40 weeks | 40 weeks
Date of Last Exposure
October 30–31, 2000 | November 1–2, 2000
Necropsy Dates
October 30–31, 2000 | November 1–2, 2000
Average Age at Necropsy
44 to 45 weeks | 45 to 46 weeks
Size of Study Groups
15 males and 15 females | 15 males and 15 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
1 | 1
Method of Animal Identification
Tail tattoo | Tail tattoo
Diet
Irradiated NTP-2000 open formula meal (Zeigler Brothers, Inc., Gardners, PA), available ad libitum | Same as Tg.AC hemizygous mouse study
Water
Tap water (Washington Suburban Sanitary Commission Potomac Plant) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum | Same as Tg.AC hemizygous mouse study
Cages
Polycarbonate cages (Lab Products, Inc., Seaford, DE), changed weekly | Same as Tg.AC hemizygous mouse study
Bedding
Irradiated Sani-Chips^®^ (P.J. Murphy Forest Produces, Montville, NJ), changed weekly | Same as Tg.AC hemizygous mouse study
Cage Filters
Remay 2016 (Snow Filtration, West Chester, OH), changed every 2 weeks | Same as Tg.AC hemizygous mouse study
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated every 2 weeks | Same as Tg.AC hemizygous mouse study
Animal Room Environment
Temperature: 72° ± 3° F | Temperature: 72° ± 3° F
Relative humidity: 50% ± 15% | Relative humidity: 50% ± 15%
Room fluorescent light: 12 hours/day | Room fluorescent light: 12 hours/day
Room air changes: 10/hour | Room air changes: 10/hour
Exposure Concentrations
0%, 0.3%, 1%, or 3% acesulfame potassium in feed, available ad libitum | 0%, 0.3%, 1%, or 3% acesulfame potassium in feed, available ad libitum
Type and Frequency of Observation
Observed twice daily; animals were weighed and clinical observations were recorded initially, weekly, and at the end of the studies. Feed consumption was recorded weekly. | Observed twice daily; animals were weighed and clinical observations were recorded initially, weekly, and at the end of the studies. Feed consumption was recorded weekly.
Method of Sacrifice
Carbon dioxide asphyxiation | Carbon dioxide asphyxiation
Necropsy
Necropsy was performed on all mice. | Necropsy was performed on all mice.
Histopathology
Complete histopathology was performed on all mice that died early and 0% and 3% mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eye, gallbladder, harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin, spleen, stomach (forestomach and glandular), testis (with epididymis and seminal vesicle), thymus, thyroid gland, tongue, trachea, urinary bladder, uterus, vagina, and Zymbal’s gland. In addition, the lung was examined in the remaining groups of males. | Complete histopathology was performed on all mice that died early and 0% and 3% mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eye, gallbladder, harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin, spleen, stomach (forestomach and glandular), testis (with epididymis and seminal vesicle), thymus, thyroid gland, tongue, trachea, urinary bladder, uterus, vagina, and Zymbal’s gland.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier (1958) and is presented in the form of graphs. Animals found dead of other than natural causes were censored from the survival analyses; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s (1972) method for testing two groups for equality and Tarone’s (1975) life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Tables A1, A4, B1, B4, C1, C4, D1, and D4 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Tables A3, B3, C3, and D3) and all nonneoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., harderian gland, intestine, mammary gland, and skin) before microscopic evaluation, or when neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Tables A3, B3, C3, and D3 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific lesion free animals that do not reach terminal sacrifice.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidences

The Poly-k test (Bailer and Portier, 1988; Portier and Bailer, 1989; Piegorsch and Bailer, 1997) was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal sacrifice; if the animal died prior to terminal sacrifice and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time (Bailer and Portier, 1988). Unless otherwise specified, a value of k=3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier (1988) following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344 rats and B6C3F_1_ mice (Portier et al., 1986). Bailer and Portier (1988) showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams (1993).

Tests of significance included pairwise comparisons of each exposed group with controls and a test for an overall exposure-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence, and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1–P with the letter N added (e.g., P=0.99 is presented as P=0.01N).

### Analysis of Continuous Variables

Body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett (1955) and Williams (1971, 1972). Average severity values were analyzed for significance with the Mann-Whitney U test (Hollander and Wolfe, 1973).

## Quality Assurance Methods

The 9-month studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations (21 CFR, Part 58). In addition, as records from the 9-month studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent quality assurance contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of acesulfame potassium was assessed by testing the ability of the chemical to induce increases in the frequency of micronucleated erythrocytes in mouse peripheral blood. The protocol for this study and the results are given in Appendix E.

The genetic toxicity studies have evolved from an earlier effort by the NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity (Miller and Miller, 1977) and the somatic mutation theory of cancer (Straus, 1981; Crawford, 1985). However, it should be noted that not all cancers arise through genotoxic mechanisms.

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites (Ashby and Tennant, 1991). A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens) (Tennant et al., 1987; Zeiger et al., 1990). Other tests, although less predictive of rodent carcinogenicity, can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

The predictivity for carcinogenicity of a positive response in acute in vivo bone marrow chromosome aberration or micronucleus tests appears to be less than that in the Salmonella test (Shelby et al., 1993; Shelby and Witt, 1995). However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity (Witt et al., 2000); negative results in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies. Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical. Most organic chemicals that are identified by the International Agency for Research on Cancer as human carcinogens, other than hormones, are genotoxic. The vast majority of these are detected by both the Salmonella assay and rodent bone marrow cytogenetics tests (Shelby, 1988; Shelby and Zeiger, 1990).