# APPENDIX G FEED AND COMPOUND CONSUMPTION IN THE 9-MONTH FEED STUDIES OF ACESULFAME POTASSIUM

TABLE G1 Feed and Compound Consumption by Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium

Week | 0% | | 0.3% | | | 1% | | | 3%
Week | Feed (g)^a^ | Body Weight (g) | Feed (g) | Body Weight (g) | Dose (mg/kg)^b^ | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) (g)
2 | 3.9 | 22.6 | 4.1 | 22.0 | 554 | 4.5 | 22.7 | 1,978 | 4.6 | 22.5 | 6,093
3 | 4.2 | 23.3 | 4.4 | 23.6 | 564 | 4.5 | 23.7 | 1,901 | 4.6 | 23.7 | 5,838
4 | 4.3 | 24.2 | 4.3 | 24.9 | 524 | 4.5 | 24.8 | 1,817 | 4.6 | 24.7 | 5,615
5 | 4.2 | 24.9 | 4.4 | 25.7 | 509 | 4.3 | 25.3 | 1,686 | 4.4 | 25.1 | 5,309
6 | 4.2 | 25.5 | 4.1 | 26.3 | 470 | 4.4 | 26.4 | 1,659 | 4.5 | 25.6 | 5,290
7 | 4.1 | 26.3 | 4.1 | 26.5 | 460 | 4.3 | 26.8 | 1,607 | 4.5 | 26.9 | 5,021
8 | 3.8 | 25.9 | 4.2 | 27.2 | 467 | 4.3 | 27.5 | 1,567 | 4.5 | 27.4 | 4,918
9 | 4.2 | 27.4 | 4.1 | 27.6 | 445 | 4.1 | 27.7 | 1,464 | 4.3 | 27.7 | 4,656
10 | 4.1 | 27.5 | 4.1 | 27.6 | 450 | 4.2 | 28.0 | 1,515 | 4.4 | 27.7 | 4,739
11 | 4.1 | 27.0 | 4.2 | 28.2 | 445 | 4.3 | 28.4 | 1,528 | 4.4 | 27.6 | 4,790
12 | 4.2 | 28.0 | 4.3 | 29.0 | 444 | 4.4 | 29.2 | 1,502 | 4.6 | 28.8 | 4,832
13 | 4.0 | 28.2 | 4.2 | 28.9 | 436 | 4.3 | 29.4 | 1,463 | 4.5 | 29.0 | 4,683
14 | 3.9 | 28.8 | 4.1 | 29.8 | 413 | 4.2 | 29.7 | 1,418 | 4.5 | 29.3 | 4,589
15 | 4.1 | 29.3 | 4.3 | 29.9 | 434 | 4.4 | 30.0 | 1,458 | 4.6 | 29.9 | 4,575
16 | 4.0 | 29.5 | 4.0 | 29.8 | 406 | 4.2 | 30.3 | 1,402 | 4.5 | 30.1 | 4,485
17 | 4.2 | 29.6 | 4.2 | 29.8 | 420 | 4.4 | 30.5 | 1,454 | 4.7 | 30.4 | 4,669
18 | 4.1 | 29.2 | 4.4 | 30.5 | 429 | 4.4 | 30.7 | 1,440 | 4.5 | 30.6 | 4,399
19 | 4.2 | 29.4 | 4.0 | 30.4 | 396 | 4.1 | 30.5 | 1,331 | 4.5 | 30.7 | 4,399
20 | 3.9 | 29.5 | 4.0 | 29.7 | 409 | 4.2 | 30.5 | 1,391 | 4.4 | 30.6 | 4,342
21 | 4.0 | 29.5 | 4.2 | 30.1 | 417 | 4.3 | 31.2 | 1,367 | 4.4 | 31.1 | 4,232
22 | 3.8 | 29.5 | 4.1 | 30.9 | 393 | 4.3 | 31.6 | 1,359 | 4.6 | 31.5 | 4,379
23 | 4.1 | 30.4 | 4.1 | 32.0 | 387 | 4.1 | 31.4 | 1,298 | 4.4 | 31.8 | 4,130
24 | 4.1 | 31.5 | 3.9 | 31.1 | 374 | 4.0 | 31.8 | 1,242 | 4.4 | 31.9 | 4,156
25 | 4.0 | 31.6 | 4.4 | 32.2 | 408 | 4.2 | 32.2 | 1,299 | 4.4 | 32.1 | 4,073
26 | 4.0 | 31.8 | 4.2 | 32.2 | 393 | 4.1 | 32.2 | 1,264 | 4.5 | 32.8 | 4,109
27 | 4.0 | 32.0 | 4.1 | 32.2 | 386 | 4.2 | 32.2 | 1,318 | 4.4 | 32.3 | 4,065
28 | 3.8 | 32.0 | 4.2 | 32.6 | 386 | 4.2 | 32.9 | 1,276 | 4.4 | 32.8 | 4,037
29 | 4.3 | 32.4 | 4.3 | 32.8 | 394 | 4.2 | 33.1 | 1,280 | 4.3 | 32.5 | 3,977
30 | 3.9 | 32.5 | 4.2 | 33.3 | 378 | 4.1 | 33.4 | 1,231 | 4.3 | 33.0 | 3,948
31 | 4.1 | 32.5 | 4.2 | 33.3 | 377 | 4.2 | 33.1 | 1,266 | 4.2 | 33.0 | 3,778
32 | 4.1 | 32.5 | 4.2 | 33.2 | 379 | 4.3 | 33.6 | 1,287 | 4.7 | 33.7 | 4,187
33 | 4.1 | 32.3 | 4.1 | 32.5 | 379 | 4.2 | 33.2 | 1,280 | 4.3 | 33.0 | 3,888
34 | 4.1 | 32.2 | 4.4 | 32.7 | 402 | 4.3 | 33.4 | 1,281 | 4.4 | 33.4 | 3,935
35 | 4.3 | 32.6 | 4.2 | 32.8 | 383 | 4.5 | 33.4 | 1,346 | 4.3 | 33.4 | 3,818
36 | 4.3 | 33.0 | 4.3 | 32.7 | 390 | 4.5 | 33.7 | 1,325 | 4.5 | 33.4 | 4,071
37 | 4.4 | 32.7 | 4.3 | 33.5 | 387 | 4.6 | 34.1 | 1,344 | 4.6 | 33.3 | 4,171
38 | 4.3 | 32.9 | 4.6 | 33.5 | 412 | 4.4 | 33.4 | 1,318 | 4.6 | 33.2 | 4,162
39 | 4.2 | 33.2 | 4.0 | 32.9 | 361 | 4.4 | 34.4 | 1,275 | 4.6 | 33.9 | 4,070
40 | 4.2 | 33.2 | 4.5 | 33.6 | 400 | 4.2 | 34.1 | 1,245 | 4.5 | 33.5 | 4,059
Mean for weeks
1–13 | 4.1 | 25.9 | 4.2 | 26.5 | 481 | 4.3 | 26.7 | 1,641 | 4.5 | 26.4 | 5,149
14–40 | 4.1 | 31.3 | 4.2 | 31.8 | 396 | 4.3 | 32.2 | 1,326 | 4.5 | 32.1 | 4,174

a Grams of feed consumed per animal per day

b Milligrams of acesulfame potassium consumed per kilogram body weight per day

TABLE G2 Feed and Compound Consumption by Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium

Week | 0% | | 0.3% | | | 1% | | | 3%
Week | Feed (g)^a^ | Body Weight (g) | Feed (g) | Body Weight (g) | Dose (mg/kg)^b^ | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg)
2 | 3.6 | 17.5 | 4.3 | 18.2 | 710 | 3.9 | 18.2 | 2,160 | 4.5 | 18.1 | 7,467
3 | 4.3 | 17.8 | 4.1 | 18.5 | 660 | 4.3 | 18.3 | 2,339 | 4.0 | 18.3 | 6,630
4 | 4.5 | 19.6 | 4.1 | 19.5 | 625 | 4.1 | 19.3 | 2,106 | 4.1 | 19.7 | 6,299
5 | 4.3 | 19.7 | 3.8 | 19.6 | 582 | 3.8 | 19.8 | 1,944 | 3.9 | 19.7 | 5,992
6 | 4.0 | 19.7 | 4.1 | 19.5 | 626 | 3.8 | 19.6 | 1,948 | 4.1 | 19.4 | 6,303
7 | 3.9 | 20.3 | 3.9 | 20.1 | 588 | 4.2 | 20.5 | 2,029 | 4.1 | 20.6 | 5,926
8 | 4.0 | 20.7 | 4.1 | 20.8 | 592 | 4.0 | 21.2 | 1,902 | 4.0 | 20.8 | 5,771
9 | 3.9 | 21.3 | 4.0 | 21.6 | 559 | 4.0 | 21.5 | 1,875 | 4.0 | 21.2 | 5,672
10 | 4.0 | 21.7 | 3.9 | 21.6 | 548 | 4.1 | 21.9 | 1,880 | 4.2 | 21.4 | 5,897
11 | 4.2 | 22.1 | 4.0 | 21.9 | 546 | 4.4 | 22.2 | 1,960 | 4.4 | 22.3 | 5,953
12 | 4.2 | 22.5 | 4.2 | 22.1 | 573 | 4.3 | 22.6 | 1,892 | 4.2 | 21.9 | 5,801
13 | 4.1 | 22.2 | 4.0 | 22.4 | 538 | 3.9 | 22.7 | 1,737 | 4.2 | 21.9 | 5,770
14 | 3.8 | 22.3 | 4.0 | 22.7 | 533 | 3.9 | 22.7 | 1,719 | 4.0 | 22.1 | 5,411
15 | 4.3 | 22.5 | 4.0 | 23.1 | 514 | 4.1 | 22.9 | 1,785 | 3.9 | 22.6 | 5,230
16 | 4.2 | 23.5 | 4.0 | 23.3 | 512 | 4.0 | 23.2 | 1,705 | 4.2 | 23.4 | 5,448
17 | 4.0 | 23.7 | 4.2 | 23.6 | 528 | 4.2 | 23.2 | 1,828 | 4.1 | 23.0 | 5,316
18 | 4.1 | 24.0 | 3.8 | 23.4 | 491 | 4.1 | 23.7 | 1,738 | 4.2 | 23.3 | 5,408
19 | 4.0 | 23.8 | 3.9 | 23.3 | 500 | 3.9 | 23.9 | 1,615 | 4.1 | 23.3 | 5,249
20 | 4.3 | 24.4 | 4.0 | 23.5 | 507 | 4.2 | 23.9 | 1,760 | 4.3 | 23.7 | 5,447
21 | 4.1 | 24.6 | 4.0 | 23.8 | 498 | 4.3 | 24.4 | 1,781 | 3.7 | 23.5 | 4,754
22 | 4.0 | 24.9 | 3.9 | 24.0 | 488 | 4.0 | 24.6 | 1,628 | 3.9 | 23.3 | 5,026
23 | 4.3 | 25.0 | 3.8 | 24.1 | 478 | 3.7 | 24.2 | 1,544 | 4.5 | 24.0 | 5,614
24 | 4.1 | 25.4 | 4.0 | 24.5 | 491 | 4.1 | 24.8 | 1,641 | 4.1 | 24.7 | 4,996
25 | 3.8 | 25.3 | 4.0 | 24.5 | 487 | 3.8 | 24.7 | 1,527 | 4.0 | 25.1 | 4,827
26 | 4.1 | 25.4 | 4.0 | 24.8 | 488 | 4.2 | 25.0 | 1,668 | 4.2 | 25.2 | 4,973
27 | 4.3 | 26.7 | 4.2 | 25.3 | 499 | 3.9 | 25.2 | 1,545 | 4.0 | 25.1 | 4,840
28 | 4.1 | 26.5 | 3.8 | 25.5 | 448 | 3.8 | 25.1 | 1,525 | 4.1 | 25.1 | 4,893
29 | 3.9 | 26.8 | 3.9 | 25.2 | 467 | 4.0 | 25.1 | 1,597 | 3.9 | 24.8 | 4,672
30 | 3.8 | 27.1 | 4.0 | 25.6 | 465 | 3.8 | 25.4 | 1,483 | 4.1 | 25.7 | 4,758
31 | 3.9 | 26.7 | 4.0 | 25.5 | 465 | 3.9 | 25.5 | 1,536 | 4.1 | 26.1 | 4,755
32 | 4.0 | 26.4 | 4.1 | 25.7 | 477 | 4.3 | 26.0 | 1,641 | 4.3 | 26.1 | 4,934
33 | 3.9 | 25.9 | 4.2 | 25.8 | 482 | 3.8 | 25.5 | 1,502 | 4.1 | 25.8 | 4,701
34 | 4.1 | 26.0 | 4.0 | 26.1 | 465 | 3.8 | 25.4 | 1,493 | 4.2 | 25.6 | 4,882
35 | 4.0 | 26.0 | 3.9 | 24.9 | 470 | 4.1 | 25.9 | 1,586 | 4.4 | 26.4 | 5,048
36 | 4.6 | 28.3 | 4.3 | 25.9 | 493 | 4.1 | 26.3 | 1,573 | 4.4 | 26.2 | 5,021
37 | 4.5 | 28.4 | 4.3 | 26.4 | 487 | 4.3 | 26.6 | 1,615 | 4.2 | 26.3 | 4,813
38 | 4.3 | 27.8 | 4.2 | 26.7 | 475 | 4.0 | 26.6 | 1,508 | 4.5 | 26.6 | 5,042
39 | 4.6 | 28.5 | 4.1 | 26.6 | 460 | 4.0 | 26.8 | 1,491 | 4.2 | 26.7 | 4,763
40 | 4.4 | 28.5 | 4.5 | 26.3 | 515 | 4.4 | 27.0 | 1,639 | 4.3 | 26.6 | 4,851
Mean for weeks
1–13 | 4.1 | 20.4 | 4.0 | 20.5 | 596 | 4.1 | 20.7 | 1,981 | 4.2 | 20.4 | 6,123
14–40 | 4.1 | 25.7 | 4.0 | 24.8 | 488 | 4.0 | 25.0 | 1,618 | 4.2 | 24.8 | 5,025

a Grams of feed consumed per animal per day

b Milligrams of acesulfame potassium consumed per kilogram body weight per day

TABLE G3 Feed and Compound Consumption by Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium

Week | 0% | | 0.3% | | | 1% | | | 3%
Week | Feed (g)^a^ | Body Weight (g) | Feed (g) | Body Weight (g) | Dose (mg/kg)^b^ | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg)
2 | 4.2 | 21.9 | 4.1 | 21.7 | 571 | 4.2 | 22.0 | 1,922 | 4.2 | 22.0 | 5,731
3 | 4.4 | 22.1 | 3.7 | 21.9 | 509 | 4.1 | 22.3 | 1,854 | 3.8 | 22.1 | 5,170
4 | 4.3 | 22.9 | 4.2 | 22.5 | 560 | 3.8 | 22.8 | 1,690 | 4.1 | 22.7 | 5,416
5 | 4.4 | 23.6 | 4.7 | 23.6 | 599 | 4.2 | 23.9 | 1,755 | 4.6 | 24.1 | 5,696
6 | 4.1 | 24.1 | 4.1 | 23.9 | 509 | 4.1 | 24.4 | 1,673 | 4.1 | 24.4 | 5,091
7 | 3.9 | 24.5 | 4.0 | 24.2 | 491 | 4.2 | 25.0 | 1,674 | 4.1 | 24.7 | 5,011
8 | 3.9 | 25.3 | 4.1 | 24.8 | 491 | 4.2 | 25.5 | 1,638 | 4.3 | 25.2 | 5,085
9 | 3.9 | 25.4 | 3.9 | 24.9 | 468 | 4.0 | 25.6 | 1,549 | 4.1 | 25.4 | 4,789
10 | 4.0 | 25.6 | 4.1 | 25.1 | 486 | 4.1 | 26.1 | 1,559 | 4.2 | 25.6 | 4,922
11 | 4.0 | 25.9 | 4.1 | 25.4 | 483 | 4.1 | 26.8 | 1,520 | 4.3 | 25.7 | 5,042
12 | 4.2 | 26.5 | 4.1 | 25.6 | 483 | 4.1 | 27.1 | 1,520 | 4.3 | 26.3 | 4,937
13 | 4.0 | 26.6 | 4.3 | 25.9 | 499 | 4.1 | 26.9 | 1,514 | 4.1 | 26.5 | 4,601
14 | 4.1 | 27.0 | 4.3 | 26.7 | 482 | 4.0 | 27.2 | 1,473 | 4.2 | 27.0 | 4,631
15 | 4.2 | 27.5 | 4.2 | 27.2 | 464 | 4.4 | 28.3 | 1,561 | 4.3 | 27.9 | 4,614
16 | 4.3 | 28.0 | 4.3 | 27.9 | 463 | 4.1 | 28.4 | 1,459 | 4.3 | 28.1 | 4,566
17 | 4.3 | 28.5 | 4.5 | 27.7 | 484 | 4.5 | 28.9 | 1,544 | 4.5 | 28.2 | 4,802
19 | 4.2 | 29.2 | 4.1 | 28.3 | 434 | 4.2 | 29.8 | 1,406 | 4.2 | 28.9 | 4,407
20 | 4.0 | 29.4 | 4.2 | 28.6 | 436 | 4.0 | 29.2 | 1,359 | 4.4 | 29.1 | 4,539
21 | 4.3 | 29.7 | 4.3 | 28.8 | 449 | 4.3 | 30.0 | 1,443 | 4.4 | 29.4 | 4,510
22 | 4.1 | 29.5 | 4.1 | 29.0 | 426 | 4.1 | 29.9 | 1,370 | 4.2 | 29.5 | 4,303
23 | 3.9 | 29.2 | 4.0 | 28.5 | 425 | 4.0 | 29.6 | 1,357 | 4.5 | 29.5 | 4,565
24 | 4.3 | 29.6 | 4.8 | 29.2 | 489 | 4.3 | 30.3 | 1,410 | 4.5 | 30.3 | 4,422
25 | 4.2 | 29.6 | 4.2 | 28.9 | 441 | 4.3 | 30.5 | 1,392 | 4.3 | 29.9 | 4,281
26 | 4.2 | 29.6 | 4.5 | 29.4 | 462 | 4.3 | 30.5 | 1,405 | 4.4 | 30.3 | 4,351
27 | 3.9 | 29.0 | 4.3 | 29.0 | 443 | 4.4 | 30.9 | 1,417 | 4.4 | 30.4 | 4,325
28 | 4.2 | 29.3 | 4.3 | 29.8 | 432 | 4.5 | 31.9 | 1,422 | 4.5 | 31.0 | 4,402
29 | 4.3 | 30.3 | 4.4 | 30.2 | 438 | 4.3 | 32.1 | 1,327 | 4.1 | 30.5 | 4,001
30 | 4.3 | 30.4 | 4.5 | 30.5 | 441 | 4.3 | 32.4 | 1,322 | 4.5 | 31.1 | 4,357
31 | 4.3 | 30.1 | 4.4 | 30.0 | 438 | 4.5 | 32.2 | 1,405 | 4.4 | 31.1 | 4,210
32 | 4.2 | 29.9 | 4.4 | 29.3 | 447 | 4.4 | 32.0 | 1,377 | 4.6 | 30.9 | 4,454
33 | 4.4 | 29.6 | 4.6 | 29.5 | 469 | 4.3 | 31.1 | 1,383 | 4.7 | 30.4 | 4,648
34 | 4.5 | 29.2 | 4.5 | 29.2 | 466 | 4.7 | 31.3 | 1,501 | 4.5 | 30.2 | 4,442
35 | 4.6 | 29.2 | 4.7 | 29.3 | 484 | 4.5 | 30.8 | 1,458 | 4.5 | 29.6 | 4,558
36 | 4.3 | 29.1 | 4.7 | 29.3 | 484 | 4.6 | 31.0 | 1,473 | 4.7 | 29.4 | 4,764
37 | 4.4 | 29.1 | 4.7 | 29.7 | 473 | 4.7 | 31.1 | 1,517 | 4.7 | 29.7 | 4,773
38 | 4.5 | 29.1 | 4.7 | 29.5 | 477 | 4.6 | 31.3 | 1,477 | 4.7 | 29.9 | 4,722
39 | 4.6 | 29.2 | 4.7 | 29.9 | 469 | 4.8 | 31.7 | 1,531 | 4.7 | 30.1 | 4,728
40 | 4.5 | 29.5 | 4.6 | 30.1 | 458 | 4.4 | 31.6 | 1,407 | 4.5 | 29.9 | 4,520
Mean for weeks
1–13 | 4.1 | 24.5 | 4.1 | 24.1 | 513 | 4.1 | 24.9 | 1,656 | 4.2 | 24.6 | 5,124
14–40 | 4.3 | 29.2 | 4.4 | 29.1 | 457 | 4.4 | 30.5 | 1,431 | 4.4 | 29.7 | 4,496

a Grams of feed consumed per animal per day

b Milligrams of acesulfame potassium consumed per kilogram body weight per day

TABLE G4 Feed and Compound Consumption by Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium

Week | 0% | | 0.3% | | | 1% | | | 3%
Week | Feed (g)^a^ | Body Weight (g) | Feed (g) | Body Weight (g) | Dose (mg/kg)^b^ | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg)
2 | 4.2 | 18.5 | 4.2 | 17.9 | 708 | 3.7 | 18.4 | 2,027 | 4.0 | 17.8 | 6,756
3 | 4.4 | 18.4 | 4.5 | 18.7 | 719 | 4.2 | 19.2 | 2,207 | 4.3 | 18.5 | 6,987
4 | 4.3 | 19.6 | 4.4 | 19.5 | 674 | 4.3 | 19.9 | 2,160 | 4.0 | 19.1 | 6,327
5 | 5.0 | 20.2 | 5.1 | 20.7 | 737 | 4.7 | 20.6 | 2,282 | 4.8 | 20.1 | 7,184
6 | 4.5 | 20.9 | 4.8 | 21.1 | 685 | 4.5 | 21.2 | 2,124 | 4.7 | 21.0 | 6,771
7 | 4.2 | 21.0 | 4.6 | 21.2 | 645 | 4.0 | 21.5 | 1,871 | 4.0 | 21.1 | 5,757
8 | 4.7 | 21.4 | 4.3 | 21.5 | 595 | 3.8 | 21.5 | 1,789 | 3.9 | 20.8 | 5,654
9 | 4.5 | 21.4 | 4.2 | 21.5 | 587 | 3.9 | 21.7 | 1,801 | 4.1 | 21.3 | 5,844
10 | 4.4 | 21.8 | 4.4 | 21.6 | 608 | 3.9 | 21.9 | 1,797 | 4.2 | 21.6 | 5,798
11 | 4.4 | 22.4 | 4.6 | 22.4 | 616 | 4.2 | 22.4 | 1,888 | 4.3 | 21.8 | 5,890
12 | 4.7 | 22.6 | 4.8 | 22.3 | 644 | 4.3 | 22.6 | 1,895 | 4.7 | 22.3 | 6,271
13 | 4.4 | 23.0 | 4.9 | 23.1 | 633 | 4.6 | 23.2 | 1,995 | 4.5 | 22.8 | 5,940
14 | 4.5 | 23.2 | 4.5 | 23.6 | 574 | 4.6 | 23.5 | 1,937 | 4.5 | 22.9 | 5,873
15 | 4.4 | 23.6 | 4.9 | 24.2 | 605 | 4.4 | 23.7 | 1,862 | 4.2 | 22.9 | 5,543
16 | 4.9 | 24.1 | 4.9 | 25.2 | 578 | 4.6 | 24.2 | 1,906 | 4.8 | 23.6 | 6,146
17 | 4.7 | 24.3 | 4.8 | 25.1 | 578 | 4.6 | 24.2 | 1,919 | 4.7 | 23.7 | 5,980
18 | 5.1 | 24.7 | 5.1 | 25.6 | 601 | 4.8 | 25.0 | 1,912 | 4.7 | 24.1 | 5,874
19 | 4.9 | 24.8 | 4.6 | 25.8 | 531 | 4.7 | 24.9 | 1,888 | 4.8 | 24.6 | 5,855
20 | 4.9 | 25.1 | 4.6 | 26.1 | 526 | 4.5 | 25.5 | 1,784 | 4.8 | 24.9 | 5,816
21 | 5.0 | 25.4 | 4.8 | 26.4 | 549 | 4.4 | 25.7 | 1,720 | 4.7 | 25.3 | 5,575
22 | 4.6 | 25.6 | 4.6 | 26.8 | 517 | 4.5 | 26.1 | 1,708 | 4.7 | 25.5 | 5,483
23 | 4.8 | 26.1 | 5.0 | 27.0 | 550 | 4.4 | 26.3 | 1,682 | 5.0 | 25.6 | 5,878
24 | 4.3 | 26.1 | 4.7 | 26.9 | 522 | 4.5 | 26.6 | 1,679 | 4.6 | 26.0 | 5,317
25 | 4.6 | 26.4 | 4.6 | 26.9 | 516 | 4.4 | 26.7 | 1,647 | 4.5 | 26.3 | 5,190
26 | 4.6 | 26.5 | 4.8 | 27.1 | 535 | 4.6 | 26.5 | 1,721 | 4.9 | 26.3 | 5,568
27 | 4.6 | 26.7 | 4.4 | 27.3 | 479 | 4.5 | 27.2 | 1,657 | 4.8 | 26.9 | 5,391
28 | 4.7 | 26.9 | 4.6 | 27.8 | 495 | 4.4 | 27.4 | 1,596 | 4.7 | 27.4 | 5,167
29 | 4.5 | 27.0 | 4.4 | 28.0 | 475 | 4.5 | 28.0 | 1,618 | 4.7 | 27.1 | 5,150
30 | 4.7 | 28.2 | 4.8 | 28.6 | 501 | 4.4 | 28.5 | 1,548 | 5.0 | 28.0 | 5,357
31 | 4.7 | 27.8 | 4.9 | 28.6 | 512 | 4.7 | 28.5 | 1,634 | 4.7 | 27.9 | 5,020
32 | 4.7 | 28.1 | 4.9 | 27.9 | 531 | 4.6 | 28.5 | 1,622 | 4.7 | 27.5 | 5,127
33 | 4.7 | 27.5 | 5.1 | 28.0 | 546 | 4.9 | 28.4 | 1,718 | 5.3 | 27.9 | 5,736
34 | 4.6 | 27.7 | 5.1 | 27.8 | 552 | 4.6 | 28.3 | 1,641 | 4.8 | 27.5 | 5,274
35 | 4.8 | 27.6 | 5.3 | 27.3 | 581 | 4.7 | 27.7 | 1,690 | 4.7 | 26.8 | 5,284
36 | 4.4 | 27.3 | 4.8 | 28.1 | 510 | 4.7 | 28.2 | 1,668 | 4.6 | 27.1 | 5,049
37 | 4.8 | 27.5 | 5.0 | 28.0 | 539 | 4.7 | 28.0 | 1,676 | 4.7 | 27.6 | 5,054
38 | 4.6 | 27.7 | 4.5 | 28.1 | 483 | 4.8 | 27.9 | 1,708 | 4.8 | 27.6 | 5,267
39 | 4.5 | 27.5 | 4.9 | 28.3 | 521 | 4.6 | 28.2 | 1,617 | 4.9 | 28.0 | 5,213
40 | 4.7 | 28.3 | 4.9 | 28.8 | 514 | 4.8 | 28.8 | 1,677 | 4.7 | 28.3 | 4,968
Mean for weeks
1–13 | 4.5 | 20.9 | 4.6 | 21.0 | 654 | 4.2 | 21.2 | 1,986 | 4.3 | 20.7 | 6,265
14–40 | 4.7 | 26.4 | 4.8 | 27.0 | 534 | 4.6 | 26.8 | 1,720 | 4.7 | 26.2 | 5,450

a Grams of feed consumed per animal per day

b Milligrams of acesulfame potassium consumed per kilogram body weight per day