# APPENDIX F CHEMICAL CHARACTERIZATION AND DOSE FORMULATION STUDIES

## Procurement and Characterization of Acesulfame Potassium

Acesulfame potassium was obtained from Riedel-deHaen (St. Louis, MO) via Research Triangle Institute (RTI) (Research Triangle Park, NC) in one lot (8415-76-02 RTI), which was used in the 9-month studies in Tg.AC hemizygous mice and p53 haploinsufficient mice. Identity and purity analyses were conducted by the analytical chemistry laboratory, RTI, and the study laboratory (BioReliance Corporation, Rockville, MD); the study laboratory also conducted stability analyses. Reports on analyses performed in support of the acesulfame potassium studies are on file at the National Institute of Environmental Health Sciences.

Lot 8415-76-02 RTI of the chemical, a white, odorless, crystalline powder, was identified as acesulfame potassium by the analytical chemistry laboratory using infrared and proton nuclear magnetic resonance spectroscopy and by the study laboratory using infrared spectroscopy. All spectra were consistent with the structure of acesulfame potassium. The infrared and proton nuclear magnetic resonance spectra are presented in Figures F1 and F2.

The purity of lot 8415-76-02 RTI was determined by the analytical chemistry laboratory using high-performance liquid chromatography (HPLC), using Waters Chromatography (Milford, MA), an Alltima C_18_ column, 25 cm × 3.2 mm (Alltech; Chicago, IL), a mobile phase of 0.0125 M potassium dihydrogen phosphate (pH3.5):acetonitrile (100:0 for 5 minutes; 100:0 to 90:10 in 25 minutes; 90:10 for 10 minutes), a flow rate of 1.0 mL/minute, with ultraviolet detection at 230 nm. The study laboratory confirmed purity by major peak comparisons versus a reference sample from the same lot (stored at −20° C) using HPLC with a variation in the mobile phase (potassium dihydrogen phosphate:acetonitrile; 95:5) and a Hewlett-Packard model 1100 (Palo Alto, CA) instrument.

For lot 8415-76-02 RTI, HPLC indicated one major peak and no impurities. The analytical chemistry laboratory determined the purity to be greater than 99%; the study laboratory determined the purity to be 101% relative to the reference standard. The overall purity of lot 8415-76-02 RTI was determined to be 99% or greater.

To ensure stability, the bulk chemical was stored at room temperature under a headspace of inert gas, protected from light, in polyethylene bags inside plastic pails. Stability of the bulk chemical was monitored during the study by the study laboratory using HPLC. No degradation of the bulk chemical was observed.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared once every 2 to 4 weeks by mixing acesulfame potassium with feed (Table F1). A premix was prepared by hand and then blended with additional feed in a Patterson-Kelly twin-shell blender for 15 minutes using an intensifier bar for the initial 5 minutes. Formulations were stored in doubled polyethylene bags at room temperature for up to 35 days.

Homogeneity studies of the 0.1% and 5% acesulfame potassium formulations and stability studies of the 0.1% formulations were performed by the analytical chemistry laboratory using HPLC with a variation in the mobile phase ratio (95:5). Homogeneity studies of the 0.3% and 3% acesulfame potassium formulations were performed by the study laboratory using HPLC and the RTI extraction method modified to centrifuge samples before analysis. Homogeneity was confirmed, and stability was confirmed for at least 35 days for dose formulations stored in amber glass bottles at −20° C, −5° C, and 25° C, and when exposed to light and air for 7 days.

Periodic analyses of the dose formulations of acesulfame potassium were conducted by the study laboratory using HPLC. Samples of the formulation were extracted with 50:50 water/methanol, shaken for 10 minutes, and then centrifuged; theophylline (2 mg/mL) was used as an internal standard. During the 9-month studies, the dose formulations were analyzed five times; all 15 of the dose formulations analyzed were within 10 % of the target concentrations (Table F2). Animal room samples of these dose formulations were also analyzed, and 12 of 15 animal room samples were within 10% of the target concentrations (Table F2).

FIGURE F1 Infrared Absorption Spectrum of Acesulfame Potassium

FIGURE F2 Proton Nuclear Magnetic Resonance Spectrum of Acesulfame Potassium

TABLE F1 Preparation and Storage of Dose Formulations in the 9-Month Feed Studies of Acesulfame Potassium

Preparation
A premix of feed and acesulfame potassium was prepared, then layered into the remaining feed and blended in a Patterson-Kelly twin-shell blender with the intensifier bar on for 5 minutes and off for 10 minutes. The dose formulations were prepared every two to four weeks.
Chemical Lot Number
8415-76-02 RTI
Maximum Storage Time
35 days
Storage Conditions
Stored in doubled polyethylene bags at room temperature, protected from light
Study Laboratory
BioReliance Corporation(Rockville, MD)

TABLE F2 Results of Analyses of Dose Formulations Administered to Tg.AC Hemizygous Mice and p53 Haploinsufficient Mice in the 9-Month Feed Studies of Acesulfame Potassium

Date Prepared | Date Analyzed | Target Concentration (%) | Determined Concentration^a^ (%) | Difference from Target (%)
January 19, 2000 | January 19, 2000 | 0.3 | 0.283 | −6
January 19, 2000 | January 19, 2000 | 1 | 1.06 | +6
January 19, 2000 | January 19, 2000 | 3 | 2.89 | −4
January 19, 2000 | March 7, 2000^b^ | 0.3 | 0.297 | −1
January 19, 2000 | March 7, 2000^b^ | 1 | 1.04 | +4
January 19, 2000 | March 7, 2000^b^ | 3 | 3.06 | +2
February 29, 2000 | February 29, 2000 | 0.3 | 0.305 | +2
February 29, 2000 | February 29, 2000 | 1 | 1.02 | +2
February 29, 2000 | February 29, 2000 | 3 | 3.14 | +5
February 29, 2000 | April 19, 2000^b^ | 0.3 | 0.301 | 0
February 29, 2000 | April 19, 2000^b^ | 1 | 0.857 | −14
February 29, 2000 | April 19, 2000^b^ | 3 | 3.01 | 0
May 9, 2000 | May 9, 2000 | 0.3 | 0.298 | −1
May 9, 2000 | May 9, 2000 | 1 | 0.985 | −2
May 9, 2000 | May 9, 2000 | 3 | 3.01 | 0
May 9, 2000 | June 8, 2000^b^ | 0.3 | 0.295 | −2
May 9, 2000 | June 8, 2000^b^ | 1. | 0.942 | −6
May 9, 2000 | June 8, 2000^b^ | 3. | 3.04 | +1
July 25, 2000 | July 25, 2000 | 0.3 | 0.288 | −4
July 25, 2000 | July 25, 2000 | 1 | 1.05 | +5
July 25, 2000 | July 25, 2000 | 3 | 3.12 | +4
July 25, 2000 | September 6, 2000^b^ | 0.3 | 0.293 | −2
July 25, 2000 | September 6, 2000^b^ | 1 | 0.847 | −15
July 25, 2000 | September 6, 2000^b^ | 3 | 2.76 | −8
October 3, 2000 | October 3, 2000 | 0.3 | 0.301 | 0
October 3, 2000 | October 3, 2000 | 1 | 1.01 | +1
October 3, 2000 | October 3, 2000 | 3 | 3.08 | +3
October 3, 2000 | November 8, 2000^b^ | 0.3 | 0.336 | +12
October 3, 2000 | November 8, 2000^b^ | 1 | 1.06 | +6
October 3, 2000 | November 8, 2000^b^ | 3 | 3.14 | +5

a Results of duplicate analyses

b Animal room samples