# APPENDIX E GENETIC TOXICOLOGY

## Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al. (1990). At the end of the 9-month toxicity studies, peripheral blood samples were obtained from male and female mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs) in up to 13 Tg.AC hemizygous and 15 p53 haploinsufficient mice per exposure group; 1,000 total erythrocytes were counted to determine the percent polychromatic erythrocytes (PCEs).

The results were tabulated as the mean of the pooled results from all animals within a treatment group plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over exposure groups with a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each exposure group and the control group (ILS, 1990). In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single exposed group is less than or equal to 0.025 divided by the number of exposure groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Results of the 9-month studies were accepted without repeat tests, because additional test data could not be obtained. Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

## Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple aliquots of a chemical were tested in the same assay, and different results were obtained among aliquots and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Technical Report presents a result that represents a scientific judgement of the overall evidence for activity of the chemical in an assay.

## Results

Acesulfame potassium did not increase the frequency of micronucleated NCEs in peripheral blood of male or female Tg.AC hemizygous mice administered 0.3% to 3% of the chemical in feed for 9 months (Table E1). A similar study was conducted in p53 haploinsufficient mice, and in this study, a significant exposure-related increase in the frequency of micronucleated NCEs was noted in males but not females; micronucleus frequencies in the 1% and 3% male groups were significantly elevated over the control group (Table E2). There was no significant alteration in the percentage of PCEs among total erythrocytes in either Tg.AC hemizygous or p53 haploinsufficient mice.

TABLE E1 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Tg.AC Hemizygous Mice Following Administration of Acesulfame Potassium in Feed for 9 Months^a^

Dose (%) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | % PCE
Male
NTP-2000 feed^d^ | 13 | 1.42 ± 0.19 | | 3.4
0.3 | 11 | 1.59 ± 0.18 | 0.3180 | 3.4
1 | 13 | 1.62 ± 0.23 | 0.2867 | 2.9
3 | 13 | 1.58 ± 0.19 | 0.3252 | 3.4
| | P=0.391^e^
Female
NTP-2000 feed | 12 | 1.29 ± 0.16 | | 3.4
0.3 | 12 | 1.13 ± 0.22 | 0.7004 | 3.1
1 | 12 | 1.17 ± 0.27 | 0.6520 | 3.5
3 | 12 | 1.58 ± 0.23 | 0.1995 | 3.3
| | P=0.098

a Study was performed at SITEK Laboratories, Inc. The detailed protocol is presented by MacGregor et al. (1990); NCE=normochromatic erythrocyte; PCE=polychromatic erythrocyte.

b Mean ± standard error

c Pairwise comparison with the controls, significant at P≤0.008 (ILS, 1990)

d Control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)

TABLE E2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of p53 Haploinsufficient Mice Following Administration of Acesulfame Potassium in Feed for 9 Months^a^

Dose (%) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | % PCE
Male
NTP-2000 feed^d^ | 14 | 1.57 ± 0.22 | | 2.98
0.3 | 15 | 2.10 ± 0.24 | 0.0691 | 3.25
1 | 15 | 2.57 ± 0.19 | 0.0043 | 3.30
3 | 14 | 2.79 ± 0.33 | 0.0010 | 3.36
| | P=0.003^e^
Female
NTP-2000 feed | 14 | 1.29 ± 0.16 | | 3.44
0.3 | 14 | 1.71 ± 0.17 | 0.0950 | 3.29
1 | 14 | 1.75 ± 0.21 | 0.0791 | 3.27
3 | 14 | 1.50 ± 0.26 | 0.2483 | 3.24
| | P=0.467

a Study was performed at SITEK Laboratories, Inc. The detailed protocol is presented by MacGregor et al. (1990); NCE=normochromatic erythrocyte; PCE=polychromatic erythrocyte.

b Mean ± standard error

c Pairwise comparison with the controls, significant at P≤0.008 (ILS, 1990)

d Control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)