# APPENDIX D SUMMARY OF LESIONS IN FEMALE p53 HAPLOINSUFFICIENT MICE IN THE 9-MONTH FEED STUDY OF ACESULFAME POTASSIUM

TABLE D1 Summary of the Incidence of Neoplasms in Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium^a^

| 0% | 0.3% | 1% | 3%
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 1 | | 1
Natural deaths | | 1 | | 1
Survivors
Terminal sacrifice | 14 | 14 | 14 | 14
Animals examined microscopically | 15 | 1 | 2 | 15
Alimentary System
Mesentery | | (1)
Sarcoma | | 1 (100%)
Cardiovascular System
Heart | (15) | | | (15)
Endocrine System
None
General Body System
Tissue NOS | (1)
Pelvic, osteosarcoma, metastatic, bone | 1 (100%)
Genital System
None
Hematopoietic System
Lymph node | | | | (1)
Pancreatic, histiocytic sarcoma | | | | 1 (100%)
Spleen | (15) | | | (14)
Histiocytic sarcoma | | | | 1 (7%)
Thymus | (15) | | | (14)
Histiocytic sarcoma | | | | 1 (7%)
Integumentary System
Mammary gland | (15) | | (1) | (13)
Osteosarcoma | | | 1 (100%)
Musculoskeletal System
Bone | (15) | | | (14)
Femur, osteosarcoma | 1 (7%)
Nervous System
None
Respiratory System
Lung | (15) | | | (15)
Osteosarcoma, metastatic, bone | 1 (7%)
Special Senses System
None
Urinary System
None
Systemic Lesions
Multiple organs | (15) | (1) | (2) | (15)
Histiocytic sarcoma | | | | 1 (7%)
Lymphoma malignant | | | | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 1 | 1 | 1 | 2
Total primary neoplasms | 1 | 1 | 1 | 2
Total animals with malignant neoplasms | 1 | 1 | 1 | 2
Total malignant neoplasms | 1 | 1 | 1 | 2
Total animals with metastatic neoplasms | 1
Total metastatic neoplasms | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE D2

Individual Animal Tumor Pathology of Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium: 0%

Number of Days on Study | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 6 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 6 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 7 | 1 | 2 | 3 | 4 | 5 | 6 | 8 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | Total Tissues/Tumors
Alimentary System
Esophagus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Gallbladder | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, colon | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, rectum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, cecum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, duodenum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, jejunum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, ileum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pancreas | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tongue | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Blood vessel | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | M | + | + | + | + | + | + | + | + | + | + | 14
Islets, pancreatic | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Parathyroid gland | + | + | M | + | + | + | M | M | M | M | + | M | M | + | M | 7
Pituitary gland | + | + | + | + | I | + | + | M | + | + | + | + | + | + | + | 13
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
Tissue NOS | + | | | | | | | | | | | | | | | 1
Pelvic, osteosarcoma, metastatic, bone | X | | | | | | | | | | | | | | | 1
Genital System
Clitoral gland | I | + | + | + | + | M | M | M | + | M | M | + | M | + | M | 7
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Vagina | I | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Hematopoietic System
Bone marrow | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
Bone | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Femur, osteosarcoma | X | | | | | | | | | | | | | | | 1
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Larynx | M | + | M | + | M | + | + | + | + | I | + | + | + | + | + | 11
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Osteosarcoma, metastatic, bone | X | | | | | | | | | | | | | | | 1
Nose | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Trachea | + | + | + | + | + | + | + | + | + | I | + | + | + | + | + | 14
Special Senses System
Eye | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Zymbal’s gland | + | + | M | + | M | + | + | M | + | M | + | M | M | + | M | 8
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | + | + | + | + | + | + | + | + | + | + | + | + | + | I | + | 14
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium: 0.3%

Number of Days on Study | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 6 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 3 | 2 | 2 | 2 | 2 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 4 | Total Tissues/Tumors
Carcass ID Number | 7 | 6 | 7 | 8 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | 6 | 8 | 9 | 0 | Total Tissues/Tumors
Alimentary System
Mesentery | + | | | | | | | | | | | | | | | 1
Sarcoma | X | | | | | | | | | | | | | | | 1
Cardiovascular System
None
Endocrine System
None
General Body System
None
Genital System
None
Hematopoietic System
None
Integumentary System
None
Musculoskeletal System
None
Nervous System
None
Respiratory System
None
Special Senses System
None
Urinary System
None
Systemic Lesions
Multiple organs | + | | | | | | | | | | | | | | | 1

Individual Animal Tumor Pathology of Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium: 1%

Number of Days on Study | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 2 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 7 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 5 | 5 | 5 | 5 | 5 | Total Tissues/Tumors
Carcass ID Number | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | Total Tissues/Tumors
Alimentary System
None
Cardiovascular System
None
Endocrine System
None
General Body System
None
Genital System
Uterus | | | | | | | | + | | | | | | | | 1
Hematopoietic System
None
Integumentary System
Mammary gland | + | | | | | | | | | | | | | | | 1
Osteosarcoma | X | | | | | | | | | | | | | | | 1
Musculoskeletal System
None
Nervous System
None
Respiratory System
None
Special Senses System
None
Urinary System
None
Systemic Lesions
Multiple organs | + | | | | | | | + | | | | | | | | 2

Individual Animal Tumor Pathology of Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium: 3%

Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 4 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 3 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 5 | 5 | 5 | 5 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 7 | Total Tissues/Tumors
Carcass ID Number | 7 | 6 | 8 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | Total Tissues/Tumors
Alimentary System
Esophagus | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Gallbladder | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine large, colon | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine large, rectum | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine large, cecum | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine small, duodenum | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine small, jejunum | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine small, ileum | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Liver | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Pancreas | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Salivary glands | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Stomach, forestomach | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Stomach, glandular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Tongue | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Cardiovascular System
Blood vessel | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Adrenal medulla | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Islets, pancreatic | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Parathyroid gland | A | + | M | M | + | M | + | + | + | + | + | M | + | M | + | 9
Pituitary gland | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Thyroid gland | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
General Body System
None
Genital System
Clitoral gland | A | + | + | + | + | M | M | + | M | M | + | + | + | M | + | 9
Ovary | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Uterus | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Vagina | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Hematopoietic System
Bone marrow | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node | | | | | | | | | | + | | | | | | 1
Pancreatic, histiocytic sarcoma | | | | | | | | | | X | | | | | | 1
Lymph node, mandibular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mesenteric | A | + | + | + | + | + | + | + | + | M | + | + | + | + | + | 13
Spleen | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Histiocytic sarcoma | | | | | | | | | | X | | | | | | 1
Thymus | + | M | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Histiocytic sarcoma | | | | | | | | | | X | | | | | | 1
Integumentary System
Mammary gland | A | M | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Skin | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Musculoskeletal System
Bone | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Skeletal muscle | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Nervous System
Brain | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Respiratory System
Larynx | A | + | + | + | + | + | + | + | + | I | + | + | I | I | + | 11
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nose | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Trachea | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Special Senses System
Eye | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Harderian gland | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Zymbal’s gland | A | + | + | + | + | + | + | + | + | + | + | + | + | M | M | 12
Urinary System
Kidney | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Urinary bladder | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | | | | | | | X | | | | | | 1
Lymphoma malignant | X | | | | | | | | | | | | | | | 1

+: Tissue examined microscopically | M: Missing tissue | X: Lesion present
A: Autolysis precludes examination | I: Insufficient tissue | Blank: Not examined

TABLE D3 Statistical Analysis of Primary Neoplasms in Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium

| 0% | 0.3% | 1% | 3%
All Organs: Malignant Neoplasms
Overall rate^a^ | 1/15 (7%) | 1/15 (7%) | 1/15 (7%) | 2/15 (13%)
Adjusted rate^b^ | 6.7% | 6.7% | 6.7% | 13.3%
Terminal rate^c^ | 0/14 (0%) | 0/14 (0%) | 0/14 (0%) | 1/14 (7%)
First incidence (days) | 166 | 176 | 127 | 243
Poly-3 test^d^ | P=0.360 | P=0.760 | P=0.760 | P=0.500
All Organs: Benign or Malignant Neoplasms
Overall rate | 1/15 (7%) | 1/15 (7%) | 1/15 (7%) | 2/15 (13%)
Adjusted rate | 6.7% | 6.7% | 6.7% | 13.3%
Terminal rate | 0/14 (0%) | 0/14 (0%) | 0/14 (0%) | 1/14 (7%)
First incidence (days) | 166 | 176 | 127 | 243
Poly-3 test | P=0.360 | P=0.760 | P=0.760 | P=0.500

a Number of neoplasm-bearing animals/number of animals necropsied.

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal sacrifice.

TABLE D4 Summary of the Incidence of Nonneoplastic Lesions in Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium^a^

| 0% | 0.3% | 1% | 3%
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 1 | | 1
Natural deaths | | 1 | | 1
Survivors
Terminal sacrifice | 14 | 14 | 14 | 14
Animals examined microscopically | 15 | 1 | 2 | 15
Alimentary System
Liver | (15) | | | (14)
Infiltration cellular, focal, lymphocyte | 2 (13%) | | | 1 (7%)
Inflammation, chronic active | 6 (40%) | | | 7 (50%)
Hepatocyte, necrosis, focal | 1 (7%)
Salivary glands | (15) | | | (14)
Infiltration cellular, focal, lymphocyte | 10 (67%) | | | 9 (64%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (15) | | | (14)
Hyperplasia, focal | 2 (13%) | | | 2 (14%)
Subcapsular, hyperplasia, focal | 13 (87%) | | | 12 (86%)
Thyroid gland | (15) | | | (14)
Ectopic thymus | | | | 1 (7%)
General Body System
None
Genital System
Uterus | (15) | | (1) | (14)
Endometrium, hyperplasia, cystic | 13 (87%) | | 1 (100%) | 13 (93%)
Hematopoietic System
Lymph node, mandibular | (15) | | | (14)
Hyperplasia | 1 (7%)
Spleen | (15) | | | (14)
Hematopoietic cell proliferation | 2 (13%) | | | 1 (7%)
Thymus | (15) | | | (14)
Atrophy | 6 (40%) | | | 2 (14%)
Atrophy, diffuse | 1 (7%)
Atrophy, focal | | | | 4 (29%)
Integumentary System
Mammary gland | (15) | | (1) | (13)
Inflammation, acute | 1 (7%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | | | (15)
Infiltration cellular, lymphocyte | 1 (7%) | | | 1 (7%)
Special Senses System
Harderian gland | (15) | | | (14)
Inflammation, chronic active | 1 (7%)
Urinary System
Kidney | (15) | | | (14)
Inflammation, chronic active | | | | 1 (7%)
Renal tubule, dilatation, focal | 6 (40%) | | | 2 (14%)
Renal tubule, nephropathy | 1 (7%)
Urinary bladder | (14) | | | (14)
Infiltration cellular, focal, lymphocyte | | | | 1 (7%)

a Number of animals examined microscopically at the site and the number of animals with lesion