# APPENDIX C SUMMARY OF LESIONS IN MALE p53 HAPLOINSUFFICIENT MICE IN THE 9-MONTH FEED STUDY OF ACESULFAME POTASSIUM

TABLE C1 Summary of the Incidence of Neoplasms in Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium^a^

| 0% | 0.3% | 1% | 3%
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 1 | | | 1
Survivors
Terminal sacrifice | 14 | 15 | 15 | 14
Animals examined microscopically | 15 | | 1 | 15
Alimentary System
None
Cardiovascular System
None
Endocrine System
None
General Body System
None
Genital System
None
Hematopoietic System
None
Integumentary System
Skin | (15) | | (1) | (15)
Pinna, hemangiosarcoma | | | 1 (100%)
Subcutaneous tissue, fibrosarcoma | | | | 1 (7%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
None
Special Senses System
None
Urinary System
None
Neoplasm Summary
Total animals with primary neoplasms^b^ | | | 1 | 1
Total primary neoplasms | | | 1 | 1
Total animals with malignant neoplasms | | | 1 | 1
Total malignant neoplasms | | | 1 | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE C2

Individual Animal Tumor Pathology of Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium: 0%

Number of Days on Study | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 9 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 0 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | 6 | 6 | 6 | 6 | 6 | Total Tissues/Tumors
Carcass ID Number | 8 | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | Total Tissues/Tumors
Alimentary System
Esophagus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Gallbladder | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, colon | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, rectum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, cecum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, duodenum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, jejunum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, ileum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Mesentery | | | | | | | | | + | | | | | | | 1
Pancreas | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tongue | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Blood vessel | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | M | + | + | + | + | 14
Islets, pancreatic | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Parathyroid gland | + | + | + | + | M | M | + | + | M | + | M | M | M | M | M | 7
Pituitary gland | + | I | + | + | I | + | + | + | + | + | I | + | I | I | I | 9
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Preputial gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Prostate | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Seminal vesicle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Bone marrow | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | M | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mediastinal | | | | | | | | | + | | | | | | | 1
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
Bone | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Larynx | + | + | I | M | I | + | + | + | I | + | I | M | + | + | + | 9
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nose | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Trachea | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
Eye | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Zymbal’s gland | M | I | + | M | M | M | + | + | M | M | M | + | + | M | M | 5
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium: 1%

Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 9 | 9 | 9 | 9 | 9 | 9 | Total Tissues/Tumors
Carcass ID Number | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | Total Tissues/Tumors
Alimentary System
None
Cardiovascular System
None
Endocrine System
None
General Body System
None
Genital System
None
Hematopoietic System
None
Integumentary System
Skin | | | | | | | | | | | | | | + | | 1
Pinna, hemangiosarcoma | | | | | | | | | | | | | | X | | 1
Musculoskeletal System
None
Nervous System
None
Respiratory System
None
Special Senses System
None
Urinary System
None
Systemic Lesions
Multiple organs | | | | | | | | | | | | | | + | | 1

Individual Animal Tumor Pathology of Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium: 3%

Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 2 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 5 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 1 | 1 | 1 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 9 | 9 | 9 | 9 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | Total Tissues/Tumors
Carcass ID Number | 9 | 6 | 7 | 8 | 0 | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | Total Tissues/Tumors
Alimentary System
Esophagus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Gallbladder | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, colon | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, rectum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, cecum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, duodenum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, jejunum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, ileum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Mesentery | | + | | | | | | | | | | | | | | 1
Pancreas | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tongue | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Blood vessel | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Islets, pancreatic | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Parathyroid gland | + | + | M | M | M | M | + | + | + | + | + | + | M | M | M | 8
Pituitary gland | + | + | + | + | + | + | + | M | + | + | + | + | + | + | M | 13
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Preputial gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Prostate | + | + | + | + | + | + | + | + | + | + | + | + | I | + | I | 13
Seminal vesicle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Bone marrow | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node | | | | | | | | | | | | | | | + | 1
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | M | + | + | + | + | + | + | + | 14
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Subcutaneous tissue, fibrosarcoma | X | | | | | | | | | | | | | | | 1
Musculoskeletal System
Bone | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Larynx | + | + | + | + | M | I | + | M | M | M | I | I | + | + | I | 7
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nose | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Trachea | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
Eye | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Zymbal’s gland | M | M | M | M | M | M | + | + | + | + | M | + | + | + | M | 7
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

+: Tissue examined microscopically | M: Missing tissue | X: Lesion present
A: Autolysis precludes examination | I: Insufficient tissue | Blank: Not examined

TABLE C3 Statistical Analysis of Primary Neoplasms in Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium

| 0% | 0.3% | 1% | 3%
All Organs: Malignant Neoplasms
Overall rate^a^ | 0/15 (0%) | 0/15 (0%) | 1/15 (7%) | 1/15 (7%)
Adjusted rate^b^ | 0.0% | 0.0% | 6.7% | 6.7%
Terminal rate^c^ | 0/14 (0%) | 0/15 (0%) | 1/15 (7%) | 0/14 (0%)
First incidence (days) | —^e^ | — | 274 (T) | 225
Poly-3 test^d^ | P=0.312 | —^f^ | P=0.509 | P=0.509
All Organs: Benign or Malignant Neoplasms
Overall rate | 0/15 (0%) | 0/15 (0%) | 1/15 (7%) | 1/15 (7%)
Adjusted rate | 0.0% | 0.0% | 6.7% | 6.7%
Terminal rate | 0/14 (0%) | 0/15 (0%) | 1/15 (7%) | 0/14 (0%)
First incidence (days) | — | — | 274 (T) | 225
Poly-3 test | P=0.312 | — | P=0.509 | P=0.509

(T) Terminal sacrifice

a Number of neoplasm-bearing animals/number of animals necropsied.

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal sacrifice.

e Not applicable; no neoplasms in animal group

f Value of statistic cannot be computed

TABLE C4 Summary of the Incidence of Nonneoplastic Lesions in Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Acesulfame Potassium^a^

| 0% | 0.3% | 1% | 3%
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 1 | | | 1
Survivors
Terminal sacrifice | 14 | 15 | 15 | 14
Animals examined microscopically | 15 | | 1 | 15
Alimentary System
Liver | (15) | | | (15)
Inflammation, chronic active | 1 (7%) | | | 5 (33%)
Hepatocyte, inflammation, chronic active | 1 (7%)
Hepatocyte, necrosis, focal | 1 (7%)
Hepatocyte, centrilobular, hypertrophy | | | | 1 (7%)
Mesentery | (1) | | | (1)
Fat, inflammation, chronic active, focal | 1 (100%)
Fat, necrosis, focal | | | | 1 (100%)
Salivary glands | (15) | | | (15)
Infiltration cellular, focal, lymphocyte | 10 (67%) | | | 8 (53%)
Tongue | (15) | | | (15)
Inflammation | 1 (7%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (15) | | | (15)
Hypertrophy, focal | | | | 1 (7%)
Capsule, inflammation, chronic active, diffuse | 1 (7%)
Subcapsular, hyperplasia, focal | 1 (7%) | | | 1 (7%)
General Body System
None
Genital System
Epididymis | (15) | | | (15)
Infiltration cellular, lymphocyte | 1 (7%)
Polyarteritis | | | | 1 (7%)
Epithelium, degeneration, focal | 1 (7%)
Testes | (15) | | | (15)
Mineralization, focal | 1 (7%)
Sertoli cell, germinal epithelium, degeneration, focal | 1 (7%)
Hematopoietic System
Lymph node | | | | (1)
Inguinal, hyperplasia | | | | 1 (100%)
Lymph node, mandibular | (15) | | | (15)
Hyperplasia | | | | 2 (13%)
Lymph node, mediastinal | (1)
Edema | 1 (100%)
Inflammation, chronic active, diffuse | 1 (100%)
Spleen | (15) | | | (15)
Hematopoietic cell proliferation | 1 (7%) | | | 1 (7%)
Thymus | (15) | | | (14)
Atrophy | 2 (13%) | | | 2 (14%)
Atrophy, focal | | | | 1 (7%)
Integumentary System
Skin | (15) | | (1) | (15)
Subcutaneous tissue, inflammation, chronic active, focal | 1 (7%)
Musculoskeletal System
None
Nervous System
Brain | (15) | | | (15)
Inflammation, chronic active | 1 (7%)
Respiratory System
Lung | (15) | | | (15)
Alveolar epithelium, inflammation, chronic active, focal | 1 (7%) | | | 1 (7%)
Nose | (15) | | | (15)
Inflammation, chronic active | 1 (7%)
Inflammation, granulomatous | 1 (7%)
Special Senses System
Harderian gland | (15) | | | (15)
Infiltration cellular, lymphocyte | | | | 1 (7%)
Inflammation, chronic active | 4 (27%) | | | 2 (13%)
Urinary System
Kidney | (15) | | | (15)
Inflammation, chronic active | 1 (7%)
Renal tubule, dilatation, focal | 1 (7%) | | | 2 (13%)
Renal tubule, nephropathy | 1 (7%)

a Number of animals examined microscopically at the site and the number of animals with lesion