# APPENDIX B SUMMARY OF LESIONS IN FEMALE Tg.AC HEMIZYGOUS MICE IN THE 9-MONTH FEED STUDY OF ACESULFAME POTASSIUM

TABLE B1 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium^a^

| 0% | 0.3% | 1% | 3%
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 1 | | 2 | 2
Natural deaths | 2 | 3 | 1 | 1
Survivors
Terminal sacrifice | 12 | 12 | 12 | 12
Animals examined microscopically^b^ | 15 | 14 | 14 | 15
Alimentary System
Liver | (15) | (2) | | (15)
Stomach, forestomach | (14) | (9) | (10) | (14)
Squamous cell papilloma | 7 (50%) | 6 (67%) | 9 (90%) | 8 (57%)
Squamous cell papilloma, multiple | 2 (14%) | 1 (11%)
Tongue | (15) | (1) | | (15)
Squamous cell carcinoma, metastatic, uncertain primary site | 1 (7%)
Tooth | (2) | (1) | (6) | (4)
Odontogenic tumor | 2 (100%) | | 6 (100%) | 3 (75%)
Cardiovascular System
None
Endocrine System
Pituitary gland | (12) | | | (14)
General Body System
None
Genital System
Uterus | (13) | (2) | (1) | (14)
Sarcoma stromal | | | | 1 (7%)
Hematopoietic System
Spleen | (15) | | (3) | (15)
Integumentary System
Skin | (15) | (5) | (6) | (15)
Squamous cell papilloma | 1 (7%) | 2 (40%) | 3 (50%) | 1 (7%)
Lip, squamous cell papilloma | | | 2 (33%)
Vulva, squamous cell papilloma | 2 (13%) | 2 (40%) | 2 (33%) | 3 (20%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | | | (15)
Alveolar/bronchiolar adenoma | 1 (7%) | | | 1 (7%)
Special Senses System
Harderian gland | (14) | (1) | | (15)
Urinary System
Kidney | (15) | (1) | | (15)
Urinary bladder | (13) | | | (15)
Transitional epithelium, papilloma | | | | 1 (7%)
Systemic Lesions
Multiple organs | (15) | (14) | (14) | (15)
Leukemia erythrocytic | 2 (13%) | 1 (7%) | | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 12 | 10 | 13 | 13
Total primary neoplasms | 17 | 12 | 22 | 19
Total animals with benign neoplasms | 11 | 9 | 10 | 10
Total benign neoplasms | 13 | 11 | 16 | 14
Total animals with malignant neoplasms | 2 | 1 | | 2
Total malignant neoplasms | 2 | 1 | | 2
Total animals with metastatic neoplasms | 1
Total metastatic neoplasms | 1
Total animals with malignant neoplasms of uncertain primary site | 1
Total animals with uncertain neoplasms-benign or malignant | 2 | | 6 | 3
Total uncertain neoplasms | 2 | | 6 | 3

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B2

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium: 0%

Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 2 | 3 | 4 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 4 | 6 | 0 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 7 | 7 | 7 | 7 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 9 | Total Tissues/Tumors
Carcass ID Number | 9 | 7 | 6 | 8 | 0 | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | Total Tissues/Tumors
Alimentary System
Esophagus | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Gallbladder | A | A | + | + | + | + | + | + | + | + | M | + | + | + | + | 12
Intestine large, colon | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Intestine large, rectum | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Intestine large, cecum | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Intestine small, duodenum | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Intestine small, jejunum | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Intestine small, ileum | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Mesentery | | | | | | + | | | + | | | | | | | 2
Pancreas | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Salivary glands | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Stomach, forestomach | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Squamous cell papilloma | | | | X | | | X | | X | X | X | | X | X | | 7
Squamous cell papilloma, multiple | X | | | | | | | | | | | | | | X | 2
Stomach, glandular | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Tongue | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell carcinoma, metastatic, uncertain primary site | | | X | | | | | | | | | | | | | 1
Tooth | | + | | | | | | + | | | | | | | | 2
Odontogenic tumor | | X | | | | | | X | | | | | | | | 2
Cardiovascular System
Blood vessel | + | + | + | + | + | M | + | + | + | + | + | M | M | + | + | 12
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Adrenal medulla | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Islets, pancreatic | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Parathyroid gland | M | A | + | M | M | + | + | M | + | + | M | M | M | M | M | 5
Pituitary gland | + | I | + | + | + | + | + | I | I | + | + | + | + | + | + | 12
Thyroid gland | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
General Body System
None
Genital System
Clitoral gland | M | A | + | + | + | + | + | M | I | + | + | M | + | M | + | 9
Ovary | A | | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Uterus | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Vagina | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Hematopoietic System
Bone marrow | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mandibular | A | + | + | + | M | + | + | + | M | + | + | + | + | + | + | 12
Lymph node, mesenteric | A | A | + | + | + | + | M | + | + | + | + | + | + | + | + | 12
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | A | A | + | + | + | + | + | M | + | M | + | + | + | + | + | 11
Integumentary System
Mammary gland | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | | | | | | | | | | X | | 1
Vulva, squamous cell papilloma | | X | | | X | | | | | | | | | | | 2
Musculoskeletal System
Bone | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Respiratory System
Larynx | A | + | M | I | I | + | I | + | I | M | I | I | I | I | M | 3
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Alveolar/bronchiolar adenoma | | | | | X | | | | | | | | | | | 1
Nose | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Pleura | | | + | | | | | | | | | | | | | 1
Trachea | + | + | + | + | + | + | + | + | + | + | + | I | + | + | + | 14
Special Senses System
Eye | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Harderian gland | + | + | + | + | M | + | + | + | + | + | + | + | + | + | + | 14
Zymbal’s gland | + | M | + | M | + | + | + | + | + | + | + | + | M | + | M | 11
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | X | X | | | | | | | | | | | | | | 2

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium: 0.3%

Number of Days on Study | 0 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 9 | 5 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 7 | 6 | 6 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 1 | 0 | 1 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 0 | 9 | 0 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 3 | 9 | 1 | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 0 | 2 | 4 | 5 | Total Tissues/Tumors
Alimentary System
Esophagus | + | | | | | | | | | | | | | | | 1
Gallbladder | A
Intestine large, colon | A
Intestine large, rectum | A
Intestine large, cecum | A
Intestine small, duodenum | A
Intestine small, jejunum | A
Intestine small, ileum | A
Liver | + | + | | | | | | | | | | | | | | 2
Pancreas | + | | | | | | | | | | | | | | | 1
Salivary glands | + | | | | | | | | | | | | | | | 1
Stomach, forestomach | A | A | | + | + | | | + | + | + | + | + | + | | + | 9
Squamous cell papilloma | | | | X | X | | | X | X | | | | X | | X | 6
Squamous cell papilloma, multiple | | | | | | | | | | | | X | | | | 1
Stomach, glandular | A
Tongue | + | | | | | | | | | | | | | | | 1
Tooth | | | + | | | | | | | | | | | | | 1
Cardiovascular System
Blood vessel | + | | | | | | | | | | | | | | | 1
Heart | A
Endocrine System
Adrenal cortex | + | | | | | | | | | | | | | | | 1
Adrenal medulla | + | | | | | | | | | | | | | | | 1
Islets, pancreatic | + | | | | | | | | | | | | | | | 1
Parathyroid gland | M
Pituitary gland | M
Thyroid gland | A
General Body System
None
Genital System
Clitoral gland | + | | | | | | | | | | | | | | | 1
Ovary | A | | A | | | | | | | | | | | + | | 1
Uterus | A | | | | | + | | + | | | | | | | | 2
Vagina | A
Hematopoietic System
Bone marrow | + | | | | | | | | | | | | | | | 1
Lymph node, mandibular | + | | | | | | | | | | | | | | | 1
Lymph node, mesenteric | A
Spleen | A
Thymus | + | | | | | | | | | | | | | | | 1
Integumentary System
Mammary gland | + | | | | | | | | | | | | | | | 1
Skin | + | | | + | + | | | | | | + | | | + | | 5
Squamous cell papilloma | | | | | X | | | | | | | X | | | | 2
Vulva, squamous cell papilloma | | | | X | | | | | | | | | | X | | 2
Musculoskeletal System
Bone | + | | + | | | | | | | | | | | | | 2
Skeletal muscle | + | | | | | | | | | | | | | | | 1
Nervous System
Brain | + | | | | | | | | | | | | | | | 1
Respiratory System
Larynx | + | | | | | | | | | | | | | | | 1
Lung | A
Nose | + | | | | | | | | | | | | | | | 1
Trachea | + | | | | | | | | | | | | | | | 1
Special Senses System
Eye | A
Harderian gland | + | | | | | | | | | | | | | | | 1
Zymbal’s gland | + | | | | | | | | | | | | | | | 1
Urinary System
Kidney | + | | | | | | | | | | | | | | | 1
Urinary bladder | A | | A
Systemic Lesions
Multiple organs | + | + | + | + | + | + | | + | + | + | + | + | + | + | + | 14
Leukemia erythrocytic | | X | | | | | | | | | | | | | | 1

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium: 1%

Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 0 | 3 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 7 | 2 | 0 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 1 | 1 | 1 | 0 | 0 | 0 | 0 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 2 | Total Tissues/Tumors
Carcass ID Number | 6 | 1 | 3 | 6 | 7 | 8 | 9 | 0 | 2 | 4 | 5 | 7 | 8 | 9 | 0 | Total Tissues/Tumors
Alimentary System
Mesentery | | | + | | | | | | | | | | | | | 1
Stomach, forestomach | | + | + | + | + | + | + | | | + | + | + | | + | | 10
Squamous cell papilloma | | X | X | X | X | X | X | | | | X | X | | X | | 9
Tooth | + | + | | | + | | + | + | + | | | | | | | 6
Odontogenic tumor | X | X | | | X | | X | X | X | | | | | | | 6
Cardiovascular System
None
Endocrine System
None
General Body System
None
Genital System
Uterus | | | | | + | | | | | | | | | | | 1
Hematopoietic System
Spleen | | | + | | | | | + | | | + | | | | | 3
Integumentary System
Skin | | | | | + | + | | | | | + | + | | + | + | 6
Squamous cell papilloma | | | | | X | | | | | | | X | | X | | 3
Lip, squamous cell papilloma | | | | | | | | | | | X | | | X | | 2
Vulva, squamous cell papilloma | | | | | | X | | | | | | | | | X | 2
Musculoskeletal System
Bone | | | | | | + | | | | | | | | | | 1
Nervous System
None
Respiratory System
None
Special Senses System
None
Urinary System
None
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | | + | + | 14

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium: 3%

Number of Days on Study | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 5 | 3 | 5 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 6 | 2 | 5 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 3 | 3 | 3 | 3 | 3 | 3 | Total Tissues/Tumors
Carcass ID Number | 4 | 1 | 9 | 2 | 3 | 5 | 6 | 7 | 8 | 0 | 1 | 2 | 3 | 4 | 5 | Total Tissues/Tumors
Alimentary System
Esophagus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Gallbladder | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine large, colon | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine large, rectum | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine large, cecum | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine small, duodenum | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine small, jejunum | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine small, ileum | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pancreas | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Squamous cell papilloma | | | | | X | X | | X | X | | | X | X | X | X | 8
Stomach, glandular | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Tongue | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tooth | + | + | + | | | | | | | | | | + | | | 4
Odontogenic tumor | X | X | | | | | | | | | | | X | | | 3
Cardiovascular System
Blood vessel | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Islets, pancreatic | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Parathyroid gland | M | M | + | M | + | + | M | M | + | M | M | M | M | + | + | 6
Pituitary gland | + | + | I | + | + | + | + | + | + | + | + | + | + | + | + | 14
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Clitoral gland | + | M | + | + | + | + | + | + | + | M | I | + | + | + | + | 12
Ovary | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Uterus | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Sarcoma stromal | | | | | | | | | | | | | | | X | 1
Vagina | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Bone marrow | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | M | + | + | + | + | + | + | 14
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | M | + | + | + | + | + | + | + | + | + | + | + | + | 14
Integumentary System
Mammary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | X | | | | | | | | | | | | 1
Vulva, squamous cell papilloma | | | | | | | | | X | | | X | X | | | 3
Musculoskeletal System
Bone | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Larynx | + | I | + | I | + | I | + | + | + | I | + | + | + | + | + | 11
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Alveolar/bronchiolar adenoma | | | | | | | | | | X | | | | | | 1
Nose | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Trachea | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
Ear | | | | | | | | | | | + | | | | + | 2
Eye | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Zymbal’s gland | + | + | + | M | + | + | + | + | M | M | I | M | + | + | + | 10
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Transitional epithelium, papilloma | | | | | | | | | | | | | | | X | 1
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | | | X | | | | | | | | | | | | | 1

+: Tissue examined microscopically | M: Missing tissue | X: Lesion present
A: Autolysis precludes examination | I: Insufficient tissue | Blank: Not examined

TABLE B3 Statistical Analysis of Primary Neoplasms in Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium

| 0% | 0.3% | 1% | 3%
Lung: Alveolar/bronchiolar Adenoma
Overall rate^a^ | 1/15 (7%) | 0/0 | 0/0 | 1/15 (7%)
Adjusted rate^b^ | 7.2% | 0.0% | 0.0% | 7.4%
Terminal rate^c^ | 1/12 (8%) | 0/0 | 0/0 | 1/12 (8%)
First incidence (days) | 274 (T) | —^e^ | — | 274 (T)
Poly-3 test^d^ | —^f^ | — | — | P=0.757
Skin: Squamous Cell Papilloma
Overall rate | 3/15 (20%) | 4/15 (27%) | 6/15 (40%) | 4/15 (27%)
Adjusted rate | 21.1% | 30.3% | 42.9% | 29.4%
Terminal rate | 2/12 (17%) | 4/12 (33%) | 6/12 (50%) | 4/12 (33%)
First incidence (days) | 236 | 274 (T) | 274 (T) | 274 (T)
Poly-3 test | P=0.489 | P=0.456 | P=0.201 | P=0.473
Stomach (Forestomach): Squamous Cell Papilloma
Overall rate | 9/15 (60%) | 7/15 (47%) | 9/15 (60%) | 8/15 (53%)
Adjusted rate | 62.9% | 53.0% | 62.4% | 58.8%
Terminal rate | 8/12 (67%) | 7/12 (58%) | 7/12 (58%) | 8/12 (67%)
First incidence (days) | 224 | 274 (T) | 232 | 274 (T)
Poly-3 test | P=0.581N | P=0.446N | P=0.637N | P=0.567N
Tooth: Odontogenic Tumor
Overall rate | 2/15 (13%) | 0/15 (0%) | 6/15 (40%) | 3/15 (20%)
Adjusted rate | 14.1% | 0.0% | 40.1% | 20.3%
Terminal rate | 1/12 (8%) | 0/12 (0%) | 4/12 (33%) | 1/12 (8%)
First incidence (days) | 236 | — | 207 | 156
Poly-3 test | P=0.319 | P=0.248N | P=0.120 | P=0.519
All Organs: Erythrocytic Leukemia
Overall rate | 2/15 (13%) | 1/15 (7%) | 0/15 (0%) | 1/15 (7%)
Adjusted rate | 13.6% | 7.2% | 0.0% | 7.3%
Terminal rate | 0/12 (0%) | 0/12 (0%) | 0/12 (0%) | 0/12 (0%)
First incidence (days) | 224 | 196 | — | 255
Poly-3 test | P=0.501N | P=0.521N | P=0.242N | P=0.522N
All Organs: Benign Neoplasms
Overall rate | 11/15 (73%) | 9/15 (60%) | 10/15 (67%) | 10/15 (67%)
Adjusted rate | 75.0% | 68.2% | 69.3% | 73.5%
Terminal rate | 9/12 (75%) | 9/12 (75%) | 8/12 (67%) | 10/12 (83%)
First incidence (days) | 224 | 274 (T) | 232 | 274 (T)
Poly-3 test | P=0.569 | P=0.509N | P=0.528N | P=0.635N
All Organs: Malignant Neoplasms
Overall rate | 3/15 (20%) | 1/15 (7%) | 0/15 (0%) | 2/15 (13%)
Adjusted rate | 20.0% | 7.2% | 0.0% | 14.5%
Terminal rate | 0/12 (0%) | 0/12 (0%) | 0/12 (0%) | 1/12 (8%)
First incidence (days) | 224 | 196 | — | 255
Poly-3 test | P=0.623N | P=0.329N | P=0.119N | P=0.540N
All Organs: Benign or Malignant Neoplasms
Overall rate | 13/15 (87%) | 10/15 (67%) | 13/15 (87%) | 13/15 (87%)
Adjusted rate | 86.7% | 72.3% | 86.7% | 86.7%
Terminal rate | 10/12 (83%) | 9/12 (75%) | 10/12 (83%) | 10/12 (83%)
First incidence (days) | 224 | 196 | 207 | 156
Poly-3 test | P=0.443 | P=0.311N | P=0.698 | P=0.698

(T) Terminal sacrifice

a Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for lung; for other tissues, denominator is number of animals necropsied.

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal sacrifice. A negative trend or a lower incidence in an exposed group is indicated by N.

e Not applicable; no neoplasms in animal group

f Value of statistic cannot be computed

TABLE B4 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium^a^

| 0% | 0.3% | 1% | 3%
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 1 | | 2 | 2
Natural deaths | 2 | 3 | 1 | 1
Survivors
Terminal sacrifice | 12 | 12 | 12 | 12
Animals examined microscopically | 15 | 14 | 14 | 15
Alimentary System
Liver | (15) | (2) | | (15)
Inflammation, chronic | 2 (13%) | | | 3 (20%)
Necrosis, focal | 1 (7%)
Tension lipidosis, focal | | | | 1 (7%)
Hepatocyte, inflammation, chronic | 1 (7%)
Hepatocyte, necrosis, focal | 2 (13%) | | | 3 (20%)
Mesentery | (2) | | (1)
Fat, inflammation, acute, focal | | | 1 (100%)
Fat, necrosis, focal | 2 (100%)
Tongue | (15) | (1) | | (15)
Ulcer | 1 (7%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (14) | (1) | | (15)
Subcapsular, hyperplasia, focal | 9 (64%) | | | 6 (40%)
Zona reticularis, vacuolization cytoplasmic | 9 (64%) | | | 10 (67%)
General Body System
None
Genital System
Uterus | (13) | (2) | (1) | (14)
Endometrium, hyperplasia, cystic | 7 (54%) | 2 (100%) | 1 (100%) | 10 (71%)
Vagina | (13) | | | (15)
Hyperplasia | 1 (8%)
Hematopoietic System
Lymph node, mandibular | (12) | (1) | | (15)
Hyperplasia | 1 (8%) | | | 3 (20%)
Spleen | (15) | | (3) | (15)
Hematopoietic cell proliferation | 12 (80%) | | 3 (100%) | 13 (87%)
Pigmentation | 3 (20%) | | | 2 (13%)
Thymus | (11) | (1) | | (14)
Atrophy, diffuse | 1 (9%) | | | 1 (7%)
Integumentary System
None
Musculoskeletal System
Bone | (14) | (2) | (1) | (15)
Mandible, inflammation, chronic active | | 1 (50%) | | 1 (7%)
Nervous System
None
Respiratory System
Lung | (15) | | | (15)
Hemorrhage, focal | | | | 1 (7%)
Special Senses System
Eye | (13) | | | (14)
Retina, atrophy | 13 (100%) | | | 14 (100%)
Harderian gland | (14) | (1) | | (15)
Infiltration cellular, focal, lymphocyte | 1 (7%)
Urinary System
Kidney | (15) | (1) | | (15)
Renal tubule, dilatation, focal | | | | 1 (7%)

a Number of animals examined microscopically at the site and the number of animals with lesion