# APPENDIX A SUMMARY OF LESIONS IN MALE Tg.AC HEMIZYGOUS MICE IN THE 9-MONTH FEED STUDY OF ACESULFAME POTASSIUM

TABLE A1 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium^a^

| 0% | 0.3% | 1% | 3%
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 4 | 2 | 1
Survivors
Terminal sacrifice | 13 | 11 | 13 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | | (1) | (15)
Stomach, forestomach | (15) | (6) | (3) | (15)
Squamous cell papilloma | 5 (33%) | 4 (67%) | 2 (67%) | 6 (40%)
Tooth | (4) | (3) | | (2)
Odontogenic tumor | 4 (100%) | 3 (100%) | | 1 (50%)
Cardiovascular System
None
Endocrine System
Thyroid gland | (15) | | | (15)
Adenoma | 1 (7%)
General Body System
None
Genital System
None
Hematopoietic System
Bone marrow | (15) | | | (15)
Spleen | (15) | (1) | (1) | (15)
Integumentary System
Skin | (15) | (7) | (8) | (15)
Squamous cell papilloma | 1 (7%) | 1 (14%) | 2 (25%) | 4 (27%)
Dermis, mast cell tumor benign | 1 (7%)
Lip, squamous cell papilloma | 2 (13%) | 3 (43%) | 5 (63%) | 2 (13%)
Pinna, squamous cell papilloma | | | 1 (13%)
Prepuce, squamous cell papilloma | 1 (7%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15)
Alveolar/bronchiolar adenoma | 1 (7%) | 1 (7%) | | 2 (13%)
Special Senses System
Harderian gland | (15) | | | (15)
Adenoma | | | | 1 (7%)
Urinary System
None
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15)
Leukemia erythrocytic | | | 1 (7%) | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 12 | 10 | 10 | 10
Total primary neoplasms | 16 | 12 | 11 | 17
Total animals with benign neoplasms | 9 | 8 | 9 | 9
Total benign neoplasms | 12 | 9 | 10 | 15
Total animals with malignant neoplasms | | | 1 | 1
Total malignant neoplasms | | | 1 | 1
Total animals with uncertain neoplasms-benign or malignant | 4 | 3
Total uncertain neoplasms | 4 | 3 | | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A2

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium: 0%

Number of Days on Study | 1 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 4 | 5 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 8 | 7 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 1 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 2 | 6 | 1 | 2 | 3 | 4 | 5 | 7 | 8 | 9 | 0 | 1 | 3 | 4 | 5 | Total Tissues/Tumors
Alimentary System
Esophagus | + | + | + | + | + | + | + | + | + | + | + | + | + | M | + | 14
Gallbladder | + | + | + | + | + | M | + | M | + | + | I | + | + | + | M | 11
Intestine large, colon | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, rectum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, cecum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, duodenum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, jejunum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | A | 14
Intestine small, ileum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Mesentery | | | | | | | | + | | | | | | + | | 2
Pancreas | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | X | | X | | | | X | | | X | | | X | 5
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tongue | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tooth | + | + | | | | | | | + | | + | | | | | 4
Odontogenic tumor | X | X | | | | | | | X | | X | | | | | 4
Cardiovascular System
Blood vessel | M | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | M | 14
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | M | 14
Islets, pancreatic | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Parathyroid gland | M | M | + | M | + | M | M | I | M | M | + | M | M | M | M | 3
Pituitary gland | + | + | + | + | + | + | + | + | + | M | I | + | + | + | + | 13
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adenoma | | | | | | | | | | | | | | X | | 1
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Penis | | + | | | | | | | | | | | | | | 1
Preputial gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Prostate | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Seminal vesicle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Bone marrow | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mandibular | + | + | + | + | + | + | + | + | M | + | + | + | + | + | + | 14
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | M | + | 14
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | X | | | | | | | | | | | | 1
Dermis, mast cell tumor benign | | | | | | | | | | X | | | | | | 1
Lip, squamous cell papilloma | | | | X | | | | X | | | | | | | | 2
Prepuce, squamous cell papilloma | | | | | | | | | | | | | | X | | 1
Musculoskeletal System
Bone | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Larynx | I | + | + | + | + | + | + | + | + | + | + | + | + | M | + | 13
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Alveolar/bronchiolar adenoma | | | | | | | | | | | | X | | | | 1
Nose | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Trachea | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
Eye | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Zymbal’s gland | M | + | + | + | + | + | + | M | M | M | M | M | I | + | M | 7
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium: 0.3%

Number of Days on Study | 0 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 4 | 3 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 1 | 8 | 3 | 1 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 3 | 2 | 2 | 2 | 1 | 1 | 1 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 0 | 2 | 1 | 3 | 6 | 7 | 8 | 9 | 0 | 4 | 5 | 6 | 7 | 8 | 9 | Total Tissues/Tumors
Alimentary System
Stomach, forestomach | | | + | | | | + | + | | + | + | | + | | | 6
Squamous cell papilloma | | | X | | | | X | | | X | | | X | | | 4
Tooth | + | + | + | | | | | | | | | | | | | 3
Odontogenic tumor | X | X | X | | | | | | | | | | | | | 3
Cardiovascular System
None
Endocrine System
None
General Body System
None
Genital System
Penis | | | + | | | | | | | | | | | | | 1
Hematopoietic System
Spleen | | | | + | | | | | | | | | | | | 1
Integumentary System
Skin | | | | + | + | + | | + | | + | | | + | + | | 7
Squamous cell papilloma | | | | | | | | | | | | | | X | | 1
Lip, squamous cell papilloma | | | | | X | X | | | | X | | | | | | 3
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Alveolar/bronchiolar adenoma | | | | | | | | | | | X | | | | | 1
Special Senses System
None
Urinary System
Kidney | | | | + | | | | | | | | | | | | 1
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium: 1%

Number of Days on Study | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 9 | 6 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 2 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 4 | 4 | 4 | 4 | 4 | 4 | Total Tissues/Tumors
Carcass ID Number | 5 | 4 | 1 | 2 | 3 | 6 | 7 | 8 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | Total Tissues/Tumors
Alimentary System
Liver | + | | | | | | | | | | | | | | | 1
Stomach, forestomach | | | | + | | + | | | | | | | + | | | 3
Squamous cell papilloma | | | | | | X | | | | | | | X | | | 2
Cardiovascular System
None
Endocrine System
None
General Body System
None
Genital System
Preputial gland | | | + | | | | | | | | | | | | | 1
Hematopoietic System
Spleen | + | | | | | | | | | | | | | | | 1
Integumentary System
Skin | | + | | | + | | + | + | | + | + | | + | | + | 8
Squamous cell papilloma | | | | | | | | | | | | | X | | X | 2
Lip, squamous cell papilloma | | | | | X | | X | X | | X | X | | | | | 5
Pinna, squamous cell papilloma | | X | | | | | | | | | | | | | | 1
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
None
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | X | | | | | | | | | | | | | | | 1

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium: 3%

Number of Days on Study | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 2 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 5 | 4 | 4 | 4 | 4 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | Total Tissues/Tumors
Carcass ID Number | 8 | 6 | 7 | 8 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 9 | 0 | Total Tissues/Tumors
Alimentary System
Esophagus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Gallbladder | + | + | + | A | A | + | + | + | + | + | + | + | + | + | + | 13
Intestine large, colon | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, rectum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, cecum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, duodenum | + | + | + | A | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine small, jejunum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, ileum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Mesentery | | | | | | | | | | | | | | + | + | 2
Pancreas | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | X | | | X | X | X | | | X | | | X | 6
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | M | + | 14
Tongue | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tooth | + | | | | | | | | + | | | | | | | 2
Odontogenic tumor | | | | | | | | | X | | | | | | | 1
Cardiovascular System
Blood vessel | + | + | + | + | + | + | + | + | + | + | + | M | + | + | + | 14
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Islets, pancreatic | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Parathyroid gland | M | M | I | M | + | M | M | M | M | M | + | M | M | M | M | 2
Pituitary gland | I | + | I | + | + | + | + | + | + | + | + | I | + | I | + | 11
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Coagulating gland | | | | | | | | | | | | + | | | | 1
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Preputial gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Prostate | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Seminal vesicle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Bone marrow | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | M | + | + | + | + | + | + | 14
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | M | 14
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | | | X | X | | | | | X | X | | 4
Lip, squamous cell papilloma | | | | X | | | | | | | | | | X | | 2
Musculoskeletal System
Bone | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Larynx | I | + | + | + | I | + | + | M | + | + | M | I | + | I | I | 8
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Alveolar/bronchiolar adenoma | | | X | | | | | | | | | | | X | | 2
Nose | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Trachea | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
Eye | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adenoma | | | | | | | | | | | | X | | | | 1
Zymbal’s gland | + | M | + | + | M | + | M | + | + | + | + | + | M | + | M | 10
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | X | | | | | | | | | | | | | | | 1

+: Tissue examined microscopically | M: Missing tissue | X: Lesion present
A: Autolysis precludes examination | I: Insufficient tissue | Blank: Not examined

TABLE A3 Statistical Analysis of Primary Neoplasms in Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium

| 0% | 0.3% | 1% | 3%
Lung: Alveolar/bronchiolar Adenoma
Overall rate^a^ | 1/15 (7%) | 1/15 (7%) | 0/15 (0%) | 2/15 (13%)
Adjusted rate^b^ | 7.5% | 7.8% | 0.0% | 14.0%
Terminal rate^c^ | 1/13 (8%) | 1/11 (9%) | 0/13 (0%) | 2/14 (14%)
First incidence (days) | 274 (T) | 274 (T) | —^e^ | 274 (T)
Poly-3 test^d^ | P=0.351 | P=0.752 | P=0.487N | P=0.523
Skin: Squamous Cell Papilloma
Overall rate | 3/15 (20%) | 4/15 (27%) | 8/15 (53%) | 5/15 (33%)
Adjusted rate | 22.5% | 31.4% | 55.8% | 35.1%
Terminal rate | 3/13 (23%) | 4/11 (36%) | 7/13 (54%) | 5/14 (36%)
First incidence (days) | 274 (T) | 274 (T) | 264 | 274 (T)
Poly-3 test | P=0.429 | P=0.473 | P=0.075 | P=0.381
Stomach (Forestomach): Squamous Cell Papilloma
Overall rate | 5/15 (33%) | 4/15 (27%) | 2/15 (13%) | 6/15 (40%)
Adjusted rate | 37.5% | 30.4% | 14.1% | 42.1%
Terminal rate | 5/13 (39%) | 3/11 (27%) | 2/13 (15%) | 6/14 (43%)
First incidence (days) | 274 (T) | 233 | 274 (T) | 274 (T)
Poly-3 test | P=0.359 | P=0.511N | P=0.164N | P=0.554
Tooth: Odontogenic Tumor
Overall rate | 4/15 (27%) | 3/15 (20%) | 0/15 (0%) | 1/15 (7%)
Adjusted rate | 26.7% | 20.0% | 0.0% | 7.0%
Terminal rate | 2/13 (15%) | 0/11 (0%) | 0/13 (0%) | 1/14 (7%)
First incidence (days) | 148 | 71 | — | 274 (T)
Poly-3 test | P=0.118N | P=0.501N | P=0.051N | P=0.179N
All Organs: Erythrocytic Leukemia
Overall rate | 0/15 (0%) | 0/15 (0%) | 1/15 (7%) | 1/15 (7%)
Adjusted rate | 0.0% | 0.0% | 6.7% | 6.7%
Terminal rate | 0/13 (0%) | 0/11 (0%) | 0/13 (0%) | 0/14 (0%)
First incidence (days) | — | — | 192 | 172
Poly-3 test | P=0.352 | —^f^ | P=0.522 | P=0.523
All Organs: Benign Neoplasms
Overall rate | 9/15 (60%) | 8/15 (53%) | 9/15 (60%) | 9/15 (60%)
Adjusted rate | 67.4% | 60.9% | 62.7% | 63.2%
Terminal rate | 9/13 (69%) | 7/11 (64%) | 8/13 (62%) | 9/14 (64%)
First incidence (days) | 274 (T) | 233 | 264 | 274 (T)
Poly-3 test | P=0.561N | P=0.521N | P=0.555N | P=0.564N
All Organs: Malignant Neoplasms
Overall rate | 0/15 (0%) | 0/15 (0%) | 1/15 (7%) | 1/15 (7%)
Adjusted rate | 0.0% | 0.0% | 6.7% | 6.7%
Terminal rate | 0/13 (0%) | 0/11 (0%) | 0/13 (0%) | 0/14 (0%)
First incidence (days) | — | — | 192 | 172
Poly-3 test | P=0.352 | — | P=0.522 | P=0.523
All Organs: Benign or Malignant Neoplasms
Overall rate | 12/15 (80%) | 10/15 (67%) | 10/15 (67%) | 10/15 (67%)
Adjusted rate | 80.0% | 66.8% | 66.7% | 66.7%
Terminal rate | 10/13 (77%) | 7/11 (64%) | 8/13 (62%) | 9/14 (64%)
First incidence (days) | 148 | 71 | 192 | 172
Poly-3 test | P=0.392N | P=0.346N | P=0.343N | P=0.343N

(T) Terminal sacrifice

a Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for lung; for other tissues, denominator is number of animals necropsied.

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal sacrifice. A negative trend or a lower incidence in an exposed group is indicated by N.

e Not applicable; no neoplasms in animal group

f Value of statistic cannot be computed

TABLE A4 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Acesulfame Potassium^a^

| 0% | 0.3% | 1% | 3%
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 4 | 2 | 1
Survivors
Terminal sacrifice | 13 | 11 | 13 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | | (1) | (15)
Hematopoietic cell proliferation | 1 (7%)
Inflammation, chronic | 1 (7%)
Hepatocyte, necrosis, focal | 1 (7%)
Mesentery | (2) | | | (2)
Fat, necrosis, focal | 2 (100%) | | | 2 (100%)
Pancreas | (15) | | | (15)
Inflammation, chronic active | 1 (7%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (14) | | | (15)
Atrophy | 10 (71%) | | | 11 (73%)
Hypertrophy, focal | 9 (64%) | | | 5 (33%)
General Body System
None
Genital System
Preputial gland | (15) | | (1) | (15)
Cyst | 1 (7%) | | 1 (100%)
Testes | (15) | | | (15)
Germinal epithelium, degeneration, focal | 1 (7%) | | | 1 (7%)
Hematopoietic System
Bone marrow | (15) | | | (15)
Hyperplasia | | | | 1 (7%)
Lymph node, mandibular | (14) | | | (15)
Hyperplasia | 2 (14%) | | | 2 (13%)
Spleen | (15) | (1) | (1) | (15)
Atrophy | 1 (7%)
Hematopoietic cell proliferation | 10 (67%) | 1 (100%) | | 7 (47%)
Thymus | (15) | | | (14)
Atrophy, diffuse | 3 (20%) | | | 2 (14%)
Atrophy, focal | 2 (13%)
Integumentary System
Skin | (15) | (7) | (8) | (15)
Sebaceous gland, hyperplasia, focal | 1 (7%)
Subcutaneous tissue, pinna, inflammation, acute, focal | | 1 (14%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15)
Alveolar epithelium, alveolus, inflammation, chronic active, focal | | | | 1 (7%)
Nose | (15) | | | (15)
Glands, hyperplasia | 1 (7%)
Special Senses System
Eye | (15) | | | (15)
Retina, atrophy | 15 (100%) | | | 14 (93%)
Urinary System
Kidney | (15) | (1) | | (15)
Infiltration cellular, plasma cell | | 1 (100%)
Renal tubule, dilatation, diffuse | | | | 1 (7%)
Renal tubule, dilatation, focal | | | | 2 (13%)
Urinary bladder | (15) | | | (15)
Edema | 1 (7%)

a Number of animals examined microscopically at the site and the number of animals with lesion