# REFERENCES

Alnouti, Y., Lewis, S.R., White, C.A., and Bartlett, M.G. (2005). Simultaneous determination of zidovudine and lamivudine from rat tissues by liquid chromatography/tandem mass spectrometry. Rapid Commun. Mass Spectrom. 19, 503–508.15678520
Anderson, L.M. (2004). Predictive values of traditional animal bioassay studies for human perinatal carcinogenesis risk determination. Toxicol. Appl. Pharmacol. 199, 162–174.15313588
Andric, N.L., Kostic, T.S., Zoric, S.N., Stanic, B.D., Andric, S.A., and Kovacevic, R.Z. (2006). Effects of PCB-based transformer oil on testicular steroidogenesis and xenobiotic-metabolizing enzymes. Reprod. Toxicol. 22, 102–110.16439096
Anonymous (1987). Zidovudine approved by FDA for treatment of AIDS. Clin. Pharm. 6, 431–435.3319360
Anonymous (2007) FDA notifications. FDA approves generic AZT. AIDS Alert 22, 79.
Antunes, A.M., Duarte, M.P., Santos, P.P., da Costa, G.G., Heinze, T.M., Beland, F.A., and Marques, M.M. (2008). Synthesis and characterization of DNA adducts from the HIV reverse transcriptase inhibitor nevirapine. Chem. Res. Toxicol. 21, 1443–1456.18597499
Arnaudo, E., Dalakas, M.C., Shanske, S., Moraes, C.T., DiMauro, S., and Schon, E.A. (1991). Depletion of muscle mitochondrial DNA in AIDS patients with zidovudine-induced myopathy. Lancet 337, 508–510.1671889
Artandi, S.E., Chang, S., Lee, S.L., Alson, S., Gottlieb, G.J., Chin, L., and DePinho, R.A. (2000). Telomere dysfunction promotes non-reciprocal trans-locations and epithelial cancers in mice. Nature 406, 641–645.10949306
Avramis, V.I., Markson, W., Jackson, R.L., and Gomperts, E. (1989). Biochemical pharmacology of zidovudine in human T-lymphoblastoid cells (CEM). AIDS 3, 417–422.2504244
Ayers, K.M. (1988). Preclinical toxicology of zidovudine. Am. J. Med. 85 (Suppl. 2A), 186–188.3044084
Ayers, K.M., Tucker, W.E., Hajian, G., and de Miranda, P. (1996a). Nonclinical toxicology studies with zidovudine; acute, subacute, and chronic toxicity in rodents, dogs, and monkeys. Fundam. Appl. Toxicol. 32, 129–139.8921316
Ayers, K.M., Clive, D., Tucker, W.E., Jr., Hajian, G., and de Miranda, P. (1996b). Nonclinical toxicology studies with zidovudine: Genetic toxicity tests and carcinogenicity bioassays in mice and rats. Fundam. Appl. Toxicol. 32, 148–158.8921318
Ayers, K.M., Torrey, C.E., and Reynolds, D.J. (1997). A transplacental carcinogenicity bioassay in CD-1 mice with zidovudine. Fundam. Appl. Toxicol. 38, 195–198.9299194
Bailer, A.J., and Portier, C.J. (1988). Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics 44, 417–431.3390507
Balzarini, J. (1994). Metabolism and mechanism of antiretroviral action of purine and pyrimidine derivatives. Pharm. World Sci. 16, 113–126.8032337
Barret, B., Tardieu, M., Rustin, P., Lacroix, C., Chabrol, B., Desguerre, I., Dollfus, C., Mayaux, M.J., and Blanche, S., for the French Perinatal Cohort Study Group (2003). Persistent mitochondrial dysfunction in HIV-1-exposed but uninfected infants: Clinical screening in a large prospective cohort. AIDS 17, 1769–1785.12891063
Beach, J.W., Jeong, L.S., Alves, A.J., Pohl, D., Kim, H.O., Chang, C.-N., Doong, S.-L., Schinazi, R.F., Cheng, Y.-C., and Chu, C.K. (1992). Synthesis of enantiomerically pure (2′R,5′S)-(-)-1-[2-hydroxymethyl) oxathiolan-5-yl]cytosine as a potent antiviral agent against hepatitis B virus (HBV) and human immuno-deficiency virus (HIV). J. Org. Chem. 57, 2217–2219.
Bieler, G.S., and Williams, R.L. (1993). Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics 49, 793–801.8241374
Binder, D.A. (1992). Fitting Cox’s proportional hazards models from survey data. Biometrika 79, 139–147.
Bishop, J.B., Tani, Y., Witt, K., Johnson, J.A., Peddada, S., Dunnick, J., and Nyska, A. (2004a). Mitochondrial damage revealed by morphometric and semiquantitative analysis of mouse pup cardiomyocytes following in utero and postnatal exposure to zidovudine and lamivudine. Toxicol. Sci. 81, 512–517.15229369
Bishop, J.B., Witt, K.L., Tice, R.R., and Wolfe, G.W. (2004b). Genetic damage detected in CD-1 mouse pups exposed to 3′-azido-3′-deoxythymidine and dideoxyinosine via maternal dosing, nursing, and direct gavage. Environ. Mol. Mutagen. 43, 3–9.14743340
Blanche, S., Tardieu, M., Rustin, P., Slama, A., Barret, B., Firtion, G., Ciraru-Vigneron, N., Lacroix, C., Rouzioux, C., Mandelbrot, L., Desguerre, I., Rötig, A., Mayaux, M.J., and Delfraissy, J.F. (1999). Persistent mitochondrial dysfunction and perinatal exposure to antiretroviral nucleoside analogues. Lancet 354, 1084–1089.10509500
Blaney, S.M., Daniel, M.J., Harker, A.J., Godwin, K., and Balis, F.M. (1995). Pharmacokinetics of lamivudine and BCH-189 in plasma and cerebrospinal fluid of nonhuman primates. Antimicrob. Agents Chemother. 39, 2779–2782.8593019
Boehmer, U., Miao, X., and Ozonoff, A. (2012). Reply to cancer survivorship and sexual orientation. Cancer 118, 1468–1469
Boorman, G.A., Montgomery, C.A., Jr., Eustis, S.L., Wolfe, M.J., McConnell, E.E., and Hardisty, J.F. (1985). Quality assurance in pathology for rodent carcinogenicity studies. In Handbook of Carcinogen Testing (H.A. Milman and E.K. Weisburger, Eds.), pp. 345–357. Noyes Publications, Park Ridge, NJ.
Bradshaw, P.C., Li, J., and Samuels, D.C. (2005). A computational model of mitochondrial AZT metabolism. Biochem. J. 392, 363–373.16060859
Brinkman, K., Smeitink, J.A., Romijn, J.A., and Reiss, P. (1999). Mitochondrial toxicity induced by nucleoside-analogue reverse-transcriptase inhibitors is a key factor in the pathogenesis of antiretroviral-therapy-related lipodystrophy. Lancet 354, 1112–1115.10509516
Brogly, S.B., Ylitalo, N., Mofenson, L.M., Oleske, J., Van Dyke, R., Crain, M.J., Abzug, M.J., Brady, M., Jean-Philippe, P., Hughes, M.D., and Seage, G.R., III (2007). In utero nucleoside reverse transcriptase inhibitor exposure and signs of possible mitochondrial dysfunction in HIV-uninfected children. AIDS 21, 929–938.17457086
Brook, I. (1987). Approval of zidovudine (AZT) for acquired immunodeficiency syndrome. A challenge to the medical and pharmaceutical communities. JAMA 258, 1517.3306004
Bull, R.J., Sanchez, I.M., Nelson, M.A., Larson, J.L., and Lansing, A.J. (1990). Liver tumor induction in B6C3F1 mice by dichloroacetate and trichloroacetate. Toxicology 63, 341–359.2219130
Cammack, N., Rouse, P., Marr, C.L., Reid, P.J., Boehme, R.E., Coates, J.A., Penn, C.R., and Cameron, J.M. (1992). Cellular metabolism of (-) enantiomeric 2′-deoxy-3′-thiacytidine. Biochem. Pharmacol. 43, 2059–2064.1318048
Cansaran, D., Aras, S., Kandemir, I., and Gökhan, H.M. (2006). Phylogenetic relations of Rhizoplaca Zopf. from Anatolia inferred from ITS sequence data. Z. Naturforsch. C. 61, 405–412.16869500
Carter, M.M., Torres, S.M., Cook, D.L., Jr., McCash, C.L., Yu, M., Walker, V.E., and Walker, D.M. (2007). Relative mutagenic potencies of several nucleoside analogs, alone or in drug pairs, at the HPRT and TK loci of human TK6 lymphoblastoid cells. Environ. Mol. Mutagen. 48, 239–247.17358029
Chan, S.S., Santos, J.H., Meyer, J.N., Mandavilli, B.S., Cook, D.L., Jr., McCash, C.L., Kissling, G.E., Nyska, A., Foley, J.F., van Houten, B., Copeland, W.C., Walker, V.E., Witt, K.L., and Bishop, J.B. (2007). Mitochondrial toxicity in hearts of CD-1 mice following perinatal exposure to AZT, 3TC, or AZT/3TC in combination. Environ. Mol. Mutagen. 48, 190–200.16395692
Cheeseman, S.H., Hattox, S.E., McLaughlin, M.M., Koup, R.A., Andrews, C., Bova, C.A., Pav, J.W., Roy, T., Sullivan, J.L., and Keirns, J.J. (1993). Pharmacokinetics of nevirapine: Initial single-rising-dose study in humans. Antimicrob. Agents Chemother. 37, 178–182.8452345
Cheeseman, S.H., Havlir, D., McLaughlin, M.M., Greenough, T.C., Sullivan, J.L., Hall, D., Hattox, S.E., Spector, S.A., Stein, D.S., Myers, M., and Richman, D.D. (1995). Phase I/II evaluation of nevirapine alone and in combination with zidovudine for infection with human immunodeficiency virus. J. Acquir. Immune Defic. Syndr. Hum. Retrovirol. 8, 141–151.7530585
Chen, J., Mannargudi, B.M., Xu, L., and Uetrecht, J. (2008). Demonstration of the metabolic pathway responsible for nevirapine-induced skin rash. Chem. Res. Toxicol. 21, 1862–1870.18729332
Child, S., Montaner, J., Tsoukas, C., Fanning, M., Le, T., Wall, R.A., and Ruedy, J. (1991). Canadian multicenter azidothymidine trial: AZT pharmacokinetics. J. Acquir. Immune Defic. Syndr. 4, 865–870.1895207
Cleveland, W.S. (1979). Robust Locally Weighted Regression and Smoothing Scatterplots. J. Amer. Stat. Assoc. 74, 829–836.
Cleveland, W.S., Devlin, S.J., and Grosse, E. (1988). Regression by Local Fitting. J. Economet. 37, 87–114.
Code of Federal Regulations (CFR) 21, Part 58.
Cohen, K.A., Hopkins, J., Ingraham, R.H., Pargellis, C., Wu, J.C., Palladino, D.E.H., Kinkade, P., Warren, T.C., Rogers, S., Adams, J., Farina, P.R., and Grob, P.M. (1991). Characterization of the binding site for nevirapine (BI-RG-587), a nonnucleoside inhibitor of human immunodeficiency virus type-1 reverse transcriptase. J. Biol. Chem. 266, 14,670–14,674.
Comstock, K.E., Johnson, K.J., Rifenbery, D., and Henner, W.D. (1993). Isolation and analysis of the gene and cDNA for a human Mu class glutathione S-transferase, GSTM4. J. Biol. Chem. 268, 16,958–16,965.
Connor, E.M., Sperling, R.S., Gelber, R., Kiselev, P., Scott, G., O’Sullivan, M.J., VanDyke, R., Bey, M., Shearer, W., Jacobson, R.L., Jimenez, E., O’Neill, E., Bazin, B., Delfraissy, J-F., Culnane, M., Coombs, R., Elkins, M., Moye, J., Stratton, P., and Balsley, J. (1994). Reduction of maternal-infant transmission of human immunodeficiency virus type 1 with zidovudine treatment. Pediatric AIDS Clinical Trials Group Protocol 076 Study Group. N. Engl. J. Med. 331, 1173–1180.7935654
Corcuera Pindado, M.T., Lopez Bravo, A., Martinez-Rodriguez, R., Picazo Talavera, A., Gomez Aguado, F., Roldan Contreras, M., Perez Alvarez, M.J., Fernandez Garcia, A., and Alonso Martin, M.J. (1994). Histochemical and ultrastructural changes induced by zidovudine in mitochondria of rat cardiac muscle. Eur. J. Histochem. 38, 311–318.7535128
Cox, D.R. (1972). Regression models and life-tables. J. R. Stat. Soc. B34, 187–220.
Cretton, E.M., Schinazi, R.F., McClure, H.M., Anderson, D.C., and Sommadossi, J.-P. (1991). Pharmacokinetics of 3′-azido-3′-deoxythymidine and its catabolites and interactions with probenecid in rhesus monkeys. Antimicrob. Agents Chemother. 35, 801–807.1854160
Dainiak, N., Worthington, M., Riordan, M.A., Kreczko, S., and Goldman, L. (1988). 3′-Azido-3′-deoxythymidine (AZT) inhibits proliferation in vitro of human haematopoietic progenitor cells. Br. J. Haematol. 69, 299–304.3261597
Dalakas, M.C., Illa, I., Pezeshkpour, G.H., Laukaitis, J.P., Cohen, B., and Griffin, J.L. (1990). Mitochondrial myopathy caused by long-term zidovudine therapy. N. Engl. J. Med. 322, 1098–1105.2320079
DeAngelo, A.B., Daniel, F.B., Most, B.M., and Olson, G.R. (1996). The carcinogenicity of dichloroacetic acid in the male Fischer 344 rat. Toxicology 114, 207–221.8980710
de Miranda, P., Burnette, T.C., and Good, S.S. (1990). Tissue distribution and metabolic disposition of zidovudine in rats. Drug Metab. Dispos. 18, 315–320.1974192
Department of Health and Human Services (DHHS) (2008a). Panel on Antiretroviral Guidelines for Adults and Adolescents. Guidelines for the Use of Antiretroviral Agents in HIV-1-infected Adults and Adolescents. Department of Health and Human Services, Washington, DC.
Department of Health and Human Services (DHHS) (2008b). Working Group on Antiretroviral Therapy and Medical Management of HIV-Infected Children. Guidelines for the Use of Antiretroviral Agents in Pediatric HIV Infection. Department of Health and Human Services, Washington, DC.
Department of Health and Human Services (DHHS) (2009). AIDS Information and guidelines. <http://aidsinfo.nih.gov/guidelines/>
Department of Health and Human Services (DHHS) (2011). Panel on Antiretroviral Guidelines for Adults and Adolescents. Guidelines for the Use of Antiretroviral Agents in HIV-1-infected Adults and Adolescents. Department of Health and Human Services, Washington, DC.
Dertinger, S.D., Torous, D.K., and Tometsko, K.R. (1996a). Induction of micronuclei by low doses of azidothymidine (AZT). Mutat. Res. 368, 301–307.8692236
Dertinger, S.D., Torous, D.K., and Tometsko, K.R. (1996b) Simple and reliable enumeration of micronucleated reticulocytes with a single-laser flow cytometer. Mut. Res. 371, 283–292.9008730
Dertinger, S.D., Bishop, M.E., McNamee, J.P., Hayashi, M., Suzuki, T., Asano, N., Nakajima, M., Saito J., Moore, M., Torous, D.K., and Macgregor, J.T. (2006). Flow cytometric analysis of micronuclei in peripheral blood reticulocytes: I. Intra- and interlaboratory comparison with microscopic scoring. Toxicol. Sci. 94, 83–91.16888078
Deveaud, C., Beauvoit, B., Reynaud, A., and Bonnet, J. (2007). Site-specific reduction of oxidative and lipid metabolism in adipose tissue of 3′-azido-3′-deoxythymidine-treated rats. Antimicrob. Agents Chemother. 51, 583–590.17158934
Divi, R.L., Walker, V.E., Wade, N.A., Nagashima, K., Seilkop, S.K., Adams, M.E., Nesel, C.J., O’Neill, J.P., Abrams, E.J., and Poirier, M.C. (2004). Mitochondrial damage and DNA depletion in cord blood and umbilical cord from infants exposed in utero to Combivir. AIDS 18, 1013–1021.15096804
Divi, R.L., Leonard, S.L., Kuo, M.M., Walker, B.L., Orozco, C.C., St. Claire, M.C., Nagashima, K., Harbaugh, S.W., Harbaugh, J.W., Thamire, C., Sable, C.A., and Poirier, M.C. (2005). Cardiac mitochondrial compromise in 1-yr-old Erythrocebus patas monkeys perinatally-exposed to nucleoside reverse transcriptase inhibitors. Cardiovasc. Toxicol. 5, 333–346.16244378
Divi, R.L., Leonard, S.L., Kuo, M.M., Nagashima, K., Thamire, C., St. Claire, M.C., Wade, N.A., Walker, V.E., and Poirier, M.C. (2007a). Transplacentally exposed human and monkey newborn infants show similar evidence of nucleoside reverse transcriptase inhibitor-induced mitochondrial toxicity. Environ. Mol. Mutagen. 48, 201–209.16538687
Divi, R.L., Leonard, S.L., Walker, B.L., Kuo, M.M., Shockley, M.E., St. Claire, M.C., Nagashima, K., Harbaugh, S.W., Harbaugh, J.W., and Poirier, M.C. (2007b). Erythrocebus patas monkey offspring exposed perinatally to NRTIs sustain skeletal muscle mitochondrial compromise at birth and at 1 year of age. Toxicol. Sci. 99, 203–213.17545213
Divi, R.L., Doerge, D.R., Twaddle, N.C., Shockley, M.E., St. Claire, M.C., Harbaugh, J.W., Harbaugh, S.W., and Poirier, M.C. (2008). Metabolism and pharmacokinetics of the combination zidovudine plus lamivudine in the adult Erythrocebus patas monkey determined by liquid chromatography-tandem mass spectrometric analysis. Toxicol. Appl. Pharmacol. 226, 206–211.17949768
Diwan, B.A., Riggs, C.W., Logsdon, D., Haines, D.C., Olivero, O.A., Rice, J.M., Yuspa, S.H., Poirier, M.C., and Anderson, L.M. (1999). Multiorgan transplacental and neonatal carcinogenicity of 3′-azido-3′-deoxythymidine in mice. Toxicol. Appl. Pharmacol. 161, 82–99.10558926
Diwan, B.A., Olivero, O.A., and Poirier, M.C. (2000). Absence of structural or functional alterations in male and female reproductive organs of F_1_ and F_2_ generations derived from female mice exposed to 3′-azido-3′-deoxythymidine during pregnancy. Toxicol. Lett. 115, 9–15.10817626
Dobrovolsky, V.N., Shaddock, J.G., Mittelstaedt, R.A., Bishop, M.E., Lewis, S.M., Lee, F.W., Aidoo, A., Leakey, J.E., Dunnick, J.K., and Heflich, R.H. (2007). Frequency of Hprt mutant lymphocytes and micronucleated erythrocytes in p53-haplodeficient mice treated perinatally with AZT and AZT in combination with 3TC. Environ. Mol. Mutagen. 48, 270–282.17358030
Donehower, L.A., Harvey, M., Slagle, B.L., McArthur, M.J., Montgomery, C.A., Jr., Butel, J.S., and Bradley, A. (1992). Mice deficient for p53 are developmentally normal but susceptible to spontaneous tumours. Nature 356, 215–221.1552940
Donehower, L.A., Harvey, M., Vogle, H., McArthur, M.J., Montgomery, C.A., Jr., Park, S.H., Thompson, T., Ford, R.J., and Bradley, A. (1995). Effects of genetic background on tumorigenesis in p53-deficient mice. Mol. Carcinog. 14, 16–22.7546219
Donnerer, J., Haas, B.J., and Kessler, H.H. (2008). Single-measurement therapeutic drug monitoring of the HIV/AIDS drugs abacavir, zidovudine, lamivudine, efavirenz, nevirapine, lopinavir and nelfinavir. Pharmacology 82, 287–292.18931536
Doshi, K.J., Gallo, J.M., Boudinot, F.D., Schinazi, R.F., and Chu, C.K. (1989). Comparative pharmacokinetics of 3′-azido-3′-deoxythymidine (AZT) and 3′-azido-2′,3′-dideoxyuridine (AZddU) in mice. Drug Metab. Dispos. 17, 590–594.2575492
Dudley, M.N. (1995). Clinical pharmacokinetics of nucleoside antiretroviral agents. J. Infect. Dis. 171 (Suppl. 2), S99–S112.7861025
Dunnett, C.W. (1955). A multiple comparison procedure for comparing several treatments with a control. J. Am. Stat. Assoc. 50, 1096–1121.
Dunnick, J.K., Hardisty, J.F., Herbert, R.A., Seeley, J.C., Furedi-Machacek, E.M., Foley, J.F., Lacks, G.D., Stasiewicz, S., and French, J.E. (1997). Phenolphthalein induces thymic lymphomas accompanied by loss of the p53 wild type allele in heterozygous p53-deficient (±) mice. Toxicol. Pathol. 25, 533–540.9437796
Efron, B. (1977). The efficiency of Cox’s likelihood function for censored data. J. Am. Stat. Assoc. 72, 557–565.
Erickson, D.A., Mather, G., Trager, W.F., Levy, R.H., and Keirns, J.J. (1999). Characterization of the in vitro biotransformation of the HIV-1 reverse transcriptase inhibitor nevirapine by human hepatic cytochromes P-450. Drug Metab. Dispos. 27, 1488–1495.10570031
Escobar, P.A., Olivero, O.A., Wade, N.A., Abrams, E.J., Nesel, C.J., Ness, R.B., Day, R.D., Day, B.W., Meng, Q., O’Neill, J.P., Walker, D.M., Poirier, M.C., Walker, V.E., and Bigbee, W.L., for the Study Team (2007). Genotoxicity assessed by the comet and GPA assays following in vitro exposure of human lymphoblastoid cells (H9) or perinatal exposure of mother-child pairs to AZT or AZT-3TC. Environ. Mol. Mutagen. 48, 330–343.17358027
Ewings, E.L., Gerschenson, M., St. Claire, M.C., Nagashima, K., Skopets, B., Harbaugh, S.W., Harbaugh, J.W., and Poirier, M.C. (2000). Genotoxic and functional consequences of transplacental zidovudine exposure in fetal monkey brain mitochondria. J. Acquir. Immune Defic. Syndr. 24, 100–105.10935684
Faucette, S.R., Zhang, T.C., Moore, R., Sueyoshi, T., Omiecinski, C.J., LeCluyse, E.L., Negishi, M., and Wang, H. (2007). Relative activation of human pregnane X receptor versus constitutive androstane receptor defines distinct classes of CYP2B6 and CYP3A4 inducers. J Pharmacol. Exp. Ther. 320, 72–80.17041008
Fischl, M.A. (1989). State of antiretroviral therapy with zidovudine. AIDS 3 (Suppl. 1), S137–S143.2514732
Fowler, D.A., Weidner, D.A., and Sommadossi, J.-P. (1995). Effects of 3′-azido-3′-deoxythymidine on erythroid inducible gene expression in human K-562 leukemia cells. Toxicol. Lett. 80, 139–146.7482581
Freireich, E.J., Gehan, E.A., Rall, D.P., Schmidt, L.H., and Skipper, H.E. (1966). Quantitative comparison of toxicity of anticancer agents in mouse, rat, hamster, dog, monkey, and man. Cancer Chemother. Rep. 50, 219–244.4957125
French, J.E. (2004). Identification and characterization of potential human carcinogens using B6.129tm1Trp53 heterozygous null mice and loss of heterozygosity at the Trp53 locus. IARC Sci. Publ. 157, 271–287.
French, J.E., Lacks, G.D., Trempus, C., Dunnick, J.K., Foley, J., Mahler, J., Tice, R.R., and Tennant, R.W. (2001a). Loss of heterozygosity frequency at the Trp53 locus in p53-deficient (+/−) mouse tumors is carcinogen- and tissue dependent. Carcinogenesis 22, 99–106.11159747
French, J.E., Storer, R.D., and Donehower, L.A. (2001b). The nature of the heterozygous Trp53 knockout model for identification of mutagenic carcinogens. Toxicol. Pathol. 29, 24–29.11695559
Furman, P.A., Fyfe, J.A., St. Clair, M.H., Weinhold, K., Rideout, J.L., Freeman, G.A., Lehrman, S.N., Bolognesi, D.P., Broder, S., Mitsuya, H., and Barry, D.W. (1986). Phosphorylation of 3′-azido-3′-deoxythymidine and selective interaction of the 5′-triphosphate with human immunodeficiency virus reverse transcriptase. Proc. Natl. Acad. Sci. USA 83, 8333–8337.2430286
Gallicchio, V.S., Doukas, M.A., Hulette, B.C., Hughes, N.K., and Gass, C. (1989). Protection of 3′-azido-3′-deoxythymidine induced toxicity to murine hematopoietic progenitors (CFU-GM, BFU-E and CFUMEG) with interleukin-1. Proc. Soc. Exp. Biol. Med. 192, 201–204.2813453
Gerschenson, M., Erhart, S.W., Paik, C.Y., St. Claire, M.C., Nagashima, K., Skopets, B., Harbaugh, S.W., Harbaugh, J.W., Quan, W., and Poirier, M.C. (2000). Fetal mitochondrial heart and skeletal muscle damage in Erythrocebus patas monkeys exposed in utero to 3′-azido-3′-deoxythymidine. AIDS Res. Hum. Retroviruses 16, 635–644.10791874
Gerschenson, M., Nguyen, V., Ewings, E.L., Ceresa, A., Shaw, J.A., St. Claire, M.C., Nagashima, K., Harbaugh, S.W., Harbaugh, J.W., Olivero, O.A., Divi, R.L., Albert, P.S., and Poirier, M.C. (2004). Mitochondrial toxicity in fetal Erythrocebus patas monkeys exposed transplacentally to zidovudine plus lamivudine. AIDS Res. Hum. Retroviruses 20, 91–100.15000702
Gonzalez Cid, M., and Larripa, I. (1994). Genotoxic activity of azidothymidine (AZT) in in vitro systems. Mutat. Res. 321, 113–118.7510839
Good, S.S., Koble, C.S., Crouch, R., Johnson, R.L., Rideout, J.L., and de Miranda, P. (1990). Isolation and characterization of an ether glucuronide of zidovudine, a major metabolite in monkeys and humans. Drug Metab. Dispos. 18, 321–326.1974193
Greene, J.A., Ayers, K.M., Tucker, W.E., Jr., and de Miranda, P. (1996). Nonclinical toxicology studies with zidovudine: Reproductive toxicity studies in rats and rabbits. Fundam. Appl. Toxicol. 32, 140–147.8921317
Hall, D.B., and MacGregor, T.R. (2007). Case-control exploration of relationships between early rash or liver toxicity and plasma concentrations of nevirapine and primary metabolites. HIV Clin. Trials 8, 391–399.18042504
Hargrave, K.D., Proudfoot, J.R., Grozinger, K.G., Cullen, E., Kapadia, S.R., Patel, U.R., Fuchs, V.U., Mauldin, S.C., Vitous, J., Behnke, M.L., Klunder, J.M., Pal, K., Skiles, J.W., McNeil, D.W., Rose, J.M., Chow, G.C., Skoog, M.T., Wu, J.C., Schmidt, G., Engel, W.W., Eberlein, W.G., Saboe, T.D., Campbell, S.J., Rosenthal, A.S., and Adams, J. (1991). Novel non-nucleoside inhibitors of HIV-1 reverse transcriptase. 1. Tricyclic pyridobenzo- and dipyridodiazepinones. J. Med. Chem. 34, 2231–2241.1712395
Hart, G.J., Orr, D.C., Penn, C.R., Figueiredo, H.T., Gray, N.M., Boehme, R.E., and Cameron, J.M. (1992). Effects of (-)-2′-deoxy-3′-thiacytidine (3TC) 5′-triphosphate on human immunodeficiency virus reverse transcriptase and mammalian DNA polymerases alpha, beta, and gamma. Antimicrob. Agents Chemother. 36, 1688–1694.1384425
Highleyman, L. (1997). NIH reaffirms support for perinatal AZT despite cancer findings. National Institutes of Health. BETA March, 21.
Horwitz, J.P., Chua, J., and Noel, M. (1964). Nucleosides. V. The monomesylates of 1-(2′-deoxy-β-D-lyxofuranosyl)thymine. J. Org. Chem. 29, 2076–2078.
Hsu, J.C. (1992). The factor analytic approach to simultaneous inference in the general linear model. J. Comput. Graph. Stat. 1, 151–168.
Huang, P., Farquhar, D., and Plunkett, W. (1990). Selective action of 3′-azido-3′-deoxythymidine 5′-triphosphate on viral reverse transcriptases and human DNA polymerases. J. Biol. Chem. 265, 11,914–11,918.
Humber, D.C., Jones, M.F., Payne, J.J., Ramsay, M.V.J., Zacharie, B., Jin, H., Siddiqui, A., Evans, C.A., Tse, H.L.A., and Mansour, T.S. (1992). Expeditious preparation of (-)-2′-deoxy-3′-thiacytidine (3TC). Tetrahedron Lett. 33, 4625–4628.
Johnson, M.D., Kamso-Pratt, J.M., Whetsell, W.O., Jr., and Pepinsky, R.B. (1989). Lipocortin-1 immunoreactivity in the normal human central nervous system and lesions with astrocytosis. Am. J. Clin. Pathol. 92, 424–429.2529760
Jonckheere, A.R. (1954). A distribution-free k-sample test against ordered alternatives. Biometrika 41, 133–145.
Kakuda, T.N. (2000). Pharmacology of nucleoside and nucleotide reverse transcriptase inhibitor-induced mitochondrial toxicity. Clin. Ther. 22, 685–708.10929917
Kakuda, T.N., Brundage, R.C., Anderson, P.L., and Fletcher, C.V. (1999). Nucleoside reverse transcriptase inhibitor-induced mitochondrial toxicity as an aetiology for lipodystrophy. AIDS 13, 2311–2312.10563722
Kalbfleisch, J.D., and Prentice, R.L. (1980). The Statistical Analysis of Failure Time Data. John Wiley and Sons, Inc., Hoboken, NJ.
King, J.R., Kimberlin, D.W., Aldrovandi, G.M., and Acosta, E.P. (2002). Antiretroviral pharmacokinetics in the paediatric population: A review. Clin. Pharmacokinet. 41, 1115–1133.12405863
Kirk, G.D., Merlo, C., O’Driscoll, P., Mehta, S.H., Galai, N., Vlahov, D., Samet, J., and Engels, E.A. (2007). HIV infection is associated with an increased risk for lung cancer, independent of smoking. Clin. Infect. Dis. 45, 103–110.17554710
Klecker, R.W., Jr., Collins, J.M., Yarchoan, R., Thomas, R., Jenkins, J.F., Broder, S., and Myers, C.E. (1987). Plasma and cerebrospinal fluid pharmacokinetics of 3′-azido-3′-deoxythymidine: A novel pyrimidine analog with potential application for the treatment of patients with AIDS and related diseases. Clin. Pharmacol. Ther. 41, 407–412.3549120
Koup, R.A., Merluzzi, V.J., Hargrave, K.D., Adams, J., Grozinger, K., Eckner, R.J., and Sullivan, J.L. (1991). Inhibition of human immunodeficiency virus type 1 (HIV-1) replication by the dipyridodiazepinone BI-RG-587. J. Infect. Dis. 163, 966–970.1708400
Kramer, C.Y. (1956). Extension of multiple range tests to group means with unequal numbers of replications. Biometrics 12, 307–310.
Lamperth, L., Dalakas, M.C., Dagani, F., Anderson, J., and Ferrari, R. (1991). Abnormal skeletal and cardiac muscle mitochondria induced by zidovudine (AZT) in human muscle in vitro and in an animal model. Lab. Invest. 65, 742–751.1753716
Lamson, M.J., Sabo, J.P., MacGregor, T.R., Pav, J.W., Rowland, L., Hawi, A., Cappola, M., and Robinson, P. (1999). Single dose pharmacokinetics and bioavailability of nevirapine in healthy volunteers. Biopharm. Drug Dispos. 20, 285–291.10701699
Lewis, S.M., Lee, F.W., Ali, A.A., Allaben, W.T., Weis, C.C., and Leakey, J.E.A (2010). Modifying a displacement pump for oral gavage dosing of solution and suspension preparations to adult and neonatal mice. Lab. Anim. 39, 149–154.
Lewis, W., Papoian, T., Gonzales, B., Louie, H., Kelly, D.P., Payne, R.M., and Grody, W.W. (1991). Mitochondrial ultrastructural and molecular changes induced by zidovudine in rat hearts. Lab. Invest. 65, 228–236.1715447
Lewis, W., Gonzales, B., Chomyn, A., and Papoian, T. (1992). Zidovudine induces molecular, biochemical, and ultrastructural changes in rat skeletal muscle mitochondria. J. Clin. Invest. 89, 1354–1360.1556193
Lewis, W., Simpson, J.F., and Meyer, R.R. (1994). Cardiac mitochondrial DNA polymerase-γ is inhibited competitively and noncompetitively by phosphorylated zidovudine. Circ. Res. 74, 344–348.8293572
Lewis, W., Grupp, I.L., Grupp, G., Hoit, B., Morris, R., Samarel, A.M., Bruggeman, L., and Klotman, P. (2000). Cardiac dysfunction in the HIV-1 transgenic mouse treated with zidovudine. Lab. Invest. 80, 187–197.10701688
Lewis, W., Kohler, J.J., Hosseini, S.H., Haase, C.P., Copeland, W.C., Bienstock, R.J., Ludaway, T., McNaught, J., Russ, R., Stuart, T., and Santoianni, R. (2006). Antiretroviral nucleosides, deoxynucleotide carrier and mitochondrial DNA: Evidence supporting the DNA pol γ hypothesis. AIDS 20, 675–684.16514297
Liang, K.Y., and Zeger, S.L. (1986). Longitudinal data analysis using generalized linear modes. Biometrika, 73, 13–22.
Lim, S.E., and Copeland, W.C. (2001). Differential incorporation and removal of antiviral deoxynucleotides by human DNA polymerase γ. J. Biol. Chem. 276, 23,616–23,623.
Lin, D.Y., and Wei, L.J. (1989). The robust inference for the Cox proportional hazards model. J. Am. Stat. Assoc. 84, 1074–1078.
Lin, D.Y., Wei, L.J., and Ying, Z. (1993). Checking the Cox model with cumulative sums of martingale-based residuals. Biometrika 80, 557–572.
Luzuriaga, K., Bryson, Y., McSherry, G., Robinson, J., Stechenberg, B., Scott, G., Lamson, M., Cort, S., and Sullivan, J.L. (1996). Pharmacokinetics, safety, and activity of nevirapine in human immunodeficiency virus type 1-infected children. J. Infect. Dis. 174, 713–721.8843207
Lynx, M.D., and McKee, E.E. (2006). 3′-Azido-3′-deoxythymidine (AZT) is a competitive inhibitor of thymidine phosphorylation in isolated rat heart and liver mitochondria. Biochem. Pharmacol. 72, 239–243.16720018
Lynx, M.D., Bentley, A.T., and McKee, E.E. (2006). 3′-Azido-3′-deoxythymidine (AZT) inhibits thymidine phosphorylation in isolated rat liver mitochondria: A possible mechanism of AZT hepatotoxicity. Biochem. Pharmacol. 71, 1342–1348.16472780
McClain, R.M. (1990). Mouse liver tumors and microsomal enzyme-inducing drugs: Experimental and clinical perspectives with phenobarbital. Prog. Clin. Biol. Res. 331, 345–365.2156272
McClain, R.M. (1995). Phenobarbital mouse liver tumors: Implications of hepatic tumor promotion for cancer risk assessment. Prog. Clin. Biol. Res. 391, 325–336.8532725
McConnell, E.E., Solleveld, H.A., Swenberg, J.A., and Boorman, G.A. (1986). Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. JNCI 76, 283–289.3456066
McCullagh, P., and Nelder, J.A. (1989). Generalized Linear Models, 2nd ed. Chapman and Hall, London.
McIntyre, J. (2006). Strategies to prevent mother-to-child transmission of HIV. Curr. Opin. Infect. Dis. 19, 33–38.16374215
McKee, E.E., Bentley, A.T., Hatch, M., Gingerich, J., and Susan-Resiga, D. (2004). Phosphorylation of thymidine and AZT in heart mitochondria: Elucidation of a novel mechanism of AZT cardiotoxicity. Cardiovasc. Toxicol. 4, 155–167.15371631
Mallal, S.A., John, M., Moore, C.B., James, I.R., and McKinnon, E.J. (2000). Contribution of nucleoside analogue reverse transcriptase inhibitors to subcutaneous fat wasting in patients with HIV infection. AIDS 14, 1309–1316.10930144
Maronpot, R.R., and Boorman, G.A. (1982). Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol. Pathol. 10, 71–80.28094716
Martin, J.L., Brown, C.E., Matthews-Davis, N., and Reardon, J.E. (1994). Effects of antiviral nucleoside analogs on human DNA polymerases and mitochondrial DNA synthesis. Antimicrob. Agents Chemother. 38, 2743–2749.7695256
Mays, D.C., Dixon, K.F., Balboa, A., Pawluk, L.J., Bauer, M.R., Nawoot, S., and Gerber, N. (1991). A nonprimate animal model applicable to zidovudine pharmacokinetics in humans: Inhibition of glucuronidation and renal excretion of zidovudine by probenecid in rats. J. Pharmacol. Exp. Ther. 259, 1261–1270.1762074
Meng, Q., Grosovsky, A.J., Shi, X., and Walker, V.E. (2000a). Mutagenicity and loss of heterozygosity at the APRT locus in human lymphoblastoid cells exposed to 3′-azido-3′-deoxythymidine. Mutagenesis 15, 405–410.10970446
Meng, Q., Su, T., Olivero, O.A., Poirier, M.C., Shi, X., Ding, X., and Walker, V.E. (2000b). Relationships between DNA incorporation, mutant frequency, and loss of heterozygosity at the TK locus in human lymphoblastoid cells exposed to 3′-azido-3′-deoxythymidine. Toxicol. Sci. 54, 322–329.10774814
Meng, Q., Walker, D.M., Olivero, O.A., Shi, X., Antiochos, B.B., Poirier, M.C., and Walker, V.E. (2000c). Zidovudine-didanosine coexposure potentiates DNA incorporation of zidovudine and mutagenesis in human cells. Proc. Natl. Acad. Sci. U.S.A. 97, 12,667–12,671.10618362
Meng, Q., Su, T., O’Neill, J.P., and Walker, V.E. (2002). Molecular analysis of mutations at the HPRT and TK loci of human lymphoblastoid cells after combined treatments with 3′-azido-3′-deoxythymidine and 2′,3′-dideoxyinosine. Environ. Mol. Mutagen. 39, 282–295.12112380
Meng, Q., Olivero, O.A., Fasco, M.J., Bellisario, R., Kaminsky, L., Pass, K.A., Wade, N.A., Abrams, E.J., Nesel, C.J., Ness, R.B., Bigbee, W.L., O’Neill, J.P., Walker, D.M., Poirier, M.C., and Walker, V.E., for the Study Team (2007). Plasma and cellular markers of 3′-azido-3′-dideoxythymidine (AZT) metabolism as indicators of DNA damage in cord blood mononuclear cells from infants receiving prepartum NRTIs. Environ. Mol. Mutagen. 48, 307–321.17358024
The Merck Index (2006a). 14th ed. (M.J. O’Neil, P.E. Heckelman, C.B. Koch, and K.J. Roman, Eds.), pp. 927–928. Merck and Company, Inc., Whitehouse Station, NJ.
The Merck Index (2006b). 14th ed. (M.J. O’Neil, P.E. Heckelman, C.B. Koch, and K.J. Roman, Eds.), p. 1123. Merck and Company, Inc., Whitehouse Station, NJ.
Merluzzi, V.J., Hargrave, K.D., Labadia, M., Grozinger, K., Skoog, M., Wu, J.C., Shih, C.-K., Eckner, K., Hattox, S., Adams, J., Rosenthal, A.S., Faanes, R., Eckner, R.J., Koup, R.A., and Sullivan, J.L. (1990). Inhibition of HIV-1 replication by a nonnucleoside reverse transcriptase inhibitor. Science 250, 1411–1413.1701568
Mirochnick, M., Fenton, T., Gagnier, P., Pav, J., Gwynne, M., Siminski, S., Sperling, R.S., Beckerman, K., Jimenez, E., Yogev, R., Spector, S.A., and Sullivan, J.L., for the Pediatric AIDS Clinical Trials Group Protocol 250 Team (1998). Pharmacokinetics of nevirapine in human immunodeficiency virus type 1-infected pregnant women and their neonates. J. Infect. Dis. 178, 368–374.9697716
Mirochnick, M., Clarke, D.F., and Dorenbaum, A. (2000). Nevirapine: Pharmacokinetic considerations in children and pregnant women. Clin. Pharmacokinet. 39, 281–293.11069214
Mitsuya, H., Weinhold, K.J., Furman, P.A., St. Clair, M.H., Lehrman, S.N., Gallo, R.C., Bolognesi, D., Barry, D.W., and Broder, S. (1985). 3′-Azido-3′-deoxythymidine (BW A509U): An antiviral agent that inhibits the infectivity and cytopathic effect of human T-lymphotropic virus type III/lymphadenopathy-associated virus in vitro. Proc. Natl. Acad. Sci. USA. 82, 7096–7100.2413459
Motimaya, A.M., Subramanya, K.S., Curry, P.T., and Kitchin, R.M. (1994). Lack of induction of micronuclei by azidothymidine (AZT) in vivo in mouse bone marrow cells. Environ. Mol. Mutagen. 23, 74–76.7802748
Moussian, B. (2008). The role of GlcNAc in formation and function of extracellular matrices. Comp. Biochem. Physiol. B Biochem. Mol. Biol. 149, 215–226.18032081
Murphy, R.L. (2003). Defining the toxicity profile of nevirapine and other antiretroviral drugs. J. Acquir. Immune Defic. Syndr. 34, S15–S20.14562854
National Toxicology Program (NTP) (1999). Toxicology and Carcinogenesis Studies of AZT (CAS No. 30516-87-1) and AZT/α-Interferon A/D in B6C3F_1_ Mice (Gavage Studies). Technical Report Series No. 469. NIH Publication No. 99-3959. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (2005a). Toxicology Studies of Acesulfame Potassium (CAS No. 55589-62-3) in Genetically Modified (FVB Tg.AC Hemizygous) Mice and Carcinogenicity Studies of Acesulfame Potassium in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Feed Studies). Genetically Modified Model Report No. 2. NIH Publication No. 06-4460. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2005b). Toxicology Studies of Aspartame (CAS No. 22839-47-0) in Genetically Modified (FVB Tg.AC Hemizygous) and B6.129-Cdkn2a^tm1Rdp^ (N2) Deficient Mice and Carcinogenicity Studies of Aspartame in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Feed Studies). Genetically Modified Model Report No. 1. NIH Publication No. 06-4459. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2006). Toxicology and Carcinogenesis Studies of 3′-Azido-3′-deoxythymidine (AZT) (CAS No. 30516-87-1) in Swiss (CD-1^®^) Mice (In Utero Studies). Technical Report Series No. 522. NIH Publication No. 06-4458. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Service, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007a). Toxicology Studies of Bromodichloromethane (CAS No. 75-27-4) in Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal, Drinking Water, and Gavage Studies) and Carcinogenicity Studies of Bromodichloromethane in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Drinking Water and Gavage Studies). Genetically Modified Model Report No. 5. NIH Publication No. 07-4422. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007b). Toxicology Studies of Sodium Bromate (CAS No. 7789-38-0) in Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal and Drinking Water Studies) and Carcinogenicity Studies of Sodium Bromate in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Drinking Water Studies). Genetically Modified Model Report No. 6. NIH Publication No. 07-4423. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007c). Toxicology Studies of Dicyclohexylcarbodiimide (CAS No. 538-75-0) in F344/N Rats, B6C3F_1_ Mice, and Genetically Modified (FVB Tg.AC Hemizygous) Mice and Carcinogenicity Study of Dicyclohexylcarbodiimide in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Dermal Studies). Genetically Modified Model Report No. 9. NIH Publication No. 07-4426. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007d). Toxicology Study of Diisopropylcarbodiimide (CAS No. 693-13-0) in Genetically Modified (FVB Tg.AC Hemizygous) Mice and Carcinogenicity Study of Diisopropylcarbodiimide in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Dermal Studies). Genetically Modified Model Report No. 10. NIH Publication No. 07-4427. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007e). Toxicology Studies of Dichloroacetic Acid (CAS No. 79-43-6) in Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal and Drinking Water Studies) and Carcinogenicity Studies of Dichloroacetic Acid in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Drinking Water Studies). Genetically Modified Model Report No. 11. NIH Publication No. 07-4428. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2008). Toxicology Study of Allyl Bromide (CAS No. 106-95-6) in Genetically Modified (FVB Tg.AC Hemizygous) Mice and Carcinogenicity Study of Allyl Bromide in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Dermal and Gavage Studies). Genetically Modified Model Report No. 7. NIH Publication No. 07-4427. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2012). NTP Report on the Toxicology Study Of Senna (CAS No. 8013-11-4) in C57BL/6NTac Mice and Toxicology and Carcinogenesis Study of Senna in Genetically Modified C3B6.129F1 Trp53^tm1Brd^ N12 Haploinsufficient Mice (Feed Studies). Genetically Modified Model Report No. 15. NIH Publication No. 12-5968. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2013a). NTP Technical Report on the Toxicology and Carcinogenesis Studies of Mixtures of 3′-Azido-3′-Deoxythymidine (AZT), Lamivudine (3TC), Nevirapine (NVP), And Nelfinavir Mesylate (NFV) (CAS Nos. 30516-87-1, 134678-17-4, 129618-40-2, 159989-65-8) In B6C3F1 Mice (Transplacental Exposure Studies). Technical Report Series No. 569. NIH Publication No. 13-5911. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2013b). NTP Report on the Toxicology and Carcinogenesis Studies of 3′-Azido-3′-Deoxythymidine (CAS No. . 30516-87-1) in Genetically Modified C3B6.129F1 Trp 53^tm1Brd^ N12 Haploinsufficient (+/−) (Heterozygous F1 p53^+/−^) Mice (In Utero and Postnatal Gavage Studies). Genetically Modified Model Report No. 14. NIH Publication No. 14-5967. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
Nierkens, S., Aalbers, M., Bol, M., van Wijk, F., Hassing, I., and Pieters, R. (2005). Development of an oral exposure mouse model to predict drug-induced hypersensitivity reactions by using reporter antigens. Toxicol. Sci. 83, 273–281.15509662
Olin, B.R., and Kastrup, E.K., Eds. (1995). Drug Facts and Comparisons, p. 404c. Facts and Comparisons, Inc., St. Louis, MO.
Olivero, O.A. (2007). Mechanisms of genotoxicity of nucleoside reverse transcriptase inhibitors. Environ. Mol. Mutagen. 48, 215–223.16395695
Olivero, O.A. (2008). Relevance of experimental models for investigation of genotoxicity induced by antiretroviral therapy during human pregnancy. Mutat. Res. 658, 184–190.18295533
Olivero, O.A., Anderson, L.M., Diwan, B.A., Haines, D.C., Harbaugh, S.W., Moskal, T.J., Jones, A.B., Rice, J.M., Riggs, C.W., Logsdon, D., Yuspa, S.H., and Poirier, M.C. (1997). Transplacental effects of 3′-azido-2′,3′-dideoxythymidine (AZT): Tumorigenicity in mice and genotoxicity in mice and monkeys. J. Natl. Cancer Inst. 89, 1602–1608.9362158
Olivero, O.A., Parikka, R., Poirier, M.C., and Vahakangas, K. (1999). 3′-Azido-3′-deoxythymidine (AZT) transplacental perfusion kinetics and DNA incorporation in normal human placentas perfused with AZT. Mutat. Res. 428, 41–47.10517977
Olivero, O.A., Shearer, G.M., Chougnet, C.A., Kovacs, A.A., Baker, R., Stek, A.M., Khoury, M.M., and Poirier, M.C. (2000). Incorporation of zidovudine into cord blood DNA of infants and peripheral blood DNA of their HIV-1-positive mothers. Ann. N.Y. Acad. Sci. 918, 262–268.11131712
Olivero, O.A., Reddy, M.K., Pietras, S.M., and Poirier, M.C. (2001). Plasma drug levels compared with DNA incorporation of 3′-azido-3′-deoxythymidine (AZT) in adult cynomolgus (macaca fascicularis) monkeys. Exp. Biol. Med. 226, 446–449.
Parker, W.B., White, E.L., Shaddix, S.C., Ross, L.J., Buckheit, R.W., Jr., Germany, J.M., Secrist, J.A., III, Vince, R., and Shannon, W.M. (1991). Mechanism of inhibition of human immunodeficiency virus type I reverse transcriptase and human DNA polymerases α, β, and γ by the 5′-triphosphates of carbovir, 3′-azido-3′-deoxythymidine, 2′,3′-dideoxyguanosine, and 3′-deoxythymidine. A novel RNA template for the evaluation of antiretroviral drugs. J. Biol. Chem. 266, 1754–1762.1703154
Patel, B.A., Chu, C.K., and Boudinot, F.D. (1989). Pharmacokinetics and saturable renal tubular secretion of zidovudine in rats. J. Pharm. Sci. 78, 530–534.2778651
Pérez-Pérez, M.J., Hernandez, A.I., Priego, E.M., Rodríguez-Barrios, F., Gago, F., Camarasa, M.J., and Balzarini, J. (2005). Mitochondrial thymidine kinase inhibitors. Curr. Top. Med. Chem. 5, 1205–1219.16305527
Perry, C.M., and Faulds, D. (1997). Lamivudine. A review of its antiviral activity, pharmacokinetic properties and therapeutic efficacy in the management of HIV infection. Drugs 53, 657–680.9098665
Phillips, M.D., Nascimbeni, B., Tice, R.R., and Shelby, M.D. (1991). Induction of micronuclei in mouse bone marrow cells: An evaluation of nucleoside analogues used in the treatment of AIDS. Environ. Mol. Mutagen. 18, 168–183.1915312
Physicians’ Desk Reference (PDR) (2010a). Epivir^®^ (GlaxoSmithKline) (lamivudine) tablets and oral solution. 64th ed., pp. 1437–1448. Thomson PDR, Montvale, NJ.
Physicians’ Desk Reference (PDR) (2010b). Viramune^®^ (Boehringer Ingelheim) (nevirapine) tablets and oral suspension. 64th ed., pp. 887–906. Thomson PDR, Montvale, NJ.
Pluda, J.M., Mitsuya, H., and Yarchoan, R. (1991). Hematologic effects of AIDS therapies. Hematol. Oncol. Clin. North Am. 5, 229–248.1708759
Plumb, R.S., Gray, R.D., Harker, A.J., and Taylor, S. (1996). High-performance chromatographic assay for the sulphoxide metabolite of 2′-deoxy-3′-thiacytidine in human urine. J. Chromatogr. Biomed. Appl. 687, 457–461.
Poirier, M.C., Patterson, T.A., Slikker, W., and Olivero, O.A. (1999). Incorporation of 3′-azido-3′-deoxythymidine (AZT) into fetal DNA and fetal tissue distribution of drug after infusion of pregnant late-term rhesus macaques with a human-equivalent AZT dose. J. Acquir. Immune Defic. Syndr. 22, 477–483.10961609
Pollard, R.B., Robinson, P., and Dransfield, K. (1998). Safety profile of nevirapine, a nonnucleoside reverse transcriptase inhibitor for the treatment of human immunodeficiency virus infection. Clin. Ther. 20, 1071–1092.9916603
Popovic, M., Caswell, J.L., Mannargudi, B., Shenton, J.M., and Uetrecht, J.P. (2006). Study of the sequence of events involved in nevirapine-induced skin rash in Brown Norway rats. Chem. Res. Toxicol. 19, 1205–1214.16978025
Pritchard, J.B., French, J.E., Davis, B.J., and Haseman, J.K. (2003). The role of transgenic mouse models in carcinogen identification. Environ. Health. Perspect. 111, 444–454.12676597
Public Health Service Task Force (PHS) (2008). Recommendations for use of antiretroviral drugs in pregnant HIV-infected women for maternal health and interventions to reduce perinatal HIV transmission in the United States. U.S. Department of Health and Human Services, Washington, DC.
Raidel, S.M., Haase, C.P., Jansen, N.R., Russ, R.B., Sutliff, R.L., Velsor, L.W., Day, B.J., Hoit, B.D., Samarel, A.M., and Lewis, W. (2002). Targeted myocardial transgenic expression of HIV Tat causes cardiomyopathy and mitochondrial damage. Am. J. Physiol. Heart Circ. Physiol. 282, H1672–H1678.11959630
Rajagopalan, P., Boudinot, F.D., Chu, C.K., Tennant, B.C., Baldwin, B.H., and Schinazi R.F. (1996). Pharmacokinetics of (-)-2′-3′-dideoxy-3′-thiacytidine in woodchucks. Antimicrob. Agents Chemother. 40, 642–645.8851586
Rice, J.M. (1973). An overview of transplacental chemical carcinogenesis. Teratology 8, 113–126.
Richman, D., Rosenthal, A.S., Skoog, M., Eckner, R.J., Chou, T.-C., Sabo, J.P., and Merluzzi, V.J. (1991). BI-RG-587 is active against zidovudine-resistant human immunodeficiency virus type 1 and synergistic with zidovudine. Antimicrob. Agents Chemother. 35, 305–308.1708976
Riska, P., Lamson, M., MacGregor, T., Sabo, J., Hattox, S., Pav, J., and Keirns, J. (1999a). Disposition and biotransformation of the antiretroviral drug nevirapine in humans. Drug Metab. Dispos. 27, 895–901.10421616
Riska, P.S., Joseph, D.P., Dinallo, R.M., Davidson, W.C., Keirns, J.J., and Hattox, S.E. (1999b). Biotransformation of nevirapine, a non-nucleoside HIV-1 reverse transcriptase inhibitor, in mice, rats, rabbits, dogs, monkeys, and chimpanzees. Drug Metab. Dispos. 27, 1434–1447.10570025
Samuels, D.C. (2006). Mitochondrial AZT metabolism. IUBMB Life 58, 403–408.16801215
Senda, S., Blanche, S., Costagliola, D., Cibert, C., Nigon, F., Firtion, G., Floch, C., Parat, S., and Viegas-Péquignot, E. (2007). Altered heterochromatin organization after perinatal exposure to zidovudine. Antivir. Ther. 12, 179–187.17503660
Shafik, H.M., Nokta, M.A., and Pollard, R.B. (1991). Recombinant human interferon beta ser protects against zidovudine-induced genetic damage in AIDS patients. Antiviral Res. 16, 205–212.1799278
Shenton, J.M., Teranishi, M., Abu-Asab, M.S., Yager, J.A., and Uetrecht, J.P. (2003). Characterization of a potential animal model of an idiosyncratic drug reaction: Nevirapine-induced skin rash in the rat. Chem. Res. Toxicol. 16, 1078–1089.12971795
Shenton, J.M., Chen, J., and Uetrecht, J.P. (2004). Animal models of idiosyncratic drug reactions. Chem. Biol. Interact. 150, 53–70.15522261
Shewach, D.S., Liotta, D.C, and Schinazi, R.F. (1993). Affinity of the antiviral enantiomers of oxathiolane cytosine nucleosides for human 2′-deoxycytidine kinase. Biochem. Pharmacol. 45, 1540–1543.8385948
Shirley, E. (1977). A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics 33, 386–389.884197
Simpson, M.V., Chin, C.D., Keilbaugh, S.A., Lin, T.S., and Prusoff, W.H. (1989). Studies on the inhibition of mitochondrial DNA replication by 3′-azido-3′-deoxythymidine and other dideoxynucleoside analogs which inhibit HIV-1 replication. Biochem. Pharmacol. 38, 1033–1036.2706007
Singlas, E., Poiger, J.C., Taburet, A.M., Colaneri, S., and Fillastre, J.P. (1989). Comparative pharmacokinetics of zidovudine (AZT) in healthy subjects and HIV seropositive patients. Eur. J. Clin. Pharmacol. 36, 639–640.2776824
Smerdon, S.J., Jäger, J., Wang, J., Kohlstaedt, L.A., Chirino, A.J., Friedman, J.M., Rice, P.A., and Steitz, T.A. (1994). Structure of the binding site for nonnucleoside inhibitors of the reverse transcriptase of human immunodeficiency virus type 1. Proc. Natl. Acad. Sci. USA 91, 3911–3915.7513427
Sommadossi, J.-P., and Carlisle, R. (1987). Toxicity of 3′-azido-3′-deoxythymidine and 9-(1,3-dihydroxy-2-propoxymethyl)guanine for normal human hematopoietic progenitor cells in vitro. Antimicrob. Agents Chemother. 31, 452–454.3495235
Sommadossi, J.-P., Carlisle, R., and Zhou, Z. (1989). Cellular pharmacology of 3′-azido-3′-deoxythymidine with evidence of incorporation into DNA of human bone marrow cells. Mol. Pharmacol. 36, 9–14.2747633
Song, S., Wheeler, L.J., and Mathews, C.K. (2003). Deoxyribonucleotide pool imbalance stimulates deletions in HeLa cell mitochondrial DNA. J. Biol. Chem. 278, 43,893–43,896.
Soudeyns, H., Yao, X.I., Gao, Q., Belleau, B., Kraus, J.L., Nguyen-Ba, N., Spira, B., and Wainberg, M.A. (1991). Anti-human immuno-deficiency virus type 1 activity and in vitro toxicity of 2′-deoxy-3′-thiacytidine (BCH-189), a novel hetero-cyclic nucleoside analog. Antimicrob. Agents Chemother. 35, 1386–1390.1929298
Spence, R.A., Kati, W.M., Anderson, K.S., and Johnson, K.A. (1995). Mechanism of inhibition of HIV-1 reverse transcriptase by nonnucleoside inhibitors. Science 267, 988–993.7532321
Sperling, R.S., Shapiro, D.E., McSherry, G.D., Britto, P., Cunningham, B.E., Culnane, M., Coombs, R.W., Scott, G., Van Dyke, R.B., Shearer, W.T., Jimenez, E., Diaz, C., Harrison, D.D., and Delfraissy, J.F., for the Pediatric AIDS Clinical Trials Group Protocol 076 Study Group (1998). Safety of the maternal-infant zidovudine regimen utilized in the Pediatric AIDS Clinical Trial Group 076 study. AIDS 12, 1805–1813.9792381
Stagg, M.P., Cretton, E.M., Kidd, L., Diasio, R.B., and Sommadossi, J.-P. (1992). Clinical pharmacokinetics of 3′-azido-3′-deoxythymidine (zidovudine) and catabolites with formation of a toxic catabolite, 3′-amino-3′-deoxythymidine Clin. Pharmacol. Ther. 51, 668–676.1611806
Storer, R.D., French, J.E., Haseman, J., Hajian, G., LeGrand, E.K., Long, G.G., Mixson, L.A., Ochoa, R., Sagartz, J.E., and Soper, K.A. (2001). P53^(+/−)^ hemizygous knockout mouse: Overview of available data. Toxicol. Pathol. 29, 30–50.11695560
Streck, E.L., Scaini, G., Rezin, G.T., Moreira, J., Fochesato, C.M., and Romão, P.R.T. (2008). Effects of the HIV treatment drugs nevirapine and efavirenz on brain creatine kinase activity. Metab. Brain Dis. 23, 485–492.18815873
Susan-Resiga, D., Bentley, A.T., Lynx, M.D., LaClair, D.D., and McKee, E.E. (2007). Zidovudine inhibits thymidine phosphorylation in the isolated perfused rat heart. Antimicrob. Agents Chemother. 51, 1142–1149.17220403
Sussman, H.E., Olivero, O.A., Meng, Q., Pietras, S.M., Poirier, M.C., O’Neill, J.P., Finette, B.A., Bauer, M.J., and Walker, V.E. (1999). Genotoxicity of 3′-azido-3′-deoxythymidine in the human lymphoblastoid cell line, TK6: Relationships between DNA incorporation, mutant frequency, and spectrum of deletion mutations in HPRT. Mutat. Res. 429, 249–259.10526209
Taburet, A.-M., Naveau, S., Zorza, G., Colin, J.-N., Delfraissy, J.-F., Chaput, J.-C., and Singlas, E. (1990). Pharmacokinetics of zidovudine in patients with liver cirrhosis. Clin. Pharmacol. Ther. 47, 731–739.2357867
Tardieu, M., Brunelle, F., Raybaud, C., Ball, W., Barret, B., Pautard, B., Lachassine, E., Mayaux, M.-J., and Blanche, S. (2005). Cerebral MR imaging in uninfected children born to HIV-seropositive mothers and perinatally exposed to zidovudine. AJNR Am. J. Neuroradiol. 26, 695–701.15814907
Tennant, R.W., French, J.E., and Spalding, J.W. (1995). Identifying chemical carcinogens and assessing potential risk in short-term bioassays using transgenic mouse models. Environ. Health Perspect. 103, 942–950.8529591
Terpstra, T.J. (1952). The asymptotic normality and consistency of Kendall’s test against trend, when ties are present in one ranking. Indagat. Mathemat. 14, 327–333.
Thompson, M.B., Dunnick, J.K., Sutphin, M.E., Giles, H.D., Irwin, R.D., and Prejean, J.D. (1991). Hematologic toxicity of AZT and ddC administered as single agents and in combination to rats and mice. Fundam. Appl. Toxicol. 17, 159–176.1655546
Toltzis, P., Marx, C.M., Kleinman, N., Levine, E.M., and Schmidt, E.V. (1991). Zidovudine-associated embryonic toxicity in mice. J. Infect. Dis. 163, 1212–1218.2037787
Törnevik, Y., Ullman, B., Balzarini, J., Wahren, B., and Eriksson, S. (1995). Cytotoxicity of 3′-azido-3′-deoxythymidine correlates with 3′-azidothymidine-5′-monophosphate (AZTMP) levels, whereas anti-human immunodeficiency virus (HIV) activity correlates with 3′-azidothymidine-5′-triphosphate (AZTTP) levels in cultured CEM T-lymphoblastoid cells. Biochem. Pharmacol. 49, 829–837.7702641
Torres, S.M., Walker, D.M., Carter, M.M., Cook, D.L., Jr., McCash, C.L., Cordova, E.M., Olivero, O.A., Poirier, M.C., and Walker, V.E. (2007). Mutagenicity of zidovudine, lamivudine, and abacavir following in vitro exposure of human lymphoblastoid cells or in utero exposure of CD-1 mice to single agents or drug combinations. Environ. Mol. Mutagen. 48, 224–238.17358033
Torres, S.M., Walker, D.M., McCash, C.L., Carter, M.M., Ming, J., Cordova, E.M., Pons, R.M., Cook, D.L., Jr., Seilkop, S.K., Copeland, W.C., and Walker, V.E. (2009). Mutational analysis of the mitochondrial tRNA genes and flanking regions in umbilical cord tissue from uninfected infants receiving AZT-based therapies for prophylaxis of HIV-1. Environ. Mol. Mutagen. 50, 10–26.19031409
Trang, J.M., Prejean, J.D., James, R.H., Irwin, R.D., Goehl, T.J., and Page, J.G. (1993). Zidovudine bioavailability and linear pharmacokinetics in female B6C3F1 mice. Drug Metab. Dispos. 21, 189–193.8095218
UNAIDS (2008). 2008 Report on the Global AIDS Epidemic. Joint United Nations Programme on HIV/AIDS, New York.
Von Tungeln, L.S., Hamilton, L.P., Dobrovolsky, V.N., Bishop, M.E., Shaddock, J.G., Heflich, R.H., and Beland, F.A. (2002). Frequency of Tk and Hprt lymphocyte mutants and bone marrow micronuclei in B6C3F_1_/Tk^+/−^ mice treated neonatally with zidovudine and lamivudine. Carcinogenesis 23, 1427–1432.12189183
Von Tungeln, L.S., Williams, L.D., Doerge, D.R., Shaddock, J.G., McGarrity, L.J., Morris, S.M., Mittelstaedt, R.A., Heflich, R.H., and Beland, F.A. (2007). Transplacental drug transfer and frequency of Tk and Hprt lymphocyte mutants and peripheral blood micronuclei in mice treated transplacentally with zidovudine and lamivudine. Environ. Mol. Mutagen. 48, 258–269.16850453
Walker, D.M., Poirier, M.C., Campen, M.J., Cook, D.L., Jr., Divi, R.L., Nagashima, K., Lund, A.K., Cossey, P.Y., Hahn, F.F., and Walker, V.E. (2004). Persistence of mitochondrial toxicity in hearts of female B6C3F1 mice exposed in utero to 3′-azido-3′-deoxythymidine. Cardiovasc. Toxicol. 4, 133–153.15371630
Walker, D.M., Malarkey, D.E., Seilkop, S.K., Ruecker, F.A., Funk, K.A., Wolfe, M.J., Treanor, C.P., Foley, J.F., Hahn, F.F., Hardisty, J.F., and Walker, V.E. (2007). Transplacental carcinogenicity of 3′-azido-3′-deoxythymidine in B6C3F1 mice and F344 rats. Environ. Mol. Mutagen. 48, 283–298.17358026
Walubo, A., Barr, S., and Abraham, A.M. (2006). Rat CYP3A and CYP2B1/2 were not associated with nevirapine-induced hepatotoxicity. Methods Find. Exp. Clin. Pharmacol. 28, 423–431.17003847
Weidner, D.A., and Sommadossi, J.-P. (1990). 3′-Azido-3′-deoxythymidine inhibits globin gene transcription in butyric acid-induced K-562 human leukemia cells. Mol. Pharmacol. 38, 797–804.2174502
Wen, B., Chen, Y., and Fitch, W.L. (2009). Metabolic activation of nevirapine in human liver microsomes: Dehydrogenation and inactivation of cytochrome P450 3A4. Drug Metab. Dispos. 37, 1557–1562.19364830
Williams, D.A. (1986). A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics 42, 183–186.3719054
Williams, L.D., Von Tungeln, L.S., Beland, F.A., and Doerge, D.R. (2003). Liquid chromatographic-mass spectrometric determination of the metabolism and disposition of the anti-retroviral nucleoside analogs zidovudine and lamivudine in C57BL/6N and B6C3F1 mice. J. Chromatogr. B Analyt. Technol. Biomed. Life Sci. 798, 55–62.
Witt, K.L., Tice, R.R., Wolfe, G.W., and Bishop, J.B. (2004). Genetic damage detected in CD-1 mouse pups exposed perinatally to 3′-azido-3′-deoxythymidine or dideoxyinosine via maternal dosing, nursing, and direct gavage: II. Effects of the individual agents compared to combination treatment. Environ. Mol. Mutagen. 44, 321–328.15476197
Witt, K.L., Cunningham, C.K., Patterson, K.B., Kissling, G.E., Dertinger, S.D., Livingston, E., and Bishop, J.B. (2007). Elevated frequencies of micronucleated erythrocytes in infants exposed to zidovudine in utero and postpartum to prevent mother-to-child transmission of HIV. Environ. Mol. Mutagen. 48, 322–329.17358032
World Health Organization Report (WHO) (2004). Report 2004: Changing History. World Health Organization, Geneva.
Wu, J.C., Warren, T.C., Adams, J., Proudfoot, J., Skiles, J., Raghavan, P., Perry, C., Potocki, I., Farina, P.R., and Grob, P.M. (1991). A novel dipyridodiazepinone inhibitor of HIV-1 reverse transcriptase acts through a nonsubstrate binding site. Biochemistry 30, 2022–2026.1705436
Yarchoan, R., Klecker, R.W., Weinhold, K.J., Markham, P.D., Lyerly, H.K., Durack, D.T., Gelmann, E., Lehrman, S.N., Blum, R.M., Barry, D.W., Shearer, G.M., Fischl, M.A., Mitsuya, H., Gallo, R.C., Collins, J.M., Bolognesi, D.P., Myers, C.E., and Broder, S. (1986). Administration of 3′-azido-3′-deoxythymidine, an inhibitor of HTLV-III/LAV replication, to patients with AIDS or AIDS-related complex. Lancet 1, 575–580.2869302
Zhang, W., Mauldin, J.K., Schmiedt, C.W., Brockus, C.W., Boudinot, F.D., and McCrackin Stevenson, M.A. (2004). Pharmacokinetics of lamivudine in cats. Am. J. Vet. Res. 65, 841–846.15198226
Zimmerman, T.P., Mahoney, W.B., and Prus, K.L. (1987). 3′-Azido-3′-deoxythymidine. J. Biol. Chem. 262, 5748–5754.3471758