# SUMMARY OF PEER REVIEW PANEL COMMENTS

On February 9, 2012, the draft Report on the study of mixtures of 3′-azido-3′-deoxythymidine (AZT), lamivudine (3TC), and nevirapine (NVP) received public review by the National Toxicology Program’s Board of Scientific Counselors’ Technical Reports Peer Review Panel. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. J.E.A. Leakey, FDA, reviewed information on the toxicity and carcinogenicity of AZT in rodents and humans, including absorption, distribution, metabolism and excretion issues and mechanisms of AZT-induced toxicity in eukaryotic cells. He presented information regarding AZT human toxicity, noting that long-term consequences of perinatal exposure to AZT are unknown. He provided background information regarding the development of the C3B6.129F1-Trp53^tm1Brd^ N12 haploinsufficient mouse model, which is designed to develop tumors at an increased rate and thus shorten the duration of carcinogenicity studies.

The study reported in GMM 16 was designed to test AZT in combination with 3TC and NVP. Mice were dosed twice per day with AZT, 3TC, and NVP alone or in combination from gestation day 12 until postnatal day 28. The study was designed to more closely mimic the clinical situation where human infants are dosed with drug combinations twice daily, but only prenatally and in infancy. Dr. Leakey presented the results of the study, including a significant increase in liver tumors.

The proposed conclusions for the GMM 16 study were clear evidence of carcinogenic activity of AZT alone in male heterozygous F1 p53^+/−^ mice; clear evidence of carcinogenic activity of AZT in combination with 3TC, and AZT in combination with 3TC and NVP in male heterozygous F1 p53^+/−^ mice; no evidence of carcinogenic activity of 3TC alone in male heterozygous F1 p53^+/−^ mice administered 150 mg/kg; no evidence of carcinogenic activity of NVP alone in male heterozygous F1 p53^+/−^ mice administered 168 mg/kg; equivocal evidence of carcinogenic activity of NVP alone, AZT in combination with 3TC, and AZT in combination with 3TC and NVP in female heterozygous F1 p53^+/−^ mice; equivocal evidence of carcinogenic activity of 3TC alone in female heterozygous F1 p53^+/−^ mice; and no evidence of carcinogenic activity of AZT alone in female heterozygous F1 p53^+/−^ mice administered 240 mg/kg.

Dr. Olivero, the first primary reviewer, expressed concern that this mouse model may not be appropriate to evaluate the carcinogenic potential of the drugs. She acknowledged that the studies were very complex. She was also concerned that the model did not produce anemia, because that has been a signature of other studies. She suggested that, in the future, the animals’ micronuclei should be examined to determine whether they have intact chromosomes. She also suggested adding protease inhibitors to future studies, because some evidence has shown that they have a protective anticarcinogenic effect.

Dr. Anderson, the second primary reviewer, called GMM 16 a remarkable study. She particularly appreciated the extra information on litter and paternal effects. She had no major scientific criticisms and agreed with the proposed conclusions.

Dr. Elwell, the third primary reviewer, agreed with the previous reviewers and concurred with the proposed conclusions. He suggested discussion in the report on the microscopic finding of centrilobular degeneration and inclusion of more information on the increased severity of vacuolization in the liver. He also noted inconsistency in the discussion of nonneoplastic findings.

Dr. Leakey replied that tests for anemia had not been conducted to avoid adding stress to the pups, which were already in a toxic environment. He agreed to add discussion of AZT lymphoma protection and to clarify the discussion and treatment of nonneoplastic findings. Dr. G.R. Olson, Toxicologic Pathology Associates, noted that the liver tumors were quite distinct. Dr. Leakey mentioned that in the GMM series the severity scores for graded nonneoplastic lesions were not in the report, but were available on the NTP website. Dr. Elwell asked whether the other liver findings had an impact on tumor response, and if there was something unusual about this study in that most of the animals, including controls, had liver degeneration. Dr. Olson agreed that it was not a typical response. After further discussion, it was recommended that the severity score information should be incorporated into the report.

Dr. Anderson moved to approve the conclusions as written and Dr. Olivero seconded. The panel voted unanimously to accept the conclusions as written.

Dr. Bucher asked the panel for recommendations concerning future transgenic model studies. Dr. Olivero noted that in her research program, the models, dosing, and other aspects were evolving, generating very different types of data than traditional studies. Dr. Cattley suggested formulating some type of guidance, because the studies are not full lifetime studies, the group sizes are smaller, and the genetic background is unusual. He noted what seemed to him to be a discrepancy between the intention to generate large changes in tumor incidence and the actual results, which had a more limited range. Dr. Anderson inquired whether the genetic models are in fact faster and cheaper, since they have their own special issues. Dr. Bucher said that the savings are not as great as had been anticipated, and said it remained an open question whether using the models would ultimately be cost-effective and rapid enough to actually influence clinical decision making in the use of the therapeutics and the evaluation of exposed children. Dr. Anderson suggested that there are classical models that should be considered in this context.