# CONTRIBUTORS

The study on 3′-azido-3′-deoxythymidine, lamivudine, and nevirapine was conducted at the Food and Drug Administration’s (FDA) National Center for Toxicological Research (NCTR) under an interagency agreement between the FDA and the National Institute of Environmental Health Sciences (NIEHS). The studies were monitored by a Toxicology Study Selection and Review Committee composed of representatives from the NCTR and other FDA centers, NIEHS, and other ad hoc members from other governmental agencies and academia. The interagency agreement was designed to use the staff and facilities of the NCTR in the testing of FDA priority chemicals and to provide FDA scientists and regulatory policymakers with information for hazard identification and risk assessment.

## National Center for Toxicological Research, Food and Drug Administration

### Conducted studies, evaluated and interpreted results and pathology findings, and reported findings

- J.E.A. Leakey, Ph.D., Study Scientist
- W.T. Allaben, Ph.D., Co-Study Scientist
- J.K. Dunnick, Ph.D., Co-Study Scientist
  National Toxicology Program
- S.M. Lewis, Ph.D., Co-Study Scientist
- P.C. Howard, Ph.D.
- C.C. Weis, B.S.

### Provided microbiological support

- D.D. Paine, B.S.

### Conducted chemical analysis of the purity of the test chemicals

- B.R. Brown, B.S.
- J.P. Freeman, Ph.D.
- T.M. Heinze
- P.H. Siitonen, B.S.

### Conducted quality assurance audits

- S.J. Culp, Ph.D.
- J.M. Fowler, B.S.
- R.D. Smith, B.S.

### Provided statistical analysis

- R.P. Felton, M.S.
- B.T. Thorn, M.S.

## Bionetics Corporation

### Prepared animal feed and cared for mice

- C.J. Cain
- J.W. Carson, B.S.
- A. Matson, B.S.

## Z-Tech Corporation

### Provided software systems development and data entry

- K.A. Carroll
- S.H. Green

## Toxicologic Pathology Associates

### Evaluated pathology findings

- P.W. Mellick, D.V.M., Ph.D.
- G.R. Olson, D.V.M., Ph.D.
- A.R. Warbritton
- L.P. Wiley, B.S.

## Experimental Pathology Laboratories, Inc.

### Provided pathology review

- M.H. Hamlin, II, D.V.M., Principal Investigator
- E.T. Adams, D.V.M., Ph.D.
- R.A. Miller, D.V.M., Ph.D.

## NTP Pathology Working Group

### Evaluated slides and contributed to pathology report on mice (October 16, 2009)

- R.A. Miller, D.V.M., Ph.D., Coordinator
  Experimental Pathology Laboratories, Inc.
- E.T. Adams, D.V.M., Ph.D.
  Experimental Pathology Laboratories, Inc.
- G.P. Flake, M.D.
  National Toxicology Program
- J.R. Latendresse, D.V.M., Ph.D.
  National Center for Toxicological Research
- G.R. Olson, D.V.M., Ph.D.
  National Center for Toxicological Research

## NIEHS/FDA Interagency Agreement Project Officers

- P.C. Howard, Ph.D.
  National Center for Toxicological Research
- W.T. Allaben, Ph.D.
  National Center for Toxicological Research
- N.J. Walker, Ph.D.
  National Toxicology Program
- J.R. Bucher, Ph.D.
  National Toxicology Program

## Biotechnical Services, Inc.

### Prepared Report

- S.R. Gunnels, M.A., Principal Investigator
- L.M. Harper, B.S.
- T.S. Kumpe, M.A.
- E.S. Rathman, M.S.
- D.C. Serbus, Ph.D.