# DISCUSSION AND CONCLUSIONS

While the advent of Highly Active Antiretroviral Therapy (HAART) has dramatically improved rates of morbidity and mortality in people infected with HIV, the long-term toxicological consequences of such therapy are unknown (PHS, 2008). AZT is a key component of HAART and although it has previously been studied in cancer bioassays, it has not been extensively studied in combination with other antiretroviral drugs. A major objective of this study was to develop and evaluate the heterozygous F1 p53^+/−^ mouse model as a tool for investigating the potential carcinogenicity of AIDS drug combinations.

The genetically modified mouse in this study was designed to produce a p53 haploinsufficiency on a genetic background that was similar to the B6C3F1 mouse. However, the parental strains were reversed relative to the B6C3F1 mouse to take advantage of the readily available B6.129-Trp53(N12)^tmlBrd(−/−)^ mouse to supply p53 haploinsufficiency from the paternal side so that healthy wild type female mice would be exposed to AZT during pregnancy. Unlike many other strains, C3H female mice show excellent tolerance to the dosing of their pups. The observed incidences of hepatocellular adenoma in the male heterozygous F1 p53^+/−^ mice used in this study suggest that these genetically modified mice do express a tumor profile that is similar to the B6C3F1 mouse.

The B6.129-Trp53(N12)^tmlBrd(+/−)^ p53 haploinsufficient mouse model, which was used in previous NTP genetically modified model (GMM) studies (NTP, 2012, 2013b) exhibited very low incidences of liver tumors and was unresponsive to exposure to dichloroacetate (Brook, 1987), a chemical that has been shown to be hepatocarcinogenic in both B6C3F1 mice and Fischer 344 rats (Bull et al., 1990; DeAngelo et al., 1996).

The preceding study in this series of experiments (NTP, 2013b), which utilized AZT alone given continuously until 45 weeks of age, demonstrated increased incidences of hepatocellular adenoma with a positive dose trend in male heterozygous F1 p53^+/−^ mice continuously exposed to either 160/80/160 or 240/120/240 mg/kg AZT. In the current study, where heterozygous F1 p53^+/−^ mice were dosed only from postnatal day (PND) 1 though PND 28, significantly increased incidences of hepatocellular adenoma or hepatocellular adenoma or carcinoma (combined), were also observed in male mice evaluated at 45 weeks of age that were exposed to either AZT alone or AZT in combination with either 3TC or 3TC and NVP, but not in male mice exposed to either 3TC or NVP alone.

While 3TC has not been reported to be carcinogenic in rodents, it has been reported to enhance the genotoxicity of AZT in mice simultaneously exposed to both drugs (Von Tungeln et al., 2002; Dobrovolsky et al., 2007). Nevirapine is reported in be a constitutive androstane receptor (CAR)-type cytochrome P450 inducer and to be hepatocarcinogenic in both rats and mice following 2-year exposures (PDR, 2010b). CAR agonists generally increase mouse liver tumor incidences in cancer bioassays (McClain, 1995) via promotional mechanisms that require continuous exposure and the relevance of such tumors to human risk assessment is questionable (McClain, 1990). However, the presence of such tumors could potentially mask other hepatocarcinogenic mechanisms such as genotoxicity. NVP metabolites have been reported to form adducts with DNA (Antunes et al., 2008). The heterozygous F1 p53^+/−^ mouse model as used in this study eliminated the potential for CAR-related tumor promotion by dosing only up to PND 28. Clearly, this eliminated NVP-dependent hepatocarcinogenicity while still enabling the manifestation of AZT-dependent hepatocarcinogenicity. Thus, the mouse model, as used in this study, provides a mechanism to investigate hepatocarcinogenic effects of CAR-dependent tumor promotors that are additional and unrelated to CAR-related signal transduction.

Although NVP exposure as used in this study did not significantly increase liver tumor incidences in either male or female mice, there were greater than twofold increases in the incidences of malignant lymphoma in female heterozygous F1 p53^+/−^ mice to over six times the mean historical incidence for all NTP studies that have used this mouse model (Table J2). However, the increases were not statistically significant and so may not be indicative of a treatment-related carcinogenic response. While incidences of malignant lymphoma were increased approximately twofold over vehicle control values in the AZT/3TC/NVP-M and AZT/3TC/NVP-H groups, they were also increased more than twofold in the AZT/3TC-H group which was not exposed to NVP. The incidence of malignant lymphoma was not increased by AZT alone; the overall incidences in the vehicle control and AZT-H groups were both 2/25. In addition, incidences of mammary gland adenoacanthoma and adenocarcinoma (combined) were increased in female heterozygous F1 p53^+/−^ mice exposed to 3TC, from an overall rate of 4% in the vehicle control group to 16% in the 3TC-H group and 8.7% in the AZT/3TC-H group. While these increases were not statistically significant the incidences were greater than the historical incidence of mammary gland adenoacanthoma and adenocarcinoma for all NTP studies that have used this mouse model (1%; Table J2). The mouse model used in this study was not designed to detect small changes in the incidences of neoplasms with low background rates of occurrence. Increased experimental group size is required to detect effects on rarer neoplasm endpoints. Evidence of carcinogenicity for these increases in neoplasm incidence in female heterozygous F1 p53^+/−^ mice should therefore be considered equivocal because, although the increases are not statistically significant, the experimental design does not eliminate the possibility that they are treatment related.

The heterozygous F1 p53^+/−^ mouse model used in this study has demonstrated clear evidence of hepatocarcinogenicity of AZT in male heterozygous F1 p53^+/−^ mice. The model not only provides a bioassay system that is of comparable sensitivity to the male B6C3F1 mouse in detecting hepatocarcinogens, it also has the ability to differentiate between promotional mouse hepatocarcinogens such as CAR and peroxisome proliferator-activated receptor agonists and more dangerous genotoxic and epigenetic agents.

Early rodent cancer bioassays of AZT using low doses (20 or 40 mg/kg per day) did not report clinically relevant carcinogenic activity (Ayers, 1988), but NTP studies have reported carcinogenic activity when higher doses have been used. For example, B6C3F1 mice exposed to 60 or 120 mg/kg AZT by gavage for 2 years exhibited increased incidences of vaginal squamous cell carcinoma (females) and Harderian gland adenoma (males) (NTP, 1999). While no increase in the incidence of hepatocellular tumors were reported in this study, data interpretation was complicated by a high background liver tumor incidence associated with active infections of Helicobacter hepaticus. In a follow-up study using Swiss CD-1^®^ mice exposed to AZT throughout gestation via maternal gavage (NTP, 2006), male F_1_ mice exposed to 200 or 300 mg/kg exhibited increased incidences of lung tumors [alveolar/bronchiolar carcinoma and alveolar/bronchiolar adenoma or carcinoma (combined)] at 2 years of age.

Walker et al. (2007) reported increased incidences of hepatocellular carcinoma in 2-year-old male B6C3F1 mice exposed during gestation to either 240 or 480 mg/kg AZT. However, a more recent study in B6C3F1 mice that were exposed to AZT transplacentally from gestational day (GD) 12 to GD 18 at doses up to only 240 mg/kg per day, did not report increased rates of hepatocarcinogenicity when the mice were evaluated at 2 years of age (NTP, 2013a).

The mechanisms for the carcinogenic effects of AZT in rodents may also be related to how AZT is metabolized. AZT is metabolized by three pathways: glucuronidation, which accounts for up to 75% of the human urinary product; mixed-function oxidase-mediated reactions, giving 3′-amino-3′-deoxythymidine (AMT), a minor urinary metabolite; and phosphorylation, which occurs throughout the tissues. Phosphorylation is fundamental to the antiviral activity of AZT but accounts for only about 1% of its total disposition. Unchanged AZT constitutes about 20% of the human urinary products; in contrast, the unchanged drug in rats and mice accounts for up to 90% of the drug recovered in the urine (Doshi et al., 1989; Patel et al., 1989; de Miranda et al., 1990). It has been argued that increased incidences of tumors of the vaginal epithelium observed in rodent bioassays may be due to chronic local exposure to unconjugated AZT via urine which would not occur in humans (Ayers et al., 1996b). While lack of conjugation could also influence AZT concentrations in liver and lung tissues following oral AZT exposure, tissue concentrations have not been directly compared between humans and rodents. Despite low rates of glucuronidation, oral doses of AZT are rapidly eliminated in mice; for example, the serum half-life of AZT in adult female C57BL/6N mice treated orally with 400 mg/kg AZT was reported to be 44 minutes (Williams et al., 2003). Toxicokinetic studies associated with the current study are presented in Appendix I. Both the C_max_ and AUC values for AZT in mice receiving 160 or 240 mg/kg were considerably greater than those of human patients receiving therapeutic doses of AZT. For example, AZT therapy is designed to maintain serum AZT concentrations above 1 µM and typically produces C_max_ values of between 5 and 10 µM (Klecker et al., 1987; Donnerer et al., 2008), whereas when measured in heterozygous F1 p53^+/−^ mouse pups on PND 28, oral gavage of AZT at 160 or 240 mg/kg resulted in apparent C_max_ concentrations of 152 and 718 µM, respectively (Table I4). However, the current study demonstrated a significant increase in the incidence of hepatocellular adenomas in male heterozygous F1 p53^+/−^ mice in the AZT/3TC/NVP-L dose group (Table 7), which received 20 mg AZT/kg twice daily by gavage from PND 1 through PND 10, 40 mg/kg twice daily by maternal gavage from GD 12 through GD 18, and 40 mg/kg twice daily by gavage from PND 11 through PND 28. The simulation in Appendix I predicts that administration of 40 mg AZT/kg body weight twice daily to 28-day-old mice would result in apparent C_max_ and AUC values of 20.6 µM and 60.3 µM•hour, respectively (Table I7). These values are 212% and 136%, respectively, of those predicted for human patients receiving therapeutic doses of AZT (Figure I3 and Table I7).

AZT has a relatively high rate of incorporation into liver and lung nuclear and mitochondrial DNA after transplacental exposure (Olivero et al., 1997), and this may explain why these organs are targets for transplacental and neonatal carcinogenicity of the drug. AZT has been reported to evoke a wide range of genotoxic effects in both in vitro and in vivo test systems, and specifically increases the incidences of micronucleated erythrocytes and reticulocytes in blood from exposed mice (NTP, 1999, 2006, 2013a,b; Bishop et al., 2004b; Witt et al., 2004; Dobrovolsky et al., 2007). In the current genotoxicity studies, erythrocyte and reticulocyte micronucleus frequencies were increased by AZT exposure in heterozygous F1 p53^+/−^ mice evaluated on PND 1 and PND 28, but not after exposure to 3TC or NVP in the absence of AZT; there was some evidence that 3TC and/or NVP enhanced the effect of AZT (Appendix B).

In vitro studies have reported that AZT accumulates in mitochondria as AZT-monophosphate and inhibits mitochondrial synthesis of thymidine triphosphate (TTP) (Lynx et al., 2006). Lack of mitochondrial TTP synthesis may explain at least some of the genotoxic activity of AZT, because in nonproliferating cells, mitochondria are the sole source of nuclear TTP that is required as a substrate for mitochondrial DNA replication and nuclear DNA repair processes (Song et al., 2003; McKee et al., 2004).

While there have been no reports of AZT causing cancer in humans, a recent epidemiology study reported that patients with HIV infection or AIDS have increased risk of developing lung cancer (Kirk et al., 2007). Since the increased risk was not significantly correlated with either HAART or low CD4^+^ cell count it is not yet known whether AZT exposure contributes to this increased cancer risk. Another recent study from California has reported that homosexual men have a higher incidence of cancer diagnosis than heterosexual men, but the explanation for this has not been investigated (Boehmer et al., 2012). Cancer takes time to develop, and further follow-up of patients is required to determine any association between AZT (and other antiretroviral drugs) and long-term adverse effects, including cancer. While the benefits of HAART clearly outweigh the potential short-term risks of AZT and other AIDS therapeutics for individuals exposed to HIV, more information is needed on the long-term consequences of HAART so that the therapeutic regimes can be optimized for long-term health. The heterozygous F1 p53^+/−^ mouse model provides a useful tool for further evaluating the hepatocarcinogenic potential of AZT when used in combination with other therapeutic agents. It has the advantage of potentially providing data within 12 months of study initiation, and if sufficient animal numbers are used to provide statistical power, it promises high sensitivity for detecting hepatocarcinogenicity and possibly other neoplasias.

The previous study in this series (NTP, 2013b) exposed heterozygous F1 p53^+/−^ mice to AZT alone through the same dosing period used in the current study, but continued the dosing 5 days per week from PND 20 until evaluation at 45 weeks of age. The Poly-3 adjusted incidence rates for hepatocellular adenoma or carcinoma (combined) in the 80/40/80, 160/80/160, and 240/120/240 mg/kg AZT dose groups of males in this study were 13.2%, 22.2%, and 36.5%, respectively. This corresponds to Poly-3-adjusted rates of 36.4%, 34.9%, and 43.8% for the AZT/3TC/NVP-L, AZT/3TC/NVP-M, and AZT/3TC/NVP-H dose groups of males in the current study. In females, the incidences of malignant lymphoma in the vehicle control, 80/40/80, 160/80/160, and 240/120/240 mg/kg AZT dose groups were 0/26, 0/27, 1/27 and 3/27, respectively, whereas in the current study they were 2/25, 2/25, 4/22, 4/25 and 2/25 for the vehicle control, AZT/3TC/NVP-L, AZT/3TC/NVP-M, AZT/3TC/NVPH, and AZT-H dose groups, respectively. The mice in the corresponding dose groups in both studies were exposed to identical total daily doses of AZT between GD 12 and PND 28. The studies differed in that (1) dosing continued until terminal evaluation in the previous study (NTP, 2013b) but ceased at PND 28 in the current study, (2) the dose was administered as a single gavage dose in the previous study but was split into two gavage administrations 6 hours apart in the current study, and (3) AZT was administered alone in the previous study but was part of a three-drug combination in the current study.

Despite the shorter exposure time, there is clearly a greater carcinogenic response in the male mice of the current study than in the previous study (NTP, 2013b), particularly with the low and mid doses. The Poly-3 adjusted rates for the incidences of hepatocellular adenoma or carcinoma (combined) for the AZT-H and AZT/3TC-H dose groups in the current study are 40.2% and 45.0%, respectively, and as such are not able to significantly demonstrate that 3TC and/or NVP exposure enhances AZT-induced hepatocarcinogenicity. Likewise, the small difference between the Poly-3 adjusted liver neoplasm incidence rates in the AZT-H group in the current study and that of the 240/120/240 AZT dose group in the previous study (NTP, 2013b) is insufficient to significantly demonstrate that splitting the dose enhances carcinogenicity. Unfortunately, the current study did not include an AZT-L dose group, which might have been able to resolve this. In contrast, there was no evidence from the current study that AZT alone increased incidence of malignant lymphoma in female heterozygous F1 p53^+/−^ mice, despite equivocal evidence for this effect from the previous study. Diwan et al., (1999) also observed no increase in the incidence of malignant lymphoma in CD-1 mice exposed to AZT in utero. Thus, it is possible that adult exposure to AZT is responsible for the increased incidence of malignant lymphoma observed in the previous study. Nevertheless, it is apparent from comparing the two studies that a combination of twice-daily dosing and coadministration of 3TC and NVP lowers the threshold AZT dose that produces hepatocellular adenomas and carcinomas in male heterozygous F1 p53^+/−^ mice. This observation has some relevance to the potential long-term human risk of HAART therapy, because AZT is used therapeutically in multidrug combinations, and AZT is administered two or three times daily to achieve constant blood levels.

## Conclusions

Under the conditions of this gavage study, there was clear evidence of carcinogenic activity* of AZT alone in male heterozygous F1 p53^+/−^ mice based on increased incidences of hepatocellular adenoma. There was clear evidence of carcinogenic activity of AZT in combination with 3TC, and AZT in combination with 3TC and NVP in male heterozygous F1 p53^+/−^ mice based on increased incidences of hepatocellular adenoma and hepatocellular adenoma or carcinoma (combined). The occurrence of malignant lymphoma may have been related to treatment with AZT alone and with AZT in combination with 3TC.

There was no evidence of carcinogenic activity of 3TC alone in male heterozygous F1 p53^+/−^ mice administered 150 mg/kg. There was no evidence of carcinogenic activity of NVP alone in male heterozygous F1 p53^+/−^ mice administered 168 mg/kg.

There was equivocal evidence of carcinogenic activity of NVP alone, AZT in combination with 3TC, and AZT in combination with 3TC and NVP in female heterozygous F1 p53^+/−^ mice based on the occurrence of malignant lymphoma. There was equivocal evidence of carcinogenic activity of 3TC alone in female heterozygous F1 p53^+/−^ mice based on the occurrence of mammary gland adenoacanthoma or adenocarcinoma (combined).

There was no evidence of carcinogenic activity of AZT alone in female heterozygous F1 p53^+/−^ mice administered 240 mg/kg.

* Explanation of Levels of Evidence of Carcinogenic Activity is on page 13. A summary of the Peer Review Panel comments and the public discussion on this Report appears on page 15.