# RESULTS

## Litter Success and Pup Survival

As shown in Table 3, the chemical combinations were relatively nontoxic to the pregnant dams at the doses used, because most produced viable litters. However, there were apparent treatment-related effects on both litter success and pup survival to postnatal day (PND) 28. The average number of pups born per litter was lower in the AZT/3TC/NVP-H group compared to the vehicle control group. Pup survival was not affected by treatment between PNDs 1 and 10, which suggested that the reduction of the concentration of the NVP component of the doses between PNDs 1 and 3 had protected the neonatal mice from NVP toxicity. However, survival was significantly decreased between PNDs 11 and 28 in the AZT/3TC/NVP-M and AZT/3TC/NVP-H groups relative to the vehicle control group. The majority of pup deaths occurred between PNDs 13 and 20. This effect on pup mortality was likely due to a combination of multiple components of the dose, because, while survival was significantly reduced in the AZT-H group relative to the vehicle control group (Table 4), the observed decrease was significantly less than that of the AZT/3TC/NVP-H group. Overall, pup survival across all the dose groups was significantly decreased relative to that observed in previous studies that used heterozygous F1 p53^+/−^ mice (NTP, 2013b), and because of this reduction in pup survival, more dams (and litters) had to be supplied to the study than the 25 dams per dose group anticipated in the experimental design. There were also treatment effects on rates of pup growth between PND 1 and PND 10 (Figures H3 and H4), which potentially contributed to the treatment effects on survival between PNDs 11 and 28 (Tables H1 through H4 and Figures H1 and H2).

TABLE 3 Litter Parameters and Pup Survival to 28 Days in the In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Total dams pregnant^b^ | 30 | 26 | 24 | 37
Dams that did not litter | 2 | 2 | 1 | 2
Total litters | 28 | 24 | 23 | 35
Total pups born | 204 | 180 | 156 | 208
Average per litter | 7.29 | 7.5 | 6.78 | 5.94
Number of males born | 105 | 85 | 71 | 93
Sex ratio of live pups (female:male) | 1:1.18 | 1:1.10 | 1:0.90 | 1:0.89
Pups born dead (%) | 10 (4.9) | 18 (10.0) | 6 (3.8) | 11 (5.3)
Percent survival PND 1 - PND 10^c^ | 82.74% | 78.70% | 90.58% | 81.03%
Survival analysis^d^ | NS | NS | NS | NS
Percent survival PND 11 - PND 28^e^ | 96.54% | 98.02% | 81.52% | 48.82%
Survival analysis^f^ | P<0.001 | NS | P=0.006 | P<0.001
Pups assigned to 45-week study | 50 | 50 | 50 | 50
Litters used for 45-week study | 24 | 16 | 16 | 24

a AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg.

b Plug positive dams were randomly assigned to dose groups on gestational day (GD) 0 (day plug was observed), and their weight gain was monitored to confirm pregnancy. Dams that did not gain sufficient weight to indicate pregnancy by GD 11 were returned to the breeding pool and are not included in this table.

c Excludes pups that were culled on postnatal day (PND) 1, and includes both males and females

d Overall survival within litters to PND 10. Beneath the vehicle control group is the P value associated with a linear trend test. Beneath the dosed groups are the P values corresponding to pairwise comparisons by Dunnett’s test. NS=not significant

e Excludes pups that died or were culled before PND 11, and includes both males and females

f Beneath the vehicle control group is the P value associated with a linear trend test. Beneath the dosed groups are the P values corresponding to pairwise comparisons by Dunnett-Hsu adjusted comparisons among groups in log-rank analysis between the vehicle controls and that dosed group.

TABLE 4 Litter Parameters and Pup Survival to 28 Days in the In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
Total dams pregnant^b^ | 30 | 29 | 28 | 26 | 28 | 37
Dams that did not litter | 2 | 0 | 3 | 3 | 1 | 2
Total litters | 28 | 29 | 25 | 23 | 27 | 35
Total pups born | 204 | 206 | 147 | 155 | 184 | 208
Average per litter | 7.29 | 7.10 | 5.88 | 6.74 | 6.81 | 5.94
Number of males born | 105 | 100 | 64 | 74 | 91 | 93
Sex ratio of live pups
(female:male) | 1:1.18 | 1:0.99 | 1:0.84 | 1:0.94 | 1:1.12 | 1:0.89
Pups born dead (%) | 10 (4.9) | 5 (2.4) | 7 (4.8) | 2 (1.3) | 12 (6.5) | 11 (5.3)
Percent survival
PND 1 - PND 10^c^ | 82.74% | 83.10% | 86.11% | 86.23% | 94.00% | 81.03%
Survival analysis
[vs. vehicle control]^d^ | | NS | NS | NS | NS | NS
Survival analysis
[vs. AZT/3TC/NVP-H]^d^ | NS | NS | NS | NS | NS
Percent survival
PND 11 - PND 28^e^ | 96.54% | 80.60% | 99.09% | 99.24% | 71.47% | 48.82%
Survival analysis
[vs. vehicle control]^f^ | | P=0.037 | NS | NS | P<0.001 | P<0.001
Survival analysis
[vs. AZT/3TC/NVP-H]^f^ | P<0.001 | P<0.001 | P<0.001 | P<0.001 | P<0.001
Pups assigned to 45-week study | 50 | 50 | 50 | 51 | 50 | 50
Litters used for study | 24 | 22 | 17 | 19 | 20 | 24

a AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b Plug positive dams were randomly assigned to dose groups on gestational day (GD) 0 (day plug was observed), and their weight gain was monitored to confirm pregnancy. Dams that did not gain sufficient weight to indicate pregnancy by GD 11 were returned to the breeding pool and are not included in this table.

c Excludes pups that were culled on postnatal day (PND) 1, and includes both males and females

d Overall survival within litters to PND 10. P values represent pairwise comparisons with a Tukey’s test. NS=not significant

e Excludes pups that died or were culled before PND 11, and includes both males and females

f P values represent Tukey-Kramer adjusted comparisons among groups in log-ranked analysis. NS=not significant

## 45-Week Study

### Survival

Estimates of survival probabilities for male and female mice are shown in Tables 5 and 6 and Figures 2 and 3. In general, survival was relatively high with at least 75% surviving to terminal sacrifice in all groups. No obvious dose-dependent effects were observed in either males or females when the combination doses were compared or when the individual high dose constituent chemicals were compared. For males, survival was significantly greater in the AZT/3TC/NVP-L and AZT/3TC/NVP-M groups relative to the vehicle control group. This result was not considered to be treatment related. The natural deaths and morbidity in the control group were not associated with any single pathological lesion, but were the result of osteosarcomas and other malignant sarcomas, or malignant lymphoma. For females, there was no significant treatment effect for any of the three combination doses relative to the vehi cle controls. There were no significant differences in survival between high dose groups of the constituent chemicals in either sex (statistical data not presented); however, survival of females in the AZT/3TC-H group was significantly less than that of the vehicle control group.

Additional statistical analyses were performed to determine possible litter and common sire effects on survival (Appendix G). This required different analytical methods than used for the standard Cox Proportional Hazards Model (Cox, 1972) and resulted in significant increases in hazard for all dosed female groups relative to the vehicle controls. However, these effects were are attributed to the 100% survival in the vehicle control group rather than a genuine significant dose effect. There were no significant differences in survival in either male or female mice due to clustering of litter or sire effects.

TABLE 5 Survival of Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Male
Mice initially in study | 25 | 25 | 25 | 25
Removals^b^ | 0 | 0 | 2 | 1
Moribund | 2 | 0 | 1 | 1
Natural deaths | 3 | 1 | 0 | 1
Mice surviving to study termination | 20 | 24 | 22 | 22
Probability of survival to end of study^c^ | 80.0% | 96.0% | 95.7% | 91.7%
Mean survival (days) | 321.0 | 332.6 | 334.0 | 324.8
Survival analysis^d^ | P=0.206N | P=0.043N | P=0.047N | P=0.157N
Female
Mice initially in study | 25 | 25 | 25 | 25
Removals^b^ | 0 | 0 | 3 | 0
Moribund | 0 | 2 | 2 | 2
Natural deaths | 0 | 1 | 1 | 2
Mice surviving to study termination | 25 | 22 | 19 | 21
Probability of survival to end of study | 100% | 88.0% | 86.4% | 84.0%
Mean survival (days) | 332.8 | 324.4 | 313.9 | 328.7
Survival analysis | P=0.078 | P=0.104 | P=0.088 | P=0.079

a AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg

b Censored from survival analysis

c Kaplan-Meier determinations

d Cox Proportional Hazards Regression Model results. Tests formed by suitable contrasts in the Cox Estimates. All tests are single degree of freedom and one sided. The P value in the vehicle control column is the trend test; other P values are pairwise comparisons to the vehicle control group. A negative trend or a lower mortality in a dose group is indicated by N.

FIGURE 2 Kaplan-Meier Survival Curves for Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison

AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg

Kaplan-Meier Survival Curves for Male Heterozygous F1 p53+/− Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison

Kaplan-Meier Survival Curves for Female Heterozygous F1 p53+/− Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison

TABLE 6 Survival of Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
Male
Mice initially in study | 25 | 25 | 25 | 26 | 25 | 25
Removals^b^ | 0 | 1 | 0 | 0 | 0 | 1
Moribund | 2 | 4 | 0 | 0 | 3 | 1
Natural deaths | 3 | 2 | 2 | 4 | 1 | 1
Mice surviving to study termination | 20 | 18 | 23 | 22 | 21 | 22
Probability of survival to end of study^c^ | 80.0% | 75.0% | 92.0% | 84.6% | 84.0% | 91.7%
Mean survival (days) | 321.0 | 302.7 | 325.3 | 310.7 | 312.8 | 324.8
Survival analysis^d^ | | P=0.418 | P=0.085N | P=0.263N | P=0.283N | P=0.171N
Female
Mice initially in study | 25 | 25 | 25 | 25 | 25 | 25
Missexed^b^ | 0 | 0 | 0 | 0 | 1 | 0
Moribund | 0 | 3 | 3 | 2 | 4 | 2
Natural deaths | 0 | 2 | 2 | 3 | 1 | 2
Mice surviving to study termination | 25 | 20 | 20 | 20 | 19 | 21
Probability of survival to end of study | 100% | 80.0% | 80.0% | 80.0% | 79.2% | 84.0%
Mean survival (days) | 332.8 | 328.2 | 326.2 | 325.4 | 309.6 | 328.7
Survival analysis | | P=0.051 | P=0.054 | P=0.051 | P=0.037 | P=0.075

a AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b Censored from survival analysis

c Kaplan-Meier determinations

d Cox Proportional Hazards Regression Model results. Tests formed by suitable contrasts in the Cox Estimates. All tests are single degree of freedom, one sided, pairwise comparisons to the vehicle control group. A lower mortality in a dose group is indicated by N.

FIGURE 3 Kaplan-Meier Survival Curves for Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison

AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

Kaplan-Meier Survival Curves for Male Heterozygous F1 p53+/− Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison

Kaplan-Meier Survival Curves for Female Heterozygous F1 p53+/− Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison

### Body Weights, Organ Weights, and Clinical Pathology

Growth curves for males and females are shown in Figures 4 and 5. Body weight data are also presented in Appendix D. In the combination dose comparison, males and females dosed with the AZT/3TC/NVP-H combination had significantly decreased body weights compared to the vehicle control groups for several weeks after PND 11 when individual monitoring began (until 11 weeks for females and 20 weeks for males) (Tables D1 and D3). There were also significant linear trends across the dose groups during this period. In addition, mean body weights for the male and female AZT/3TC/NVP-M groups were significantly less than those of the vehicle control groups until 14 weeks. The high dose comparison suggested that AZT was the major contributor to the observed body weight decreases in the combination chemical groups. Mean body weights for the male and female AZT-H groups were significantly less than those of the vehicle control groups during some of the early weeks of dosing, whereas those of the 3TC-H and NVP-H groups tended to be greater than those of the vehicle control groups (Tables D2 and D4).

In male and female mice, absolute brain weights in the combination dose groups decreased with increasing dose and, except in low dose males, the absolute brain weights of the dosed groups were significantly less than those of the vehicle control groups (Table E1). Because body weights also decreased with increasing dose, there were no significant decreases in relative brain weights compared to the vehicle controls. When the high dose constituent chemicals were compared, absolute brain weights of the male and female AZT-H and AZT/3TC/NVP-H groups were significantly less than those of the vehicle control groups (Table E2). When the high dose groups were compared for females, the decrease appeared to be dependent on AZT exposure; the absolute brain weights of the AZT-H and AZT/3TC/NVP-H groups were statistically similar to one another and the remaining dose groups had absolute brain weights that were significantly greater than that of the AZT/3TC/NVP-H group. Compared to the vehicle control group, there were no significant differences in relative brain weights among the high dose groups of male and female mice.

Relative liver weights of male combination dose groups followed a positive trend with dose (Table E1). When the high dose groups were compared, increases in relative liver weights of male mice appeared to be associated with AZT exposure (Table E2). This is shown in that the relative liver weight of the AZT/3TC/NVP-H group was significantly greater than that of the vehicle control group but similar to the AZT-H and AZT/3TC-H group, while the relative liver weights of the 3TC-H and NVP-H groups were significantly less than that of the AZT/3TC/NVP-H group. In female mice, neither absolute or relative liver weights were significantly affected by any treatment (Tables E1 and E2).

In combination dose groups, the absolute heart weight of AZT/3TC/NVP-H females was significantly greater than that of the vehicle control group, and there was a positive trend in absolute heart weights (Table E1). There was also a positive trend for relative heart weights in these combination dose groups, though no individual group relative weight was significantly greater than that of the vehicle control group. In females, absolute heart weight was also significantly increased in the AZT/3TC-H group relative to the vehicle control group (Table E2). Neither absolute or relative heart weights of males were affected in any group (Tables E1 and E2).

Serum alanine aminotransferase activity was increased in the male AZT/3TC/NVP-H group compared to the vehicle control group (Tables C1 and C2) by a small but statistically significant amount with a significant dose trend across the combination doses. There were no other significant effects on clinical pathology parameters in treated groups of mice.

FIGURE 4 Growth Curves for Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison

AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg

Growth Curves for Male Heterozygous F1 p53+/− Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison

Growth Curves for Female Heterozygous F1 p53+/− Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison

FIGURE 5 Growth Curves for Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison

AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

Growth Curves for Male Heterozygous F1 p53+/− Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison

Growth Curves for Female Heterozygous F1 p53+/− Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of malignant lymphoma and neoplasms and/or nonneo-plastic lesions of the liver, mammary gland, kidney, and spleen. Summaries of the incidences of neoplasms and nonneoplastic lesions and statistical analysis of selected primary neoplasms are presented in Appendix A.

Liver: In the combination dose comparison, the incidences of hepatocellular adenoma and hepato-cellular adenoma or carcinoma (combined) in all groups of males dosed with AZT/3TC/NVP were significantly increased compared to the vehicle control group, and the incidences increased across the dose range with significant trends (Tables 7, A1, and A2).

The severity of cytoplasmic vacuolization in males in the AZT/3TC/NVP groups was greater than that in the vehicle control group, and the severities increased with a significant (P≤0.029) trend (Tables A3 and G8). The background incidences of cytoplasmic vacuolization were relatively high: 19/25 and 14/25 for male and female mice, respectively (Tables A3 and A9). High background incidences of this lesion have also been reported in other studies that used the methyl-cellulose/Tween^®^ 80 dosing vehicle used in the current study (NTP, 2013a,b). The incidences of basophilic focus were slightly increased in AZT/3TC/NVP-M and AZT/3TC/NVP-H males (Table 7).

TABLE 7 Incidences of Neoplasms and Nonneoplastic Lesions of the Liver in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Number Examined Microscopically | 25 | 25 | 23 | 23
Basophilic Focus^b^ | 0 | 0 | 2 | 2
Hepatocellular Adenoma, Multiple | 0 | 3 | 2 | 2
Hepatocellular Adenoma (includes multiple)^c^
Overall rate^d^ | 1/25 (4.0%) | 7/25 (28.0%) | 7/23 (30.4%) | 9/23 (39.1%)
Adjusted rate^e^ | 1/22.9 (4.4%) | 7/24.8 (28.3%) | 7/22.9 (30.5%) | 9/22.8 (39.4%)
Terminal rate^f^ | 0/20 (0.0%) | 7/24 (29.2%) | 7/22 (31.8%) | 9/22 (40.9%)
First incidence (days) | 313 | 315 (T) | 318 (T) | 316 (T)
Poly-3 test^g^ | P=0.006 | P=0.030 | P=0.021 | P=0.003
Hepatocellular Carcinoma, Multiple | 0 | 0 | 0 | 1
Hepatocellular Carcinoma (includes multiple) | 0 | 2 | 2 | 1
Hepatocellular Adenoma or Carcinoma
Overall rate | 1/25 (4.0%) | 9/25 (36.0%) | 8/23 (34.8%) | 10/23 (43.5%)
Adjusted rate | 1/22.9 (4.4%) | 9/24.8 (36.4%) | 8/22.9 (34.9%) | 10/22.8 (43.8%)
Terminal rate | 0/20 (0.0%) | 9/24 (37.5%) | 8/22 (36.4%) | 10/22 (45.5%)
First incidence (days) | 313 | 315 (T) | 318 (T) | 316 (T)
Poly-3 test | P=0.004 | P=0.006 | P=0.009 | P=0.001

(T) Terminal kill

a AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg

b Number of animals with lesion

c Historical incidence for control groups in 40- and 45-week heterozygous F1 p53^+/−^ mouse studies: 8/100, range 4.0%–12.5%

d Number of animals with neoplasm per number of animals with liver examined microscopically

e Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

f Observed incidence at terminal kill

g Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

In the high dose comparison, the incidences of hepatocellular adenoma and hepatocellular adenoma or carcinoma (combined) in males in the AZT-H, AZT/3TC-H, and AZT/3TC/NVP-H groups were significantly greater than those in the vehicle control group (Tables 8, A4, and A5). The incidences of these lesions in the 3TC-H and NVP-H groups were significantly less than those in the AZT/3TC/NVP-H group suggesting that the AZT component of the remaining dosed groups was the main factor contributing to the increased incidences of liver neoplasms.

TABLE 8 Incidences of Neoplasms of the Liver in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
Number Examined
Microscopically | 25 | 23 | 25 | 25 | 25 | 23
Hepatocellular Adenoma, Multiple^b^ | 0 | 4 | 1 | 0 | 2 | 2
Hepatocellular Adenoma (includes multiple)^c^
Overall rate^d^ | 1/25 (4.0%) | 8/23 (34.8%) | 3/25 (12.0%) | 2/25 (8.0%) | 9/25 (36.0%) | 9/23 (39.1%)
Adjusted rate^e^ | 1/22.9 (4.4%) | 8/19.9 (40.2%) | 3/23.6 (12.7%) | 2/22.4 (8.9%) | 9/22.2 (40.5%) | 9/22.8 (39.4%)
Terminal rate^f^ | 0/20 (0.0%) | 8/18 (44.4%) | 3/23 (13.0%) | 2/22 (9.1%) | 9/21 (42.9%) | 9/22 (40.9%)
First incidence (days) | 313 | 316 (T) | 318 (T) | 322 (T) | 316 (T) | 316 (T)
Poly-3 test vs. Vehicle Control^g^ | | P=0.004 | P=0.313 | P=0.493 | P=0.003 | P=0.003
Poly-3 test vs. AZT/3TC/NVP-H^h^ | P=0.003 | P=0.601 | P=0.036N | P=0.016N | P=0.589
Hepatocellular
Carcinoma, Multiple | 0 | 0 | 0 | 0 | 1 | 1
Hepatocellular Adenoma or Carcinoma
Overall rate | 1/25 (4.0%) | 8/23 (34.8%) | 3/25 (12.0%) | 2/25 (8.0%) | 10/25 (40.0%) | 10/23 (43.5%)
Adjusted rate | 1/22.9 (4.4%) | 8/19.9 (40.2%) | 3/23.6 (12.7%) | 2/22.4 (8.9%) | 10/22.2 (45.0%) | 10/22.8 (43.8%)
Terminal rate | 0/20 (0.0%) | 8/18 (44.4%) | 3/23 (13.0%) | 2/22 (9.1%) | 10/21 (47.6%) | 10/22 (45.5%)
First incidence (days) | 313 | 316 (T) | 318 (T) | 322 (T) | 316 (T) | 316 (T)
Poly-3 test vs. Vehicle Control | | P=0.004 | P=0.313 | P=0.493 | P<0.001 | P=0.001
Poly-3 test vs. AZT/3TC/NVP-H | P=0.001 | P=0.529N | P=0.017N | P=0.007N | P=0.585

(T) Terminal kill

a AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b Number of animals with neoplasm

c Historical incidence for control groups in 40- and 45-week heterozygous F1 p53^+/−^ mouse studies: 8/100, range 4.0%–12.5%

d Number of animals with neoplasm per number of animals with liver examined microscopically

e Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

f Observed incidence at terminal kill

g Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

h Beneath the dose group incidence are the P values corresponding to pairwise comparisons between the AZT/3TC/NVP-H group and that dose group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in a dose group is indicated by N.

Malignant Lymphoma: The incidences of malignant lymphoma in females administered AZT/3TC/NVP-M or AZT/3TC/NVP-H were slightly greater than that in the vehicle control group and the time to first tumor was earlier in all AZT/3TC/NVP groups than in the vehicle controls (Tables 9, A7 and A8). When the high dose constituent chemicals were compared, the highest incidence occurred in the NVP-H group suggesting that the NVP contributed to the increase (Tables 10, A10, and A11). However, the incidence in the AZT/3TC-H group was also higher than that in the vehicle control group. Historical control data from other NTP and NCTR studies using heterozygous F1 p53^+/−^ mice, which includes this study, give an overall incidence of 3/102 (2.9%) for malignant lymphoma in females (Tables 9, 10, and J2).

In the high dose comparison, the incidences of malignant lymphoma were slightly greater in males administered AZT-H (3/24) or AZT/3TC-H (3/25) than in the vehicle controls (1/25) (Tables A4 and A5). The historical incidence of malignant lymphoma in male control groups of F1 p53^+/−^ mice in 40- and 45-week studies is 3/101 (0.0%–8.0%) (Table J1).

Mammary Gland: The incidence of mammary gland adenoacanthoma or adenocarcinoma (combined) was sightly increased in the 3TC-H group of females relative to the vehicle control group and the AZT/3TC/NVP-H groups (Tables 10, A10, and A11). Mammary gland neoplasms did not occur in the AZT/3TC/NVP-L or AZT/3TC/NVP-M groups of females (Table A7). Historical control data from other NTP and NCTR studies using heterozygous F1 p53^+/−^ mice, which includes the current study, give overall incidences of 0/101 for mammary gland adenoacanthoma and 1/101 (1.0%) for mammary gland adenocarcinoma in females (Table J2). While the increases in the incidences of malignant mammary gland neoplasms in female mice were small and did not reach statistical significance, the possibility that they were treatment related cannot be ruled out under the experimental conditions of this study.

TABLE 9 Incidences of Malignant Lymphoma in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Malignant Lymphoma^b^
Overall rate^c^ | 2/25 (8.0%) | 2/25 (8.0%) | 4/22 (18.2%) | 4/25 (16.0%)
Adjusted rate^d^ | 2/25.0 (8.0%) | 2/24.4 (8.2%) | 4/22.0 (18.2%) | 4/24.5 (16.3%)
Terminal rate | 2/25 (8.0%) | 0/22 (0.0%) | 1/19 (5.3%) | 2/21 (9.5%)
First incidence (days) | 316 (T) | 186 | 101 | 247
Poly-3 test^f^ | P=0.156 | P=0.687 | P=0.274 | P=0.324

(T) Terminal kill

a AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg

b Historical incidence for control groups in 40- and 45-week heterozygous F1 p53^+/−^ mouse studies: 3/102, range 0.0%–8.0%

c Number of animals with malignant lymphoma per number of animals examined microscopically

d Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

e Observed incidence at terminal kill

f Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

TABLE 10 Incidences of Selected Neoplasms in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
All Organs
Malignant Lymphoma^b^
Overall rate^c^ | 2/25 (8.0%) | 2/25 (8.0%) | 1/25 (4.0%) | 5/25 (20.0%) | 4/24 (16.7%) | 4/25 (16.0%)
Adjusted rate^d^ | 2/25.0 (8.0%) | 2/24.4 (8.2%) | 1/23.7 (4.2%) | 5/23.7 (21.1%) | 4/23.6 (16.9%) | 4/24.5 (16.3%)
Terminal rate^e^ | 2/25 (8.0%) | 0/20 (0.0%) | 0/20 (0.0%) | 4/20 (20.0%) | 0/19 (0.0%) | 2/21 (9.5%)
First incidence (days) | 316 (T) | 277 | 258 | 251 | 102 | 247
Poly-3 test vs. Vehicle Control^f^ | | P=0.686 | P=0.518N | P=0.186 | P=0.307 | P=0.324
Poly-3 test vs. AZT/3TC/NVP-H^g^ | P=0.324 | P=0.336 | P=0.182 | P=0.479N | P=0.628N
Mammary Gland
Adenocarcinoma^h^
Overall rate | 1/25 (4.0%) | 0/25 (0.0%) | 3/25 (12.0%) | 0/23 (0.0%) | 2/23 (8.7%) | 0/25 (0.0%)
Adjusted rate | 1/25.0 (4.0%) | 0/23.8 (0.0%) | 3/23.6 (12.7%) | 0/21.8 (0.0%) | 2/21.1 (9.5%) | 0/23.7 (0.0%)
Terminal rate | 1/25 (4.0%) | 0/20 (0.0%) | 2/20 (10.0%) | 0/20 (0.0%) | 1/19 (5.3%) | 0/21 (0.0%)
First incidence (days) | 319 (T) | — | 277 | — | 280 | —
Poly-3 test vs. Vehicle Control | | P=0.510N | P=0.282 | P=0.527N | P=0.440 | P=0.510N
Poly-3 test vs. AZT/3TC/NVP-H | P=0.510N | — | P=0.112N | — | P=0.208N
Adenoacanthoma or Adenocarcinoma
Overall rate | 1/25 (4.0%) | 1/25 (4.0%) | 4/25 (16.0%) | 0/23 (0.0%) | 2/23 (8.7%) | 1/25 (4.0%)
Adjusted rate | 1/25.0 (4.0%) | 1/23.9 (4.2%) | 4/24.0 (16.6%) | 0/21.8 (0.0%) | 2/21.1 (9.5%) | 1/23.9 (4.2%)
Terminal rate | 1/25 (4.0%) | 0/20 (0.0%) | 2/20 (10.0%) | 0/20 (0.0%) | 1/19 (5.3%) | 0/21 (0.0%)
First incidence (days) | 319 (T) | 313 | 271 | — | 280 | 302
Poly-3 test vs. Vehicle Control | | P=0.750 | P=0.161 | P=0.527N | P=0.440 | P=0.751
Poly-3 test vs. AZT/3TC/NVP-H | P=0.751 | P=0.760N | P=0.173N | P=0.519 | P=0.455N

(T) Terminal kill

a AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b Historical incidence for control groups in 40- and 45-week heterozygous F1 p53^+/−^ mouse studies: 3/102, range 0.0%–8.0%

c Number of animals with neoplasm per number of animals with liver examined microscopically

d Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

e Observed incidence at terminal kill

f Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in a dose group is indicated by N.

g Beneath the dose group incidence are the P values corresponding to pairwise comparisons between the AZT/3TC/NVP-H group and that dose group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in a dose group is indicated by N.

h Historical incidence: 1/101, range 0.0%–4.0%

Kidney: In males, the incidence of protein casts in the AZT/3TC/NVP-H group and the incidences of hydronephrosis in the AZT/3TC/NVP-L and AZT/3TC/NVP-H groups were significantly greater than those in the vehicle control group. The incidences of these lesions also exhibited positive trends (P=0.019 and P=0.006, respectively) (Tables 11 and A3).

Spleen: The incidence of hematopoietic cell proliferation in female mice in the AZT/3TC/NVP-M group was significantly increased compared to that in the vehicle control group, and the incidences of this lesion exhibited a positive trend (P=0.007) (Tables 11 and A9).

Litter Correlation Analysis: Because up to two litter-mates per sex were used to populate the 45-week study, statistical analysis incorporating correlation of influence among littermates was also used to compute incidences of neoplasms (Appendix G). Statistical significance generally increased suggesting that there was a negative rather than positive correlation between lesion incidence and litter. However, these changes were insufficient to decrease the P values for neoplasm incidences below the 5% definition of significance.

## Genetic Toxicity

In 1-day-old mice, the percentages of total reticulocytes (RETs) were significantly decreased in groups exposed to doses that contained AZT, but not in the groups exposed to doses containing 3TC or NVP alone (Table B1). In addition, both the percentages of micronucleated normochromatic erythrocytes (NCEs) and the percentages of micronucleated RETs (except percent micronucleated RETs in AZT/3TC-H females) were significantly increased in groups exposed to doses containing AZT, but not in the 3TC-H or NVP-H groups. The percentages of micronucleated NCEs in the AZT/3TC/NVP-H groups were greater than in the AZT-H and the AZT/3TC-H groups. This suggests that the three-drug combination might potentiate the effect of AZT alone (Table B1); however, in blood from male pups evaluated at PND 28, the percentage of micronucleated RETs and the percentage of micronucleated NCEs were significantly increased in the group where 3TC was coadministered with AZT compared to the group administered only AZT (Table B2)

TABLE 11 Incidences of Selected Nonneoplastic Lesions in Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Male
Kidney^b^ | 25 | 25 | 23 | 23
Protein Casts^c^ | 3 (1.0)^d^ | 7 (1.0) | 7 (1.3) | 10^*^ (1.0)
Hydronephrosis | 1 (2.0) | 13^**^ (1.2) | 5 (1.2) | 12^**^ (2.0)
Female
Spleen | 25 | 25 | 22 | 25
Hematopoietic Cell Proliferation | 2 (2.5) | 2 (2.5) | 8^*^ (2.0) | 7 (2.6)

* Significantly different (P≤0.05) from the vehicle control group by the Poly-3 test

** P≤0.01

a AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg

b Number of animals with tissue examined microscopically

c Number of animals with lesion

d Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked