# MATERIALS AND METHODS

## Procurement and Characterization

AZT, 3TC, and NVP were obtained from Cipla Ltd., Mumbai Central (Mumbai, India) in single lots F60731, B10250, and FX1009, respectively. Identity and purity analyses were conducted by the study laboratory at the National Center for Toxicological Research (NCTR; Jefferson, AR) and Galbraith Laboratories, Inc. (Knoxville, TN) (Appendix F). To ensure stability, the bulk chemicals were stored in sealed amber jars at room temperature. Reports on analyses performed in support of the AZT, 3TC, and NVP in utero/postnatal gavage study are on file at the NCTR.

### AZT

Lot F60731 of the chemical, a white-to-beige crystalline solid, was identified as AZT using proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy, direct exposure probe/electron ionization (DEP/EI) mass spectrometry (MS), and liquid chromatography combined with mass spectrometry (LC-MS). Purity of lot F60731 was determined by proton and carbon-13 NMR spectroscopy, and high-performance liquid chromatography (HPLC).

No impurity resonances were detected by either proton or carbon-13 NMR analyses other than those associated with the solvent. HPLC detected no impurities with an overall purity of approximately 100%. The overall purity of lot F60731 was determined to be at least 99.9%.

### 3TC

Lot B10250 of the chemical, a white-to-off-white crystalline solid, was identified as 3TC using proton NMR spectroscopy, DEP/EI-MS, and LC-MS. Purity of lot B10250 was determined by elemental analyses, proton NMR spectroscopy, and HPLC.

Total impurity was estimated at 0.5% by proton NMR spectroscopy. HPLC detected one impurity with a peak area of 1.1% of the total peak area and estimated a purity of approximately 98.9%. The overall purity of lot B10250 was estimated to be approximately 99%.

### NVP

Lot FX1009 of the chemical, a white-to-off-white crystalline powder, was identified as NVP using proton NMR spectroscopy, DEP/EI-MS, gas chromatography/electron ionization MS, and LC-MS. Purity of lot FX1009 was determined by elemental analyses, proton NMR spectroscopy, and HPLC.

Karl Fischer titration indicated less than 0.14% water. Elemental analyses for carbon, hydrogen, and nitrogen were in agreement with the theoretical values for NVP. Total impurity was estimated at 0.2% by proton NMR. HPLC detected a single peak, indicating that the test article was 100.0% pure. The overall purity of lot FX1009 was estimated to be at least 99.5%.

### Dosing Vehicle

The vehicle used for dose formulations in this study was a 0.2% methylcellulose/0.1% Tween^®^ 80 aqueous solution. This vehicle was selected based upon preliminary experiments to find a vehicle that gave homogeneous formulations of the individual test articles and the test article combinations. Methylcellulose was obtained from Sigma-Aldrich Corporation (St. Louis, MO) in two lots (084K0065 and 125K0055) and Tween^®^ 80 was obtained from the same source in three lots (073K00643, 064K00631 and 125K01921). Proton and carbon-13 NMR analyses of methylcellulose lot 084K0065 were performed by the study laboratory, and spectra were consistent with those obtained previously for a methylcellulose standard obtained from Fischer Scientific (Fair Lawn, NJ).

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared by admixing the test chemicals with an aqueous solution of 0.2% methylcellulose/0.1% Tween^®^ 80 to give the required concentrations (Table F1). AZT and 3TC formed true solutions at the concentrations used, whereas NVP was insoluble and formed stable suspensions. The dose formulations were stored (with constant stirring) in sealed amber glass bottles at room temperature for up to 21 days.

Homogeneity and stability studies of 0.05 and 0.20 mg/mL formulations of AZT in the methylcellu-lose/Tween^®^ 80 vehicle and of high- and low-concentration mixtures of the three test chemicals in the dosing vehicle were conducted by the study laboratory using HPLC. Homogeneity was confirmed, and stability was confirmed for up to 29 days for the AZT formulations and for up to 21 days for the three-component formulations stored at room temperature in clear glass vials sealed with Teflon^®^-lined silicone rubber septa, that were stirred constantly.

At fifteen time points, analyses of the dose formulations of the antiretroviral drugs were conducted by the study laboratory using HPLC. Of the 161 measured concentrations of test chemical, 139 were within 10% of the target concentration; all preparations that were accepted for use were within 15% of their target concentrations (Table F2).

## Study Design

In utero exposure was selected to mimic exposures in humans and was begun at gestational day (GD) 12, a time period coinciding with administration of the test articles in the last third of pregnancy (DHHS, 2009).

Starting dosing at GD 12 also allows for maximal sensitivity for carcinogenesis studies of genotoxic agents (Rice, 1973; Anderson, 2004). Dosing was discontinued after postnatal day (PND) 28 to mimic the early postnatal Highly Active Antiretroviral Therapy (HAART) given to children of HIV-infected mothers. The doses for this study were selected to overlap human exposures based on established scaling factors (Freireich et al., 1966).

The study design incorporated a vehicle control and three-dose chronic study of HAART chemical mixtures of AZT, 3TC, and NVP. These constituent chemicals increased in the same proportion (1×, 2×, 3×) across the doses. The individual constituent chemicals were also tested alone at the highest dose in order to determine which was responsible for effects observed in the dose groups exposed to the mixtures.

Male and female heterozygous F1 p53^+/−^ mice were exposed to AZT, 3TC, NVP, AZT/3TC, or AZT/3TC/NVP in utero on GDs 12 through 18, then pups were administered the same chemical or combination of chemicals by gavage from PND 1 through PND 28 and then observed until 45 weeks of age (Figure 1). The concentrations of test chemicals varied based on the age of the pups as defined in Table 1. In general, pups were administered half the maternal dose from PND 1 to PND 10, but the dose concentration of NVP was further reduced from PND 1 to PND 3 to increase pup survival. Vehicle control mice received only an aqueous solution containing 0.2% methylcellulose and 0.1% Tween 80. The dosing volume was 10 mL/kg, except on PNDs 1 through 10, when the dosing volume was 3 mL/kg. Dams were dosed twice daily, 7 days per week, and pups were dosed twice daily, 5 days per week. Full details of the dosing technique have been published by Lewis et al. (2010).

FIGURE 1 Dosing Schedules for the 45-Week Study

Dosing Schedules for the 45-Week Study

Because of the complexity of the dosing regimen, where dose levels changed up to three times per group during the study, describing dose groups in conventional terms of the administered dose is not practical for this report. The dose groups are therefore described in terms of their constituent chemicals and concentration type, low (L), medium (M) and high (H), and are defined in terms of constituent chemical concentration (Table 1).

TABLE 1 Dosing Regimen for the 45-Week Study^a^

Treatment | AZT; (mg/kg/day) | 3TC; (mg/kg/day) | NVP; (mg/kg/day)
Dams GDs 12 through 18 and Pups
PNDs 11 to 28 (Dosing Volume = 10 mL/kg twice daily)
Vehicle Control | 0 | 0 | 0
AZT-H | 240 | 0 | 0
3TC-H | 0 | 150 | 0
NVP-H | 0 | 0 | 168
AZT/3TC-H | 240 | 150 | 0
AZT/3TC/NVP-L | 80 | 50 | 56
AZT/3TC/NVP-M | 160 | 100 | 112
AZT/3TC/NVP-H | 240 | 150 | 168
Pups PNDs 1 through 3
(Dosing volume =3 mL/kg twice daily)
Vehicle Control | 0 | 0 | 0
AZT-H | 120 | 0 | 0
3TC-H | 0 | 75 | 0
NVP-H | 0 | 0 | 21
AZT/3TC-H | 120 | 75 | 0
AZT/3TC/NVP-L | 40 | 25 | 7
AZT/3TC/NVP-M | 80 | 50 | 14
AZT/3TC/NVP-H | 120 | 75 | 21
Pups PNDs 4 through 10
(Dosing volume =3 mL/kg twice daily)
Vehicle Control | 0 | 0 | 0
AZT-H | 120 | 0 | 0
3TC-H | 0 | 75 | 0
NVP-H | 0 | 0 | 84
AZT/3TC-H | 120 | 75 | 0
AZT/3TC/NVP-L | 40 | 25 | 28
AZT/3TC/NVP-M | 80 | 50 | 56
AZT/3TC/NVP-H | 120 | 75 | 84

a GD = gestation day, PND = postnatal day

### Source and Specification of Animals

Female C3H/HeNTac wild-type mice and male C57BL/6(N12)Trp53^(−/−)^ mice were obtained under an academic breeding license from Taconic Farms, Inc. (Germantown, NY), and were received in four groups of 10 males and 50 females (an additional 48 females were supplied to compensate for low pup survival). The animals were quarantined for 14 days prior to being assigned to the study. Each male was mated with up to nine females in succession with up to two females per breeding cage at a time. Plug-positive females were provisionally assigned to the study on the morning that the vaginal plugs were identified, which was designated GD 0 for the study. The plug-positive animals were weighed daily and those not showing signs of pregnancy were removed from the study at GD 10 and returned to the breeding pool. The heterozygous F1 p53^+/−^ pups were born on GD 19 or 20 and the morning a litter was first observed was designated PND 0. On PND 1, each litter was examined, the sex of each pup was determined, and the litter was culled to six pups of equal sex ratio when possible.

### Animal Maintenance

Mouse dams were housed individually with litters until PND 21. Litters were weaned and housed with litter-mates from PND 21 to PND 29, then housed individually. Feed and water were available ad libitum, except mice were fasted overnight before necropsy. In order to monitor the health of animals, blood was drawn from one sentinel mouse dam during weeks 25, 38, and 51 and from one male and one female sentinel mouse pup during weeks, 26, 38, 51, 65, and 86 after receipt of the initial breeding mice. Sera were analyzed for antibody titers to rodent viruses; all results were negative. Further details of animal maintenance are given in Table 2.

### Clinical Examinations and Pathology

Animals were observed twice daily. Body weights were recorded daily for pregnant dams and for litters until PND 10; individual pups were weighed daily until PND 28 then weekly until the end of the studies. Clinical findings were recorded twice weekly.

All mice that survived to study termination were evaluated for hematology and clinical chemistry parameters. Blood was collected by cardiac puncture under CO_2_ anesthesia at the time of necropsy. The samples for clinical chemistry were allowed to clot then centrifuged. The serum was removed and frozen at −60° C until analysis. Whole blood for complete blood counts was collected in EDTA, and analysis was performed the same day as collection. Complete blood counts were determined on an ABX Pentra 60 C+ analyzer (ABX, Irvine CA). Clinical chemistry analyses were conducted on an Alfa Wassermann ALERA (West Caldwell, NJ). Alfa Wassermann reagents were used for alanine aminotransferase (Henry modification), alkaline phosphatase (modified Bowers and McComb), glucose (hexokinase), and total protein (biuret) analyses. The parameters measured are listed in Table 2.

Necropsies and microscopic examinations were performed on all mice. The brain, heart, left and right kidney, liver, and lung were weighed. At necropsy, all major tissues were examined grossly for visible lesions, and all major tissues were preserved in 10% neutral buffered formalin or Davidson’s solution (eyes and testes). The major tissues and gross lesions were trimmed, processed, and embedded in Formula R^®^, sectioned at approximately 5 µm, and stained with hematoxylin and eosin. When applicable, nonneoplastic lesions were graded for severity as 1 (minimal), 2 (mild), 3 (moderate), or 4 (marked).

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Laboratory Data Aquisition System (LDAS) database. The slides, individual animal data records, and pathology tables were evaluated by the Toxicologic Pathology Associates (Jefferson, AR) and NCTR quality assurance units. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. A quality assessment pathologist evaluated slides from all tumors; there were no designated target organs. Tissues examined microscopically are listed in Table 2.

The quality assessment report and the reviewed slides were submitted to the NTP Pathology Working Group (PWG) coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and quality assessment pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and quality assessment pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the quality assessment pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups or previously rendered diagnoses. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist, and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman (1982) and Boorman et al. (1985). For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al. (1986).

TABLE 2 Experimental Design and Materials and Methods in the In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP

Study Laboratory
National Center for Toxicological Research (Jefferson, AR)
Strain and Species
Transgenic mouse model (C3H/HeNTac × B6.129SvEv)F_1_^+/−^Trp53^tm1Brd^ (abbr, C3B6F1^+/−^Trp53^tm1Brd^ or C3B6F_1_Trp53^(+/-)^ or heterozygous F1 p53^+/−^). Dams were C3H/HeNTac; sires were C57BL/6(N12)Trp53^-/-^
Animal Source
Dams and sires, Taconic Farms, Inc. (Germantown, NY); pups, National Center for Toxicological Research
Time Held Before Study
Male and female breeders, 6 weeks of age, were maintained 14 days in quarantine and were allocated to study.
Age When Study Began
Breeders were 8 weeks old at breeding; dosing of dams began on GD 12
Initial Conception Date
Start date for first breeders was 12/21/2006; first conception date: 12/22/2006
Start date of last breeders was 9/9/2007; last conception date: 9/21/2007
Duration of Dosing
GDs 12 through 18, then PNDs 1 through 28; observed through week 45
Date of Last Dose
11/08/2007
Date of Necropsy
07/15/2008
Age at Necropsy
45 weeks for terminal sacrifice; early deaths and moribund animals were also necropsied
Size of Study Groups
25 or 26 males and 24 or 25 females
Animals per Cage
One male and up to two females during breeding; dams housed individually with litters until PND 21; pups housed with littermates PNDs 21 to 28 then individually beginning PND 29
Method of Animal Identification
Paw tattoo (by PND 11), ear clipped at PND 21, tail tattoo with cage bar code number
Diet
NIH-31 autoclavable pellets (5022CGP3, Lab Diet, Purina Mills, Inc., St. Louis, MO) available ad libitum until day before necropsy
Water
Millipore-filtered water (Jefferson, AR, municipal supply) via plastic water bottles fitted with rubber stoppers and sipper tubes (bottles: Allentown Caging Equipment Co., Inc., Allentown, NJ; stoppers and tubes: Ancare Corp., Bellmore, NY), available ad libitum
Cages
Polycarbonate single mouse cages for breeder males and females with litters. After PND 29, offspring were housed individually in polycarbonate double cages with dividers (Allentown Caging Equipment Co., Inc., Allentown, NJ, and Lab Products, Seaford, DE), changed weekly, rotated monthly
Bedding
Hardwood chip bedding (Northeastern Products Corp., Warrensburg, NY), changed weekly for animals housed individually and twice weekly for cages with litters present
Cage Filters
Micro-vent cage filtration with 0.2 micron HEPA filter (Allentown Caging Equipment Co., Inc., Allentown, NJ), changed weekly
Racks
Stainless steel (Allentown Caging Equipment Co., Inc., Allentown, NJ), changed every 3 weeks
Animal Room Environment
Temperature: 22° ± 4° C
Relative humidity: 40%–70%
Room fluorescent light: 12 hours/day
Room air changes: 10–15/hour
Doses
Dams GDs 12 through 18 and Pups PNDs 11 through 28, dosing volume 10 mL/kg twice daily.
AZT-H: 240 mg/kg AZT
3TC-H: 150 mg/kg 3TC
NVP-H: 168 mg/kg NVP
AZT/3TC-H: 240/150 mg/kg AZT/3TC
AZT/3TC/NVP-L: 80/50/56 mg/kg AZT/3TC/NVP
AZT/3TC/NVP-M: 160/100/112 mg/kg AZT/3TC/NVP
AZT/3TC/NVP-H: 240/150/168 mg/kg AZT/3TC/NVP
Pups PNDs 1 through 3, dosing volume 3 mL/kg twice daily
AZT-H: 120 mg/kg AZT
3TC-H: 75 mg/kg 3TC
NVP-H: 21 mg/kg NVP
AZT/3TC-H: 120/75 mg/kg AZT/3TC
AZT/3TC/NVP-L: 40/25/7 mg/kg AZT/3TC/NVP
AZT/3TC/NVP-M: 80/50/14 mg/kg AZT/3TC/NVP
AZT/3TC/NVP-H: 120/75/21 mg/kg AZT/3TC/NVP
Pups PNDs 4 through 10, dosing volume 3 mL/kg twice daily
AZT-H: 120 mg/kg AZT
3TC-H: 75 mg/kg 3TC
NVP-H: 84 mg/kg NVP
AZT/3TC-H: 120/75 mg/kg AZT/3TC
AZT/3TC/NVP-L: 40/25/28 mg/kg AZT/3TC/NVP
AZT/3TC/NVP-M: 80/50/56 mg/kg AZT/3TC/NVP
AZT/3TC/NVP-H: 120/75/84 mg/kg AZT/3TC/NVP
Dosing was twice daily, 7 days/week from GD 12 through GD 18 and then twice daily, 5 days/week from PND 1 through PND 28
Method of Distribution
Sires and dams were assigned to breeding cages randomly; pregnant dams were assigned to dose groups so as to maximize the distribution of an individual sire’s progeny across the dose groups.
Type and Frequency of Observation
Observed twice daily; body weights recorded daily for pregnant dams, for litters until PND 10, and for individual pups from PNDs 11 through 28, then weekly for individual pups; clinical findings were recorded twice weekly
Method of Sacrifice
CO_2_ asphyxiation
Necropsy
All mice were necropsied. Organs weighed were brain, heart, left and right kidney, liver, and lung.
Clinical Pathology
At the end of the study, blood was collected via cardiac puncture under carbon dioxide anesthesia for hematology and clinical chemistry.
Hematology: hematocrit, erythrocyte and platelet counts, mean cell volume, mean cell hemoglobin, mean cell hemoglobin concentration, and leukocyte count and differentials
Clinical chemistry: alanine aminotransferase, alkaline phosphatase, blood glucose, lactic acid, and total protein
Histopathology
Complete histopathology was performed on all mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, blood vessel, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder, Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis and seminal vesicle, thymus, thyroid gland, trachea, urinary bladder, uterus, and vagina.

## Statistical Methods

Two substudies were analyzed separately. The first substudy, termed the combination dose comparison, compared the vehicle control group to the different dose level group (L, M, and H) of the AZT/3TC/NVP combination. This is a one-way substudy and the results are presented in that format with dose trend and comparisons to the vehicle control group. The second substudy, termed the high dose comparison, compared high doses of the six drug combinations to one another. These six combinations were: vehicle control, AZT-H, 3TC-H, NVP-H, AZT/3TC-H, and AZT/3TC/NVP-H. Because there is not necessarily any directionality among the comparisons with the exception of the comparisons to the vehicle control group, a single-sided test was used with “N” appended to denote negative comparisons. The alpha-level was 5% for comparisons to the vehicle control group but 2.5% for comparisons among combinations.

### Survival Analyses

Survival was analyzed using the proportional hazards model (Cox, 1972). All vehicle control female pups survived to terminal sacrifice. To allow reasonable inferences, synthetic events were added to all female treatment groups. These events were uncorrelated to any litters, were given event times of 336 days, and were weighted as one-half of an actual pup.

Four covariance models were run to account for clustering. The first model assumed pup independence and used the usual Cox model-based covariance estimates. The second model assumed pup independence but used the unaggregated sandwich-estimator empirical covariance (Lin and Wei, 1989). The model was run to assess the impact of using the empirical covariance estimate alone, regardless of intralitter correlation. The third model assumed correlation within litters by aggregating the sandwich-estimator empirical covariance (Binder, 1992). The fourth model assumed correlation within sires by aggregating the sandwich-estimator empirical covariance.

### Analysis of Continuous Variables

In addition to the standard repeated-measures mixed model for predicting body weight based on a fixed treatment group effect and age, this study required the addition of a random litter effect to account for correlation among littermates. Furthermore, since the correlation could be negative within litters, the mixed model specified the litter effect in the “R” matrix rather than the “Z” matrix. In this study, pups share the dam and littermates (implicitly dam-mates) are one possible correlation. However, multiple litters can share a common sire and sire-mates are another possible correlation. Therefore, three correlation models had to be conducted: unadjusted (assumes pup independence), dam-adjusted (assumes correlation among littermates but independence among litters), and sire-adjusted (assumes pups from different sires are independent). The combination of the heteroscedastic variance over time coupled with the litter correlation makes a repeated-measures model difficult. Therefore, since the time course is not really of great concern, a basic mixed model was run by time point. Dunnett’s adjustment was used to compare to the vehicle control group.

The log-rank test (Kalbfleisch and Prentice, 1980) was used for the one-way subdesigns. This test makes no adjustment for litter clusters. It does allow adjustment for multiple comparisons. In this report, Kramer’s extension of Tukey’s method (Kramer, 1956) was used when all comparisons were of interest while Hsu’s extension of Dunnett’s test (Hsu, 1992) was used where comparisons to the vehicle control group are of primary interest. Because there is not necessarily any directionality among the comparisons with the exception of the comparisons to the vehicle control group, the analyses used two-sided tests. The relative hazard ratios indicate the direction. Two substudies, as described for survival analysis, were analyzed separately.

For the organ weight analysis, the same three correlation models were run: unadjusted (assumes pup independence), dam-adjusted (assumes correlation among littermates but independence among litters), and sire-adjusted (assumes pups from different sires are independent). However, because the correlation model generally made no difference in the conclusions, the report lists only the dam-adjusted correlation structure. Dunnett’s tests (Dunnett, 1955) were used to compare to the particular control group (vehicle control or AZT/3TC/NVP-H).

The organ weight endpoint was analyzed as an absolute value using no covariate and as a relative ratio to body weight. Because survival may have impacted some organ weights, the analyses were conducted on the sub-group of terminal kill animals.

Clinical pathology data and pup survival within litters to PND 10 were analyzed in SAS (version 9.1) under the SAS General Linear Models program to produce means, standard error values and evaluation of significant differences between dose groups. Combination dose comparisons were evaluated using a Dunnett test and a linear trend test. A Tukey test was used for the high dose comparison of constituent chemicals.

### Calculation of Lesion Incidences and Severities

The incidences of neoplasms or nonneoplastic lesions are presented in Tables A1, A3, A4, A6, A7, A9, A10, and A12 as the number of animals bearing such lesions at a specific anatomic site and the number of animals with that site examined microscopically. For all neoplasms and nonneoplastic lesions, the Poly-3 method of Bailer and Portier (1988) as modified by Bieler and Williams (1993) and NIEHS (continuity-correction) was used to analyze age-adjusted incidence (Tables A2, A5, A8, and A11).

To adjust for intralitter correlation, the Poly-3 method was envisioned as a weighted regression with binomial weights. This allows the methods of generalized linear models to be utilized with generalized estimating equation methods to allow for the estimation of intracluster correlation and adjustment for this. The binomial event is then the simple flag variable indicating whether the subject had the tumor of interest. The binomial trials count is 1 if the animal had the tumor of interest or lived to terminal sacrifice. Otherwise, it is the Poly-3 adjusted fractional value. For this study, we did not attempt to use quasi-likelihood (McCullagh and Nelder, 1989) to implement the Bieler and Williams variance correction model. This means that a uniform dose group (that is, all successes or all failures) leads to invalid variance estimates. To fix this issue, dummy events were added, if necessary, to break the uniformity. If added, they were added to all groups equally. These augmented records were assigned to dummy litters to prevent interaction with the correlation estimates. The weights of these dummy events were set to 0.005.

The model was fit using an ANOVA-style effects model with appropriate contrasts. This differs from the Poly-3 method, which is run as a series of individual regressions. This was done primarily to prevent the intralitter correlation from wobbling too much. It seems unlikely that the dose should alter the intralitter correlation but fitting the model as a series of regressions would allow this. The model-estimated means are reported as the Poly-3, cluster-adjusted incidences for these models. The decision on whether to include a lesion or lesion pool was based on this adjusted incidence exceeding 5%.

For nonneoplastic lesions, the non-zero severity score averages were computed and, to incorporate lesion severity scores, the distribution-free (but unadjusted for age or clustering) method of Jonckheere (1954) and Terpstra (1952) was used to compute monotonic trend tests and the method of Shirley (1977) as modified by Williams (1986) was used to compute comparisons to control. These results are listed as JT/SW within the tabulated results.

## Quality Assurance Methods

The 45-week study was conducted in compliance with FDA Good Laboratory Practice Regulations (21 CFR, Part 58). In addition, records from these studies including protocols and any amendments, deviations, or related information; study-related standard operating procedures (SOPs) and documentation; test article accountability and characterization; raw data generated in operational areas as defined in applicable SOPs; computer records containing INLIFE and pathology raw data; and daily animal room logs and a copy of the laboratory study report will be submitted to the NCTR Archives.

## Genetic Toxicology

Peripheral blood was collected at sacrifice from excess heterozygous F1 p53^+/−^ mice that were culled on PND 1 or PND 28, and aliquots were diluted with anticoagulant, fixed in cold (−80° C) methanol, and stored at −85° C. The fixed blood samples were shipped to Litron Laboratories (Rochester, NY) on dry ice for analysis. Micronucleated cells were identified and quantified using the MicroFlow^PLUS^ mouse kit from Litron Laboratories (Dertinger et al., 1996b, 2006). Briefly, reticulocytes were identified by fluorescein isothiocyanate-labeled antibodies against the CD71 mouse surface antigen, platelets were identified by phycoerythrin-labeled antibodies against CD61 antigen, and DNA, including micronuclei, was stained with propidium iodide. Data provided by Litron was sorted in the form of sorted spreadsheets of differences in reticulocyte micronucleus frequency between dose groups, and as audited study reports which have been added to the Study Archive. The spreadsheet data were then analyzed at NCTR in SAS (version 9.1) to produce means, standard error values, and significant differences between dose groups via a Tukey test evaluation run under the SAS General Linear Models program. Only one male and/or one female pup from any one litter were evaluated so that potential litter effects were eliminated.