# INTRODUCTION

3′-AZIDO-3′-DEOXYTHYMIDINE

CAS No. 30516-87-1

Chemical Formula: C_10_H_13_N_5_O_4_ Molecular Weight: 267.24

Synonyms: 3′-azido-2′,3′-dideoxythymidine; azidodeoxythymidine; azidothymidine; 3′-azidothymidine; AZT; BW A509U; Compound S; 3′-deoxy-3′-azidothymidine; 3′-deoxy-(8CI) (9CI); ZDV; zidovudine.

Trade name: Retrovir^®^ [Combivir^®^ with 3TC]

Molecular Structure of A Z T

2′,3′-DIDEOXY-3′-THIACYTIDINE

CAS No. 134678-17-4

Chemical Formula: C_8_H_11_N_3_O_3_S Molecular Weight: 229.26

Synonyms: 3TC; 4-amino-1-[(2R,5S)-2-(hydroxymethyl)-1,3-oxathiolan-5-yl]-1,2-dihydropyrimidin-2-one; L-2′,3′-dideoxy-3′-thiacytidine; lamivudine

Trade name: Epivir^®^ [Combivir^®^ with AZT]

Molecular Structure of 3 T C

NEVIRAPINE

CAS No. 129618-40-2

Chemical Formula: C_15_H_14_N_4_O Molecular Weight: 266.30

Synonyms: NVP; 11-cyclopropyl-4-methyl-5,11-dihydro-6H- dipyrido[3,2-b:2′,3′-e][1,4]diazepin-6-one

Trade Name: Viramune^®^

Molecular Structure of N V P

## Chemical and Physical Properties

### AZT

3′-Azido-3′-deoxythymidine (AZT) is a dideoxynucleoside of thymine and a structural analogue of 2′-deoxythymidine, and it is the most widely used and evaluated chemotherapeutic agent for the treatment of persons with acquired immune deficiency syndrome (AIDS) and persons seropositive for human immuno-deficiency virus (HIV). AZT is a white to off-white, odorless, crystalline solid that is moderately soluble in water (20 mg/mL) and alcohol (71 mg/mL) at 25° C. Aqueous solutions of AZT are clear to pale yellow and are mildly acidic (e.g., pH 5.5 for a 10 mg AZT/mL solution) (NTP, 2006).

### 3TC

Lamivudine (3TC) is an (−) enantiomer analogue of cytidine. 3TC is a white to off-white crystalline solid, with a solubility of approximately 70 mg/mL in water at 20° C (PDR, 2010a). It has a melting point of 160° to 162° C after recrystallization from ethanol (Merck, 2006a).

### NVP

Neverapine (NVP) is a white to off-white crystalline powder (PDR, 2010b). At neutral pH, NVP has a solubility in water of approximately 100 µg/mL; it is highly soluble in water at pHs below 3. NVP has a melting point of 247° to 249° C after recrystallization from aqueous pyridine (Merck, 2006b) or ethyl acetate (Hargrave et al., 1991).

## Production, Use, and Human Exposure

### AZT

AZT was first synthesized in 1964 by Horwitz et al. (1964), and it was subsequently reported by Mitsuya et al. (1985) to inhibit HIV replication in vitro at concentrations ranging from 50 to 500 nmol/L. Clinical activity for the treatment of AIDS was first reported by Yarchoan et al. (1986), and the drug was commercially developed by Burroughs Wellcome Company (Research Triangle Park, NC), under the trade name Retrovir^®^, which was approved by the Food and Drug Administration in March 1987, as the first nucleoside analogue reverse transcriptase inhibitor (NRTI) for the treatment of adult patients with AIDS or advanced AIDS-related complex (Anonymous, 1987; Brook, 1987). By May 2007, patent restrictions on all forms of AZT had expired allowing the United States Food and Drug Administration (FDA) to complete approval of a full range of generic alternatives for patented AZT formulations (Anonymous, 2007). Currently, AZT is available in capsules or syrup for oral administration and in formulations suitable for intravenous infusion. These include: solutions containing 10 mg AZT/mL for oral or intravenous administration, and capsules of either 100 or 300 mg AZT alone, or combination capsules containing either 300 mg AZT with 150 mg 3TC, or 300 mg AZT with 150 mg of 3TC and 300 mg of the NRTI, abacavir (DHHS, 2008a).

Antiviral therapy is essential for treatment and prevention of AIDS in adults and children infected with HIV, and to prevent mother-to-child transmission of HIV during pregnancy and labor (DHHS, 2008a,b). AZT is a primary drug of choice for pediatric prophylactic monotherapy in infants at risk for contracting HIV and as part of triple drug combination Highly Active Antiretroviral Therapy (HAART) for infants and children infected with HIV (Cansaran et al., 2006). Typical pediatric doses range from 1.5 mg AZT/kg body weight by intravenous infusion or 2 mg/kg orally every 12 hours for term neonates to 100 mg, three times daily for children weighing more than 30 kg (Cansaran et al., 2006). When included as part of a therapeutic regimen to prevent mother-to-child transmission of HIV, AZT has been shown to prevent the vertical transmission of HIV by nearly 70% (7.2% in treated patients versus 21.9% in a placebo control group) (Connor et al., 1994). AZT is currently a primary drug of choice for combination HAART or prophylactic treatment in pregnant women who are HIV positive, and it is the primary drug of choice for intravenous infusion during labor (PHS, 2008).

In 2007 there were an estimated 30 to 36 million people living with HIV infections worldwide, of which approximately half were women (UNAIDS, 2008). During 2007, 2.2 to 3.2 million new HIV infections occurred while 1.8 to 2.3 million people died from causes related to HIV. Estimates in 2007 suggested that there were 0.69 to 1.9 million people living with HIV infections in the United States, of which 140,000 to 400,000 were women (UNAIDS, 2008). Earlier estimates (WHO, 2004) have suggested that worldwide, some 2.2 million HIV-infected women give birth each year and that approximately 700,000 of their neonates become infected.

### 3TC

3TC was initially synthesized as a racemate in 1991 (Soudeyns et al., 1991) and then in enantiomerically pure forms in 1992 (Beach et al., 1992; Humber et al., 1992). 3TC (as 3TC 5′-triphosphate) is thought to inhibit viral reverse transcriptase by competing with deoxycytidine 5′-triphosphate for incorporation into human immunodeficiency virus type-1 (HIV-1) DNA (Perry and Faulds, 1997). When used for the management of HIV-1 infections, 3TC is recommended to be used in combination with another NRTI (e.g., AZT) and either a protease inhibitor such as lopinavir/ritonavir, or a nonnucleoside reverse transcriptase inhibitor such as NVP (DHHS, 2011). In adults, the recommended daily dose is 300 mg, in either one or two doses (PDR, 2010a). Pediatric patients older than 3 months of age are given 4 mg/kg, twice daily, up to a maximum daily dose of 300 mg. Pregnant HIV-1-positive women are administered 3TC (150 mg twice daily) in combination with AZT beginning at 32 weeks of gestation; their off-spring receive 2 mg 3TC, twice daily, until 6 weeks of age (DHHS, 2008b). 3TC is also administered in combination with AZT, tenofovir, stavudine, or didanosine for postexposure prophylaxis of HIV-1 infection in individuals who are exposed to HIV-1 either occupationally or nonoccupationally (DHHS, 2008a). These regimens can be expanded by the inclusion of a protease inhibitor or a nonnucleoside reverse transcriptase inhibitor. 3TC is also used for the management of chronic hepatitis B virus; clinical trials indicate that 100 mg daily is more efficacious than 20 mg daily (PDR, 2010a).

### NVP

NVP, a nonnucleoside reverse transcriptase inhibitor (Merluzzi et al., 1990), was first synthesized in 1991 (Hargrave et al., 1991). NVP inhibits HIV-1 reverse transcriptase noncompetitively by binding to an allosteric site on the enzyme (Cohen et al., 1991; Wu et al., 1991). This action is specific for HIV-1 reverse transcriptase (Merluzzi et al., 1990; Koup et al., 1991; Richman et al., 1991).

NVP is usually given as part of a three-drug regimen. Typical regimens in adults and adolescents include NVP and 3TC or emtricitabine and AZT or tenofovir (DHHS 2008a,b; PHS, 2008). The recommended initial dose of NVP is 200 mg daily for the first 14 days and then 200 mg twice daily (PDR, 2010b). In pediatric patients, the recommended initial dose is 4 mg/kg body weight per day for the first 14 days and then 7 mg/kg twice daily for children less than 8 years of age or 4 mg/kg twice per day for children 8 years of age and older, with the total dose not to exceed 400 mg per day (PDR, 2010b). NVP is also given to prevent mother-to-child transmission of HIV-1. In women who have not received prior antiretroviral therapy, this typically involves a single 200 mg dose at the onset of labor followed by a single 2 mg/kg dose to the infant (PHS, 2008). NVP is also used as part of the three-part AZT regimen to prevent mother-to-child transmission of HIV-1.

## Pharmacology

### AZT

The antiviral activity of AZT depends on its conversion to a nucleotide triphosphate (3′-azido-2′,3′-dideoxythymidine 5′-triphosphate or AZTTP). AZT enters mammalian cells by nonfacilitated diffusion (Zimmerman et al., 1987), and it is then phosphorylated in successive reactions primarily catalyzed in proliferating cells by thymidine kinase 1, thymidylate kinase, and nucleoside diphosphokinase present in cell cytosol, resulting in AZTTP (Avramis et al., 1989; Törnevik et al., 1995; Bradshaw et al., 2005). AZTTP is a substrate for HIV reverse transcriptase and a competitive inhibitor of deoxythymidine triphosphate. Because the 3′ position of AZT is blocked with an azido group, incorporation of AZTTP into a growing polynucleotide chain (e.g., viral DNA) terminates elongation at that position. Thus, AZT intervenes at a relatively early stage of the viral replication cycle. AZTTP is also a substrate for cellular DNA polymerases; however, the K_i_ and K_m_ of AZTTP for HIV reverse transcriptase are considerably lower than for cellular DNA polymerases. Accordingly, AZTTP inhibits viral replication at doses lower than those at which it is an efficient substrate for the cellular DNA polymerases (Furman et al., 1986; Huang et al., 1990; Parker et al., 1991).

### 3TC

3TC is converted to an active antiretroviral agent by sequential 5′-phosphorylation to 3TC 5′-phosphate (catalyzed by deoxycytidine kinase) (Shewach et al., 1993), 3TC 5′-diphosphate, and 3TC 5′-triphosphate (catalyzed by unspecified kinases) (Cammack et al., 1992; Hart et al., 1992). In a manner similar to AZT, 3TC 5′-triphosphate is thought to inhibit HIV-1 by acting as a competitive inhibitor for HIV-1 reverse transcriptase (K_i_ = 0.57 to 12 µM) (Hart et al., 1992; Riska et al., 1999a) and by causing chain termination upon incorporation into proviral DNA (Perry and Faulds, 1997). 3TC 5′-triphosphate is also a substrate for mammalian DNA polymerases α, β, γ, and ε, with K_i_s of 110 to 175, 10 to 25, 4 to 44, and 120 µM, respectively (Hart et al., 1992; Martin et al., 1994; Riska et al., 1999a; Kakuda, 2000).

### NVP

In contrast to AZT, 3TC, and other NRTIs, which require metabolic conversion to triphosphate derivatives in order to inhibit HIV-1 reverse transcriptase, NVP binds directly to the enzyme. This interaction is not through the reverse transcriptase catalytic site, but rather through an adjacent pocket that appears to involve two lysine residues. The interaction, which is noncompetitive in nature, does not prevent the binding of nucleo-side triphosphate substrates, but rather prevents the formation of a productive complex (Cohen et al., 1991; Koup et al., 1991; Wu et al., 1991; Smerdon et al., 1994; Spence et al., 1995). The K_i_ of NVP for HIV-1 reverse transcriptase is 200 nM, and it shows no inhibitory activity against mammalian DNA polymerases α, β, γ, or δ (Merluzzi et al., 1990).

## Absorption, Distribution, Metabolism, and Excretion

### AZT

Following oral administration, AZT is rapidly absorbed, and after oral or intravenous administration it is rapidly distributed (NTP, 2006). Elimination is also rapid, with essentially all parent drug and its metabolites being completely excreted within 24 hours (Singlas et al., 1989; Taburet et al., 1990; Child et al., 1991; Stagg et al., 1992). However, there are significant interspecies differences in the extent to which the parent compound is metabolized (NTP, 2006). In humans and monkeys, the majority of an administered dose is converted to the 5′-O-glucuronide and eliminated in urine along with unmetabolized parent drug and a minor metabolite, 3′-amino-2′,3′-dideoxythymidine (AMT), formed by reduction of the 3′-azido group of AZT. However, in rodents, the majority of absorbed AZT is eliminated in urine as the parent compound with relatively little conversion to the glucuronide or to AMT (Singlas et al., 1989; de Miranda et al., 1990; Good et al., 1990; Cretton et al., 1991; Mays et al., 1991; Stagg et al., 1992; Trang et al., 1993). The reduced metabolism in rodents results in equivalent doses producing greater C_max_ values than for humans, but plasma half-life values are similar to humans (Doshi et al., 1989; Patel et al., 1989; Trang et al., 1993). The glucuronide of AMT has been reported to be a minor urinary metabolite in monkeys and a minor biliary metabolite in humans, but it has not been identified in rats (de Miranda et al., 1990).

### 3TC

3TC is rapidly absorbed and distributed. In mice treated orally, 3TC has a T_max_ of 30 minutes and a t_1/2_ of 110 minutes (Williams et al., 2003), values that are appreciably greater than those observed with AZT. Comparable values after intravenous administration are 5 minutes (T_max_) and 96 minutes (t_1/2_) (Williams et al., 2003). In mouse fetuses exposed transplacentally, 3TC has a T_max_ of 60 minutes and a t_1/2_ of 161 minutes, the latter being considerably greater than the t_1/2_ of 44 minutes observed in the dams (Von Tungeln et al., 2007). In addition, the C_max_ is substantially less in the fetuses as compared to the dams (Von Tungeln et al., 2007).

3TC has a t_1/2_ of 105 minutes in rats treated intravenously (Alnouti et al., 2005). Rat fetuses exposed transplacentally to 3TC have C_max_ and AUC values that are appreciably less than those observed in the dams (Alnouti et al., 2005). Domestic cats dosed intravenously with 3TC have a t_1/2_ of 114 minutes; the comparable values after intragastric and oral dosing are 150 and 138 minutes, with T_max_ values of 30 and 66 minutes, respectively (Zhang et al., 2004). The oral bioavail-ability of 3TC in cats is 80%. Woodchucks (Marmota monax) treated orally or intravenously with 3TC have a t_1/2_ of 170 minutes; the oral bioavailability is 18% to 54% (Rajagopalan et al., 1996). In rhesus monkeys dosed intravenously, 3TC has a t_1/2_ of 84 minutes (Blaney et al., 1995). The T_max_ and t_1/2_ of 3TC in Erythrocebus patas (http://www.google.com/search?hl=en&client=firefox-a&hs=yZy&rls=org.mozilla:en-US:official&sa=X&ei=pR2CToOlBKzKsQK9pNiFDw&ved=0CBoQvwUoAQ&q=Erythrocebus+patas&spell=1) monkeys given an oral mixture of AZT and 3TC are 50 and 136 minutes, respectively (Divi et al., 2008).

In humans administered 3TC orally, the T_max_ is approximately 1 hour, the t_1/2_ is 3.5 to 11.5 hours, and the bioavailability is 86% (Perry and Faulds, 1997; King et al., 2002; PDR, 2010a). The t_1/2_ for 3TC in infants and children appears to be slightly shorter than in adults (Perry and Faulds, 1997; King et al., 2002).

In humans and experimental animals, the majority of 3TC is excreted unchanged, primarily in the urine. The percent excreted as 3TC varies across species, with 75% being reported in rats (Rajagopalan et al., 1996), 26% in woodchucks (Rajagopalan et al., 1996), 32% to 59% in rhesus monkeys (Blaney et al., 1995), and 68% to 71% in humans (Dudley, 1995; PDR, 2010a). Other than 5′-phosphate derivatives, the only reported metabolite of 3TC is 3TC sulfoxide, which has been detected in the urine of dogs and humans (Plumb et al., 1996; PDR, 2010a).

### NVP

NVP is readily absorbed following oral dosing. In chimpanzees, more than 64% of an oral dose is bio-available (Cheeseman et al., 1993); the corresponding value in humans is greater than 90% (Lamson et al., 1999; PDR, 2010b), with a T_max_ occurring 1.3 to 4.6 hours after dosing (Cheeseman et al., 1995; Lamson et al., 1999; PDR, 2010b). Compared to AZT and 3TC, NVP is eliminated very slowly. In chimpanzees, the t_1/2_ is 11 to 24 hours (Cheeseman et al., 1993), while the value in humans after a single oral dose is 40 to 51 hours (Cheeseman et al., 1993; Lamson et al., 1999; Riska et al., 1999a). A similar t_1/2_ is obtained following intravenous dosing (Lamson et al., 1999). Repeated administration of NVP to humans results in a decrease in t_1/2_ (Riska et al., 1999a), possibly resulting from autoinduction of cytochrome P450 (CYP) enzymes. The t_1/2_ in infants appears to be greater than that in adults (Luzuriaga et al., 1996; Mirochnick et al., 1998).

The disposition, biotransformation, and elimination of NVP have been reported in mice, rats, rabbits, dogs, monkeys (cynomolgus), chimpanzees, and humans (Riska et al., 1999a,b). In mice, rabbits, monkeys, and humans, urinary excretion is approximately twice that found in feces. The distribution is approximately equal in rats, and in dogs fecal excretion predominates due to poor absorption of the drug. NVP is extensively metabolized. Among the identified metabolites are 3- and 8-hydroxy-NVP, 4-hydroxymethyl-NVP (12-hydroxy-NVP), 4-carboxy-NVP, and 2-, 3-, 8-, and 12-hydroxy-NVP glucuronide. The major urinary metabolites in dogs, monkeys, chimpanzees, and humans are glucuronides, primarily of 2-, 3-, and 12-hydroxy-NVP. In rats and mice, 12-carboxy-NVP is the predominant urinary metabolite. In dogs, unchanged NVP is the primary “metabolite” found in the feces. In the other species, the major fecal metabolite is 4-carboxy-NVP or 3-hydroxy-NVP.

In humans, the formation of 2-hydroxy-NVP is attributed to the CYP3A subfamily, 3-hydroxy-NVP to CYP2B6, 8-hydroxy-NVP to CYP3A4, CYP2B6, and CYP2D6, and 12-hydroxy-NVP to CYP3A4 and, possibly, CYP2D6 and CYP2C9 (Erickson et al., 1999). Recently, an NVP-glutathione conjugate has been detected upon the incubation of NVP with human liver microsomes in the presence of glutathione (Wen et al., 2009). The NVP-glutathione conjugate formation was catalyzed primarily by CYP3A4 and to a lesser extent by CYP2D6, CYP2C19, and CYP2A6. The oxidation of NVP by CYP3A4 also caused mechanism-based inactivation of the enzyme. In vitro studies have demonstrated that NVP is a potent inducer of both CYP2A6 and CYP3A4 isoforms in primary human hepatocytes (Faucette et al., 2007). The induction is mediated by both the PXR and CAR gene activation pathways, but NVP is a preferential CAR/CYP2B6 inducer rather than a PXR/CYP3A4 inducer (Faucette et al., 2007). The induction of CYP3A-related monooxygenase activity also occurs in rats exposed to NVP (Walubo et al., 2006).

## Toxicity

### Experimental Animals

#### AZT

In animals, AZT causes hematologic toxicities (Thompson et al., 1991) and impaired function of the electron transport chain in cardiac and skeletal muscle mitochondria (Lamperth et al., 1991; Walker et al., 2004). The latter are associated with morphological damage including enlarged mitochondria with disorganized or absent cristae (Lamperth et al., 1991; Lewis et al., 1992). In Sprague-Dawley rats administered 1 mg AZT/mL drinking water for 35 days, decreases in mitochondrial DNA, RNA, and protein synthesis were observed in skeletal muscle mitochondria (Lewis et al., 1992). AZTTP is an inhibitor and alternate substrate for mitochondrial DNA polymerase γ from both skeletal and cardiac muscle (Simpson et al., 1989; Lewis et al., 1994), and therefore it is possible that AZT, via AZTTP, is acting as an inhibitor and chain terminator, disrupting mitochondrial DNA synthesis. However, more recent evidence suggests that AZT is also a potent inhibitor of thymidine phosphorylation in mitochondria resulting from its inhibition of mitochondrial thymidine kinase 2 (Johnson et al., 1989; Lynx and McKee, 2006; Susan-Resiga et al., 2007). This enzyme plays a secondary role in the conversion of thymidine into thymidine monophosphate in rapidly dividing cells, which express cytosolic thymidine kinase 1, but in nonmitotic cells such as mature hepatocytes or cardiac myocytes, it provides the primary source of thymidine triphosphate that is required for mitochondrial DNA replication and nuclear DNA repair (Pérez-Pérez et al., 2005; Samuels, 2006). AZT inhibits thymidine kinase 2 at lower concentrations (7 to 14 µM) than AZTTP inhibits DNA polymerase γ (Lynx and McKee, 2006) and pharmacologic levels of AZT would be expected to result in accumulative mitochondrial damage and increased observed mutation frequencies through this mechanism.

Heart toxicities associated with AZT treatment have been reported in rats, mice, and monkeys. For example, rats given AZT in drinking water at approximately 29 to 102 mg/kg per day for up to 49 days developed cardiac mitochondrial swelling with fractured and disrupted cristae (Lewis et al., 1991). These ultrastructural defects did not reverse after a 14-day recovery period. Ultrastructural examination of cardiomyocytes of Sprague-Dawley rats given AZT in drinking water at approximately 90 mg/kg per day showed disruption of cristae and increased size of mitochondria after 30 or 60 days of treatment; no alterations were seen in rats that received 120 days of treatment (Corcuera Pindado et al., 1994). Sprague-Dawley rats given intraperitoneal injections of AZT at approximately 17 to 51 mg/kg for 3 months developed enlarged cardiomyocytic mitochondria with disorganized or absent cristae and increased serum concentrations of creatine kinase, lactate, and glucose (Lamperth et al., 1991).

Transgenic mice (that express replication-incompetent HIV) or FVB mice given AZT in drinking water at doses that delivered approximately 180 to 200 mg/kg for 35 days developed cardiac toxicity characterized by mitochondrial destruction (Lewis et al., 2000). Treatment-related histopathologic changes were described as numerous cardiomyocytes with granular cytoplasm in normal and transgenic mice. The lesions were generally more severe in transgenic mice. Neither interstitial inflammation nor fibrosis were found. The National Toxicology Program (NTP) did not report cardiac toxicity in B6C3F1 mice given AZT by oral gavage in corn oil at doses of 0, 50, 100, 200, 800, or 2,000 mg/kg for 14 days, or at doses of 0, 30, 60, or 120 mg/kg for 2 years (NTP, 1999) However, in an NTP study where Swiss (CD-1^®^) mouse pups were exposed in utero via lactation and by direct gavage on postnatal days (PNDs) 4 through 28 with twice-daily doses of 75/37.5 mg/kg AZT/3TC or the vehicle control mixture of 0.1% polysorbate 80 and 0.2% methylcellulose, the hearts of PND 28 pups treated with AZT/3TC showed significant increases in the mean area and decreases in the mean number of cardiomyocytic mitochondria compared to vehicle controls (Bishop et al., 2004a; NTP, 2006). AZT has also been shown to cause alteration in fat metabolism in rats. Male Wistar rats exposed to AZT (0.6 mg/mL in drinking water) for 4 weeks exhibited increased serum triglyceride levels and decreased cyto-chrome c oxidase and fatty acid synthase activities in their inguinal fat (Deveaud et al., 2007).

Studies in monkeys at the National Cancer Institute showed that daily doses of AZT during the second half of gestation at approximately 86% of the recommended human daily dose caused mitochondrial abnormalities (Gerschenson et al., 2000) that were similar to those observed in human neonates exposed to antiretroviral drugs (Divi et al., 2007a). In skeletal muscle, these abnormalities were characterized as abnormally shaped mitochondria with disrupted cristae. In heart muscle, small mitochondria in myocytes with myofibrillar loss and abnormal alignment of sarcomeres were observed.

#### 3TC

Transgenic mice expressing the mitochondrial deoxynucleotide carrier do not show indication of cardiac damage when treated with 3TC under conditions where AZT causes decreases in left ventricular mass and mitochondrial ultrastructure defects (Lewis et al., 2006).

#### NVP

NVP causes an idiosyncratic skin rash in rats (Shenton et al., 2003) through a process mediated by CD4^+^ T cells (McIntyre, 2006; Popovic et al., 2006). Female Brown Norway rats are the most sensitive to this response followed by female Sprague-Dawley rats (Shenton et al., 2003). Higher concentrations of the drug induce the idiosyncratic response in male Brown Norway rats and female Lewis rats (Shenton et al., 2004). Male Sprague-Dawley rats and female Stevens-Johnson syndrome mice appear to be resistant to the induction of the rash (Shenton et al., 2003). Both NVP and the NVP metabolite 12-hydroxy-NVP induce the rash (Popovic et al., 2006; Chen et al., 2008), and it has been suggested that 12-hydroxy-NVP is the metabolite responsible for the rash as a result of subsequent metabolism to a quinone methide (Chen et al., 2008). Rats treated orally with NVP do not have elevated serum levels of alanine transferase, aspartate transferase, or alkaline phosphatase, but histological examination of the livers indicates hepatocellular hypertrophy, nuclear degranulation, disintegration, and vacuolation (Walubo et al., 2006).

Oral or intraperitoneal treatment of mice with NVP causes a systemic sensitization to a subsensitizing dose of trinitrophenyl-ovalbumin (Nierkens et al., 2005). Mice dosed orally with NVP show decreased creatine kinase activity in the cerebellum, hippocampus, striatum, and cortex of the brain (Streck et al., 2008).

### Humans

#### AZT

Exposure to AZT has resulted in myelosuppression and anemia in some human patients like that in experimental animals. In humans, this toxicity limits the useful therapeutic dose range of AZT (Fischl, 1989; Pluda et al., 1991; Balzarini, 1994). The primary target of AZT toxicity is the hematopoietic system of the bone marrow; in vitro coculture studies have demonstrated that AZT is cytotoxic to human and mouse hematopoietic progenitor cells (Sommadossi and Carlisle, 1987; Dainiak et al., 1988; Gallicchio et al., 1989). In cultures of human bone marrow cells, the extent of incorporation of AZTTP into cellular DNA and the growth inhibition of human clonal peripheral blood mononu-clear cells have been correlated (Sommadossi and Carlisle, 1987; Sommadossi et al., 1989). In human erythroid K-562 leukemia cells induced to differentiate by butyric acid treatment, AZT selectively reduced the steady-state level of globin mRNA (Weidner and Sommadossi, 1990). Neither the kinetics of induction nor the steady-state mRNA levels of other components of the heme biosynthetic pathway were altered, including erythroid-specific isozymes of aminolevulinate synthase and porphobilinogen deaminase (Fowler et al., 1995). These results suggest a specific effect on transcription of the globin gene in erythroid cells. A few patients receiving long-term AZT therapy have been reported to have toxic mitochondrial myopathy (Dalakas et al., 1990). Clinical symptoms include myalgia, muscle weakness, and elevated levels of creatinine kinase in serum. These symptoms correlate with the presence in muscle biopsies of abnormal mitochondria containing paracrystalline inclusions. Human muscle myotubes grown in tissue culture exposed to AZT for 9 days exhibited increased numbers of mitochondria as well as enlarged mitochondria with abnormal cristae and electron-dense deposits in the matrix (Lamperth et al., 1991).

The United States Department of Health and Human Services updates information on current treatment regimens for HIV and observed toxicities on an ongoing basis (PHS, 2008). Common adverse effects noted from AZT use in humans include bone marrow suppression, anemia and/or neutropenia, and subjective complaints including gastrointestinal intolerance, headache, insomnia, and asthenia. In addition, lactic acidosis with hepatic steatosis has been reported as a rare side effect from the NRTI components used in HAART, including AZT.

NRTIs such as AZT have been reported to produce mitochondrial dysfunction in human patients (Dalakas et al., 1990; Arnaudo et al., 1991; Lamperth et al., 1991; Brinkman et al., 1999; DHHS, 2008a), possibly resulting from inhibition of human mitochondrial DNA polymerase γ or thymidine kinase 2. Mitochondrial DNA dysfunction may result in pancreatitis, peripheral neuropathy, myopathy, and cardiomyopathy (Lim and Copeland, 2001; Moussian, 2008). It is thought that combinations of NRTIs will act synergistically to induce mitochondrial dysfunction. Protease inhibitors may also aggravate this mechanism (DHHS, 2008a). Lipodystrophy (fat redistribution syndrome) may be seen in patients receiving NRTIs, and is related to mitochondrial toxicities (Brinkman et al., 1999; Kakuda et al., 1999; Mallal et al., 2000; DHHS, 2008a). Metabolic complications of HAART therapies include vascular necrosis, decreased bone density, and skin rashes (DHHS, 2008a). Another study suggests that mitochondrial damage in children of mothers taking AZT may persist for up to 2 years after birth (Artandi et al., 2000). However, HIV infection by itself may lead to cardiac toxicity (Raidel et al., 2002).

#### 3TC

The toxicity of 3TC in humans has been reviewed (Perry and Faulds, 1997; PDR, 2010a). When used as monotherapy in adults and children for the treatment of HIV-1 or chronic hepatitis B virus infection, 3TC treatment can, in some instances, result in neutropenia, thrombocytopenia, peripheral neuropathy, headaches, gastrointestinal effects, and lactic acidosis.

#### NVP

The toxicity of NVP in humans has been reviewed (Pollard et al., 1998; Mirochnick et al., 2000; Murphy, 2003; Wen et al., 2009). The most severe toxicity associated with NVP is hepatotoxity, which in some instances is fatal. The most common side effect is a rash consisting of maculopapular erythematous cutaneous eruptions. This effect occurs in children and adults (including pregnant women) and at times can be life threatening, leading to discontinuation of the drug. Whether or not the rash in humans is due to 12-hydroxy-NVP is currently uncertain (Hall and MacGregor, 2007). Other reported side effects are gastrointestinal disturbances and lipodystrophy.

## Reproductive and Developmental Toxicity

### Experimental Animals

#### AZT

AZT has been shown to cross the placenta of mice (Child et al., 1991) and monkeys (Ewings et al., 2000). In a series of studies in rats, mice, and rabbits, AZT has been shown to cause adverse reproductive effects but no teratogenic effects. AZT was evaluated for adverse effects on reproductive and fetal development in CD (Sprague-Dawley) rats and New Zealand White rabbits (Greene et al., 1996). Male and female CD rats were given twice-daily oral AZT doses of 0, 25, 75, or 225 mg/kg, approximately 6 hours apart. Males were dosed for 85 days prior to mating, and continued on dosing throughout two mating cycles for a total of 175 dosing days. Treated males were mated to females (F_0_) dosed for 26 days prior to mating and throughout gestation and lactation. Early resorptions and decreased litter size were noted following parental dosing with 75 or 225 mg/kg. In a second mating, treated males were mated to untreated females and the pups were monitored for growth, survival, and developmental characteristics. All reproductive parameters were normal. The authors concluded that the embryotoxicity of AZT noted with the first mating (treated males with treated females) was not mediated by a genotoxic effect in the males. The liveborn offspring showed no developmental abnormalities or teratogenic effects. Also in these studies, pregnant New Zealand White rabbits given an oral dose of 250 mg AZT/kg body weight per day from gestational days (GDs) 6 to 18 had reduced weight gain, anemia, and increased late fetal deaths. The liveborn offspring showed no developmental abnormalities or teratogenic effects.

When pregnant CD-1^®^ mice were given daily intragastric AZT doses of 25 mg/kg from GDs 12 to 18, no developmental toxicity was seen in the F_1_ generation (Diwan et al., 2000). When these treated offspring were mated to untreated offspring, the liveborn F_2_ pups showed no adverse effects on reproductive parameters. Other studies have shown that AZT can cause cytotoxic effects in preimplantation mouse embryos by inhibition of blastocyst and post-blastocyst development at doses similar to human therapeutic doses (Toltzis et al., 1991; DHHS, 2008b).

#### 3TC

Transplacental treatment of rabbits with 3TC results in some evidence of embryolethality (PDR, 2010a). The effect is not observed in rats treated similarly; likewise, there is no indication of teratogenicity in either species (PDR, 2010a).

Perinatal exposure to 3TC is associated with mitochondrial toxicity in mice as indicated by a decrease in mitochondrial DNA (Chan et al., 2007). E. patas monkeys transplacentally exposed to 3TC show evidence of morphological damage to umbilical cord artery endothelial cell mitochondria but no evidence of skeletal muscle mitochondrial morphological damage at birth (Divi et al., 2007b).

Perinatal administration of 3TC and AZT to E. patas monkeys, in a model that mimics a dosing regimen used with pregnant women and their infants, induces cardiac and skeletal muscle mitochondrial damage to an extent that is equal to or only slightly greater than that induced by AZT alone (Divi et al., 2005, 2007b). Infant E. patas monkeys exposed transplacentally to 3TC and AZT have substantial depletion of mitochondrial oxidative phosphorylation in heart and skeletal muscle (Gerschenson et al., 2004). CD-1^®^ mice treated perinatally with mixtures of AZT and 3TC show significant decreases in the mean number and area of cardiomyocytic mitochondria (Bishop et al., 2004a); however, it is unclear if this is due to AZT, 3TC, or the combination of the two.

#### NVP

Transplacental treatment of rats with NVP causes significant decreases in fetal body weight (PDR, 2010b). There is no indication of teratogenicity with NVP in either rats or rabbits (PDR, 2010b).

### Humans

#### AZT

There have been no reported increases in congenital abnormalities in infants born to women with antepartum AZT exposure (Connor et al., 1994; Sperling et al., 1998). The NIH panel cautioned that definitive conclusions regarding teratogenic risk cannot be thoroughly evaluated because of limited numbers of children evaluated (Corcuera Pindado et al., 1994; DHHS, 2008a; PHS, 2008). When AZT crosses the human placenta, it is incorporated into the DNA of cord blood leukocytes (Olivero et al., 1999).

#### 3TC

Infants exposed in utero, during the third trimester, to 3TC or a combination of 3TC and AZT have exhibited mitochondrial dysfunction in some instances (Brogly et al., 2007). Perinatal treatments with 3TC, in combination with AZT, causes seizures, lactic acidosis, anemia, altered cerebral pathology (based upon magnetic resonance imaging), impaired skeletal, heart, and/or liver oxidative phosphorylation, skeletal muscle mitochondrial abnormalities, and cardiomyopathy (Blanche et al., 1999; Barret et al., 2003; Tardieu et al., 2005).

Transplacental exposure to 3TC and AZT results in morphological damage to mitochondria of umbilical cord artery endothelium and a decrease in mitochondrial DNA copy number in cord blood mononuclear cells and in umbilical cord tissue (Divi et al., 2004, 2007a).

#### NVP

There are no adequate studies to assess the reproductive or developmental toxicity of NVP in humans (PDR, 2010b).

## Carcinogenicity

### Experimental Animals

#### AZT

Preclinical studies in rodents were conducted by GlaxoSmithKline to determine the potential for toxicity and/or cancer from exposure to AZT. AZT was administered to CD rats by oral gavage once a day at 0, 80, 220, or 600 mg/kg body weight for up to 2 years (Dainiak et al., 1988). Because of anemia, the high dose was reduced to 450 mg/kg on day 91 and further reduced to 300 mg/kg on day 278. Squamous cell carcinoma of the vagina occurred in two females receiving 300 mg/kg; no vaginal tumors/hyperplasia occurred in any other group of female rats. These investigators also administered AZT to CD-1^®^ mice by oral gavage at 0, 30, 60, or 120 mg/kg per day. Because of anemia, the doses were reduced to 0, 20, 30, or 40 mg/kg per day on day 90, where they remained for the rest of the 22-month study. The only neoplasms associated with administration of AZT in the mice were squamous cell carcinoma of the vagina in five females receiving 40 mg/kg, squamous cell papilloma of the vagina in one female receiving 30 mg/kg and in one female receiving 40 mg/kg, and one squamous polyp of the vagina in one female receiving 40 mg/kg. Although the incidences of hyperplasia of the vaginal epithelium were not increased above that in the controls, the severities of this lesion increased with increasing doses of AZT.

In order to clarify the role of AZT in producing vaginal tumors, AZT was administered intravaginally to CD-1^®^ mice for 22 months (Ayers et al., 1996a). Higher incidences of vaginal neoplasms occurred than were seen in the AZT oral gavage study in CD-1^®^ mice reported by Dainiak et al. (1988). There was a retrograde flow of urine from the discharge point at the base of the vulva into the region of the vagina where the vaginal tumors occurred. In mice, 90% of AZT is eliminated in the urine as the parent compound following oral administration. Because there is a high rate of cell turnover in the vaginal epithelium as a consequence of the short estrous cycle in mice (4 to 5 days), the investigators concluded that prolonged exposure of the vaginal epi thelium to the relatively high concentrations of AZT in the urine could explain the observed vaginal neoplasms. In humans, the concentration of free AZT in the urine is low, and the authors concluded that the vaginal tumors seen in mice would not necessarily be predictive of vaginal tumors in humans (Ayers et al., 1996a).

The NTP has conducted 2-year studies of AZT and AZT/interferon in B6C3F1 mice (NTP, 1999). AZT was administered to male and female mice by oral gavage at doses of 0, 30, 60, or 120 mg/kg per day in two equal doses, at least 6 hours apart, 5 days per week for 105 weeks. In the AZT/interferon studies, male and female mice received AZT by oral gavage at daily doses of 0, 30, 60, or 120 mg/kg, given in two equal doses, 5 days per week for 105 weeks, and the groups receiving AZT also received subcutaneous injections of 500 or 5,000 U α-interferon A/D three times per week for 105 weeks. Additional groups of male and female mice received subcutaneous injections of the vehicle, 500 U α-interferon A/D, 5,000 U α-interferon A/D, or 5,000 U α-interferon A (all without AZT), three times per week for 105 weeks. There was equivocal evidence of carcinogenic activity of AZT in male mice based on marginally increased incidences of renal tubule and Harderian gland neoplasms in groups receiving AZT alone. There was clear evidence of carcinogenic activity of AZT in female mice based on increased incidences of squamous cell neoplasms of the vagina in groups that received AZT alone or in combination with α-interferon A/D. Hematotoxicity occurred in all groups that received AZT. Treatment with AZT alone and AZT in combination with α-interferon A/D resulted in increased incidences of epithelial hyperplasia of the vagina in all dosed groups of females.

In a follow-up transplacental exposure study (NTP, 2006), female Swiss (CD-1^®^) mice were dosed with 0, 50, 100, 200, or 300 mg AZT/kg per day via oral gavage of two equal doses from 10 to 14 days prior to conception until GD 19 and up to four pups (F_1_ generation) from each litter were followed for 2 years and evaluated for carcinogenicity. Under the conditions of this study, there was clear evidence of carcinogenic activity in F_1_ male mice exposed transplacentally to AZT based on increased incidences of alveolar/bronchiolar neoplasms, and no evidence of carcinogenic activity in F_1_ female mice.

Studies by the National Cancer Institute suggest that AZT, when given at relatively high doses, is a moderately effective perinatal carcinogen in mice, targeting several tissue types (Olivero et al., 1997; Diwan et al., 1999). In these studies, AZT was given to CD-1^®^ mice at doses of 12.5 or 25 mg (equivalent to up to 1,000 mg AZT/kg nonpregnant body weight or 450 mg AZT/kg of terminal body weight) orally from GD 12 through GD 18. AZT was incorporated into nuclear and mitochondrial DNA of the fetuses. Dose-dependent increases in tumor multiplicities in the lung, liver, and female reproductive organs occurred. In a transplacental carcinogenicity study using lower AZT doses, CD-1^®^ mice were given 20 or 40 mg AZT/kg body weight per day in the drinking water from gestation day 10 through lactation day 21 (Ayers et al., 1997). In this study, some of the pups from the litters were then continued on AZT treatment by daily gavage at 20 or 40 mg/kg per day for 24 months; AZT tumor findings were limited to the vaginal epithelium.

Walker et al. (2007) exposed B6C3F1 mice and Fischer 344 rats to either once daily gavage doses of 0, 80, or 240 mg AZT/kg body weight or 480 mg/kg, given in two gavage doses per day, during the last week of gestation. Tumor incidences were evaluated at 24 months of age. In male mice, there were statistically significant increases in the incidences of hemangioma or hemangiosarcoma (combined) in all three dosed groups and of hepatocellular carcinoma in the highest dose group. In female mice, there were statistically significant increases in the incidences of neoplasms of the uterus in the highest dose group. In female rats, the incidences of mononuclear cell leukemia were increased in all three dosed groups.

#### 3TC

The carcinogenicity of 3TC has been assessed following long-term administration to mice and rats (PDR, 2010a). There was no evidence of carcinogenicity in mice given 10 times the recommended therapeutic dose of 3TC for treating HIV-1 infection or in rats given 58 times the recommended therapeutic dose of 3TC.

#### NVP

The carcinogenicity of NVP has been assessed following long-term administration to mice and rats (PDR, 2010b). In mice administered 0, 50, 375, or 750 mg NVP/kg body weight per day, there were increased incidences of hepatocellular adenoma or carcinoma (combined) at all doses of NVP in male mice and at the two highest doses in female mice. In rats administered 0, 3.5, 17.5, or 35 mg/kg body weight per day, there were increased incidences of hepatocellular adenoma at all doses of NVP in male rats and at the highest dose in female rats.

### Humans

#### AZT

There have been no studies reported in the literature on any association between AZT and/or HAART and cancer. However, a recent epidemiology study reported that patients with HIV or AIDS do have increased risk of developing lung cancer (Kirk et al., 2007). Since the increased risk was not significantly correlated with either HAART or low CD4^+^ cell count it is not yet known whether AZT exposure contributes to this increased cancer risk. Cancer often takes many years to develop, and follow-up of patients is continuing. An NIH panel has recommended long-term follow-up in children receiving in utero exposure to AZT and other antiretroviral drugs (Highleyman, 1997).

#### 3TC

There have been no studies reported in the literature on any association between 3TC and the development of cancer in humans.

#### NVP

There have been no studies reported in the literature on any association between NVP and the development of cancer in humans.

## Genetic Toxicity

### AZT

AZT is a DNA-reactive chemical that is positive in the Salmonella typhimurium mutation assay (NTP, 1999) and has been shown to increase mutation frequencies and induce chromosomal damage in mammalian cells in vivo and in vitro. Its genotoxic effects have been extensively reviewed in previous NTP technical reports (NTP, 1999, 2006). A brief summary of the extensive genetic toxicity literature follows.

AZT was reported to be weakly positive in the mouse lymphoma cell mutagenicity test (Ayers, 1988; Olin and Kastrup, 1995) and to induce transformation in cultured mammalian cells (Olin and Kastrup, 1995). Results of in vitro cytogenetic assays with mammalian cells showed that AZT induced sister chromatid exchanges, chromosomal aberrations, and micronuclei in human lymphocytes, as well as chromosomal aberrations and sister chromatid exchanges in cultured Chinese hamster ovary cells (Gonzalez Cid and Larripa, 1994). In cyto-genetic studies in Chinese hamster ovary cells conducted by the NTP, sister chromatid exchanges were remarkably elevated by AZT, particularly in the absence of S9 activation, but no induction of chromosomal aberrations was observed (NTP, 1999).

In vivo, AZT has been shown in several studies to be an effective inducer of micronucleated reticulocytes (markers of chromosomal damage) in rats and mice exposed through various combinations of routes and exposure durations (Phillips et al., 1991; Dertinger et al., 1996a; Von Tungeln et al., 2002; Bishop et al., 2004b). For example, significantly increased micro-nucleus frequencies (6 to 27 times the frequency in concurrent controls), were noted in peripheral blood and bone marrow erythrocytes of mice after multiple treatments with 100 to 2,000 mg AZT/kg per day for periods of 72 hours, 96 hours, or 90 days. However, other studies using lower doses have reported no increase in micronucleus frequency (Motimaya et al., 1994). A study (Dobrovolsky et al., 2007) using C3B6F1^+/−^ Trp53^tm1Brd^ p53 haploinsufficient mice reported that transplacental, followed by neonatal, exposure to AZT increased the reticulocyte micronucleus frequencies 4.8-, 7.1- and 11.3-fold when measured on PND 1 with maternal doses of 48, 80 and 160 mg/kg per day, respectively, and 10.3-, 10.6-, and 26.5-fold when measured on PND 10 with maternal/neonatal doses of 40/20, 80/40, and 160/80 mg/kg per day, respectively.

Incorporation of AZT into the DNA of leukocytes and multiple organs of cynomolgus monkeys was demonstrated following a 30-day treatment period (40 mg/day, by nasogastric intubation) (Olivero et al., 2001). Organ specific differences in the amount of AZT incorporation were noted, and the average levels of incorporation were similar to what had been reported for human leukocytes (Olivero et al., 2000). Pregnant CD-1^®^ mice and E. patas monkeys were treated with AZT (mice, 12.5 or 25 mg/day; monkeys, 10 mg/day) during critical periods of gestation, and AZT incorporation into both nuclear and mitochondrial DNA, along with telomere length of chromosomes, was measured in the newborns (Comstock et al., 1993). The transplacentally exposed animals showed significant AZT incorporation into nuclear as well as mitochondrial DNA of several organs, and decreased telomere lengths were seen in chromosomes from liver and brain cells of mice, but not monkeys. Similarly, a human-equivalent dose of AZT (8 mg/kg) administered continuously over 4 hours to pregnant rhesus macaques just prior to hysterotomy at the end of gestation resulted in AZT incorporation into DNA extracted from cells of several fetal organs (Poirier et al., 1999).

The relevance of the positive results from animal mutation studies to humans is not yet clear, but numerous investigations have yielded data supporting a potential for genetic damage in humans exposed to AZT and other nucleoside analogues (Olivero, 2007, 2008). Several studies have demonstrated increased mutation frequencies in cultured human lymphoblastoid cells following AZT exposure. For example, there are a number of studies showing incorporation of AZT into DNA of human lymphoblastoid cells, followed by loss of heterozygosity at loci for the thymidine kinase 1, hypoxanthine phosphoribosyltransferase, and adenine phosphoribosyltransferase genes, resulting in significant increases in mutant frequencies (Sussman et al., 1999; Meng et al., 2000a,b,c). Analysis of the AZT-induced mutational spectra in cultured human lymphoblastoid cells showed an increase in complete gene deletions, a result consistent with DNA chain termination, and loss of heterozygosity (Meng et al., 2002). In vivo, anti-AZT radioimmunoassays were used to demonstrate that AZT is incorporated into lymphocyte DNA of HIV-infected adults taking AZT (Olivero et al., 2000).

Currently there is some evidence that AZT exposure in conjunction with HAART can result in chromosomal damage in humans. An early paper by Shafik et al. (1991) reported significantly increased chromosomal aberration frequencies in lymphocytes of AIDS patients treated with AZT alone, compared to a healthy control group. In a more recent study, children born to HIV-infected mothers who received treatment with AZT and other NRTIs were evaluated periodically for up to 9 years after birth (Senda et al., 2007). Heterochromatin analysis of blood leukocytes showed an increased frequency (P<0.001) of chromatin dispersal in samples from children exposed to NRTIs (predominantly AZT) as compared to frequencies from children of HIV-infected mothers who were not exposed to NRTIs. The heterochromatin defects persisted long after the end of the exposure period and were present in leukocytes of both myeloid and lymphoid lineages, suggesting that hematopoietic stem cells were affected.

### 3TC

TK6 human lymphoblastoid cells were incubated for 3 days with 0, 33, 100, or 300 μM 3TC alone (Carter et al., 2007; Torres et al., 2007) or in the presence of an equimolar quantity of AZT (Torres et al., 2007). Compared to control cultures, incubation with 300 μM 3TC caused significant increases in the Hprt and TK mutant frequencies, while all three levels of the combined 3TC and AZT exposures caused significant increases in the Hprt and TK mutant frequencies.

Neonatal B6C3F1/TK^+/−^ mice were treated intraperitoneally on PNDs 1 to 8 with 200 mg 3TC/kg body weight per day or a mixture of 200 mg 3TC and 200 mg AZT/kg per day (Von Tungeln et al., 2002). When assessed on PNDs 9 and 10, 3TC did not increase the frequency of polychromatic erythrocytes containing micronuclei. The percentage of polychromatic erythrocytes containing micronuclei was increased by the mixture of 3TC and AZT, but the response did not differ from that observed with AZT alone. Treatment with 3TC did not affect the mutant frequency at either the TK gene or Hprt gene of spleen T-lymphocytes. The combined treatment of 3TC and AZT did increase the TK but not the Hprt mutant frequency; however, the response did not differ from treatment with AZT alone. The increase in the TK mutant frequency was attributed to loss of heterozygosity.

Female C57Bl/6N and female C57Bl/6N/TK^+/−^ mice were bred to male C3H/HeNMTV mice and then were treated with 3TC by gavage on GDs 12 to 17 with 0 or 120 mg/kg per day or a mixture of either 40 mg 3TC and 80 mg AZT/kg per day, 80 mg 3TC and 160 mg AZT/kg, or 120 mg 3TC and 240 mg AZT/kg (Von Tungeln et al., 2007). When assessed 1 day after birth, there was no increase in micronucleated reticulocytes or micronucleated normochromatic erythrocytes in mice that had been exposed to 3TC alone, whereas there was a dose-dependent increase in mice that had been exposed to the mixtures of 3TC and AZT. Treatment with 3TC alone resulted in an increase in the TK mutant frequency when assessed 5 weeks after treatment, whereas the mixtures of 3TC and AZT resulted in increased TK mutant frequencies at 3 weeks after treatment.

Pregnant CD-1^®^ mice were given 100 mg 3TC/kg body weight per day or a mixture of 100 mg 3TC and 200 mg AZT/kg per day for the last 7 days of gestation (Torres et al., 2007). When assessed on PND 13, the mixture of 3TC and AZT, but not 3TC alone, increased the mutant frequency of the Hprt gene in spleen T-lymphocytes. An increase in mutant frequency was not detected at PNDs 15 or 21 with either treatment.

Female C3H/HeN (p53^+/+^) mice were bred to p53^+/+^ or p53^+/−^ male mice and the pregnant female mice were treated by gavage on GDs 12 to 18 with a mixture of 100 mg 3TC and 160 mg AZT/kg body weight per day (Dobrovolsky et al., 2007). After delivery, the p53^+/+^ and p53^+/^ pups were treated by gavage on PNDs 1 to 10 with 50 mg 3TC and 80 mg AZT/kg body weight per day and on PNDs 11 to 28 with 100 mg 3TC and 160 mg AZT/kg per day. When assessed on PNDs 1, 10, and 28, there were increases in micronucleated reticulocytes and micronucleated normochromatic erythrocytes that were independent of genotype. Administration of the mixtures of 3TC and AZT also produced increases in the mutant frequency at the Hprt gene of spleen lymphocytes in p53^+/−^ mice but not in p53^+/+^ mice.

Umbilical cord blood was obtained from human infants whose HIV-1-positive mothers had received antiretroviral therapy during pregnancy (Witt et al., 2007). Infants whose mothers had received regimens containing 3TC and AZT plus at least one additional antiretroviral drug had significant increases in micronucleated reticulocytes compared to infants whose mothers had either not been treated or had received regimens that did not contain 3TC and AZT. Likewise, venous blood from mothers given regimens containing 3TC and AZT had significant increases in micronucleated reticulocytes compared to mothers administered regimens that did not contain 3TC and AZT or compared to typical values measured in “control” adults.

DNA was isolated from mononuclear cells of umbilical cord blood obtained from 21 infants whose HIV-1-positive mothers had been treated with 3TC and AZT during pregnancy (Meng et al., 2007). When assessed by radioimmunoassay, AZT incorporation was detected (mean = 51.6 AZT molecules per 10^6^ nucleotides; range = 3 to 151.5 AZT molecules per 10^6^ nucleotides). This level of AZT incorporation was significantly greater than that of infants exposed to AZT alone. The levels of 3TC incorporation were not measured. AZT incorporation was also detected in mononuclear cell DNA from nine maternal blood samples (mean = 52.8 AZT molecules per 10^6^ nucleotides; range = 0 to 241.7 AZT molecules per 10^6^ nucleotides). In further work, the presence of mutations in glycophorin A was assessed in maternal and umbilical cord blood (Escobar et al., 2007; Meng et al., 2007). Compared to infants whose mothers had not been treated, the frequency of glycophorin A variants was elevated in the infants whose mothers had received mixtures of 3TC and AZT.

Umbilical cord tissue DNA of infants whose mothers had been treated during pregnancy with mixtures of AZT and 3TC was examined for sequence variations in mitochondrial DNA (Torres et al., 2009). Density gradient gel electrophoresis indicated the presence of a shift in the mutation spectrum.

### NVP

NVP was not mutagenic or clastogenic in a variety of assays, including microbial and mammalian gene mutation tests and micronucleus tests (PDR, 2010b). Synthetic esters of the NVP metabolite 12-hydroxy-NVP have been shown to react with DNA to give a number of DNA adducts (Andric et al., 2006). Whether or not these DNA adducts are formed in vivo is currently unknown.

## Background on Genetically Modified Mice Used in the AZT, 3TC, and NVP Study

The p53 tumor suppressor gene suppresses cancer in both humans and mice. The p53 protein is critical to cell cycle control, DNA repair and apoptosis, etc., and is often mutated or lost in human and rodent cancers. The haploinsufficient Trp53 tumor suppressor gene mouse model heterozygous for wildtype and null (+/−) Trp53 alleles (Donehower et al., 1992, 1995) was used in this study. In this model, a Trp53 null mutation was introduced by homologous recombination in AB1 murine embryonic stem cells that were derived from a black agouti 129Sv inbred mouse. By targeted insertion of a polII neo cassette, an engineered null mutation was induced as a result of the deletion of a 450-base pair gene fragment from the Trp53 gene that included 106 nucleotides of exon 5 and approximately 350 nucleotides of intron 4 that eliminated both mRNA and p53 protein expression from this allele. This Trp53 protein haploinsufficient mouse model has been extensively tested as a short-term cancer bioassay mouse model (Tennant et al., 1995; Dunnick et al., 1997; French et al., 2001a,b; Pritchard et al., 2003; French, 2004) based upon the observation that mice with only a single wildtype Trp53 allele show a significant decrease in the time required for genotoxic carcinogen-induced tumors to develop. These tumors are often associated with either a mutation and/or a loss of heterozygosity of the remaining wildtype Trp53 allele. Few to no sporadic tumors occur in concurrent or historical study control groups in this GMM model, which allows tests to be conducted with fewer animals and direct analysis of the target wildtype Trp53 allele to test for genotoxicity in vivo as a mode of action.

For the current study, an outcross between C3H/HeNTac (C3) female mice homozygous for the wildtype (+) Trp53 allele and the C57BL/6.129Sv-Trp53^tm1Brd^ N12 congenic (abbreviated B6.129-Trp53^tm1Brd^) N12 backcross generation males homozygous for the Trp53 null (−) allele produced C3B6.129F1/Tac-Trp53^tm1Brd^ N12 progeny heterozygous for a Trp53 wildtype (+) and null allele (−) inbred mouse progeny [hereafter referred to in the abbreviated form as the heterozygous F1 p53^+/−^ mouse, Taconic Farms, Inc. (Germantown, NY)]. The heterozygous F1 p53^+/−^ mouse was selected for the 45-week study of AZT because the B6.129-Trp53^tm1Brd^ (N5) haploinsufficient male and female mice (backcrossed to C57BL/6, subline unspecified, for two generations and then to C57BL/6NTac females for an additional three generations) were not sufficiently inbred. The N5 generation of this line retained both C57BL/6 and 129Sv strain allele heterozygosity at both the Trp53 locus and the flanking region on chromosome 11 and at unknown loci throughout the genome of this line. This residual heterozygosity in the B6.129-Trp53^tm1Brd^ N5 backcross generation mice was one covariate that may have been responsible for large variations in the p-cresidine induced urinary bladder tumors (0% to 80%, 10 of 11 studies were positive) in males, which was used as a positive control genotoxic carcinogen in the ILSI/HESI Alternatives to Carcinogenicity Testing initiative (Storer et al., 2001). Therefore, additional inbreeding to the N12 generation was anticipated to decrease the variance in tumor incidence and stabilize the penetrance of tumor phenotypes in NTP studies.

The majority of B6.129-Trp53^tm1Brd^ homozygous null females die in utero and only a few are born alive and most die early. Thus, the B6.129-Trp53^tm1Brd^ N12 line is maintained by intercross of the B6.129-Trp53^tm1Brd^ female heterozygote with the B6.129-Trp53^tm1Brd^ homo-zygous null male to produce a 1:2 population of homo-zygous null males and heterozygous null males and females. Therefore it is necessary to select the B6.129-Trp53^tm1Brd^ homozygous null male as the carrier of the null allele. However, the selection of the C3H/HeNTac female as the wildtype Trp53 allele carrier provides 1) increased fecundity and maternal instincts, 2) increased hybrid vigor of an F1 outcross that increases the number of progeny, 3) the advantage of expanding the pattern of tumor susceptibility associated with this genetic background, and 4) a genetic background similar to the B6C3F1 mouse used in NTP studies (NTP, 2013a). Together, these factors provided a rational basis for selection of this GMM test model. In addition, the NTP studies reported on AZT alone and on senna, also used the C3B6.129F1/Tac-Trp53^tm1Brd^ N12 haploinsufficient GMM model (NTP, 2012, 2013b), and the background rates for spontaneous tumors in the control groups of C3B6.129F1-Trp53^tm1Brd^ haploinsufficient mice all three studies (AZT, senna, and the current study) were not statistically different from the background rates for spontaneous tumors observed in control B6.129-Trp53^tm1Brd^ (N5) haploinsufficient mice used in previous NTP GMM studies (NTP, 2005a,b, 2007a,b,c,d,e, 2008).

## Study Rationale

The development of HAART to combat the AIDS pandemic was a major public health triumph of the late 20th century. For countries where HAART drugs are widely available, they have transformed HIV infection from a death sentence into a manageable chronic disease. In the United States, the FDA has made a significant contribution to this triumph by rapidly evaluating and approving new antiretroviral drugs. An estimated 7,000 infants are born to HIV-infected women in the United States every year, and due to the implementation of HAART the vast majority of these infants escape infection (UNAIDS, 2008).

In the United States, AZT was the primary drug of choice for treating pregnant women who are HIV positive to prevent transmission of the virus to their children when the current study was initiated (PHS, 2008). It is used either alone or in combination with other antiretroviral drugs as part of HAART. Because AZT has been in use for less than 25 years, its long-term toxicological impact on children exposed in utero or in infancy is currently unknown. As outlined previously, AZT has been shown to be both genotoxic and a rodent carcinogen. An initial study described elsewhere (NTP, 2013b) was designed to determine possible long-term sequelae of AZT exposure when it is used to prevent mother-to-child transmission of HIV. The C3B6F1^+/−^ Trp53^tm1Brd^ p53 haploinsufficient mouse was selected for this study because previous NTP studies showed that p53 mutations were associated with AZT-induced carcinogenesis processes (NTP, 2006) and it was hypothesized that when a p53 gene change is involved in the multiple genetic steps to cancer, a mouse deficient in this gene will develop cancer in a shorter time period than in the traditional 2-year mouse cancer studies. The study determined that when AZT was administered through late gestation and then continuously until 45 weeks of age in this model, clear evidence of carcinogenic activity was observed in male mice based on increased incidences of hepatocellular adenoma, and some evidence of carcinogenic activity in female mice based on increased incidences of malignant lymphoma (NTP, 2013b). The current study was designed to test this model further. AZT was again tested, but also in combination with 3TC and NVP. The study included 3TC because it has been used extensively in combination with AZT (Combivir^®^) and because neonatal C3B6F1^+/−^Trp53^tm1Brd^ p53 haploinsufficient mice pretreated with an AZT/3TC combination had exhibited a greater frequency of micronucleated reticulocytes than those treated with an equivalent dose of AZT alone (Dobrovolsky et al., 2007). The study included NVP because it has been used extensively in combination with AZT, particularly in prevention of mother-to-child transmission of HIV during labor (PHS, 2008) and because NVP causes liver toxicity in humans and therefore might potentiate the hepatocarcinogenesis of AZT in C3B6F1^+/−^Trp53^tm1Brd^ p53 haploinsufficient mice. In addition the dosing regime was changed, in relation to other studies, to dosing only up to PND 28 so as to better mimic the gestational and early postnatal HAART given to children of HIV-infected mothers. Also, the daily dose was divided into two oral gavage exposures given approximately 6 hours apart to better mimic human exposure. The current study would, therefore, be more relevant to human exposures than the initial study (NTP, 2013b).

The current study used a standard chronic GMM study design of a control and three dosed groups; however, because a three-drug combination was being tested, additional dose groups in which each drug of the combination was administered alone were added. An additional dose group in which AZT and 3TC were coadministered without NVP was also added. The purpose for these additional dose groups was to provide information as to which of the three component drugs might be responsible for any effects observed in the combination study.