# APPENDIX J HISTORICAL CONTROL INCIDENCES

TABLE J1 Historical Incidences of Neoplasms in Control Male Heterozygous F1 p53^+/−^ Mice in the 30- and 45-Week NCTR Studies of AZT, the 45-Week NCTR Study of AZT/3TC/NVP, and the 40-Week NTP Study of Senna^a^

| AZT (45 Weeks)^b^ | AZT (45-Week Stop Study)^c^ | AZT/3TC/NVP (45 Weeks)^d^ | Senna (40 Weeks)^e^ | Overall
Bone
Osteosarcoma^f^ | 0/27 | 0/24 | 1/25 | 0/25 | 1/101
Humerus, osteosarcoma | 1/27 | 0/24 | 1/25 | 0/25 | 2/101
Femur, osteosarcoma | 1/27 | 0/24 | 0/25 | 0/25 | 1/101
Tibia, osteosarcoma | 0/27 | 0/24 | 1/25 | 0/25 | 1/101
Any location, osteosarcoma | 2/27 | 0/24 | 3/25 | 0/25 | 5/101
Harderian gland
Adenoma | 1/27 | 1/24 | 0/25 | 0/25 | 2/101
Liver
Hepatocellular adenoma | 3/26 | 3/24 | 1/25 | 1/25 | 8/100
Lung
Alveolar/bronchiolar adenoma | 0/27 | 2/24 | 0/25 | 1/25 | 3/101
Mesentery
Sarcoma | 0/27 | 0/24 | 1/25 | 0/25 | 1/101
Pancreas
Acinar cell, Carcinoma | 0/27 | 1/23 | 0/24 | 0/25 | 1/99
Small intestine,
Duodenum, leiomyosarcoma | 0/26 | 0/24 | 1/23 | 0/25 | 1/98
Jejunum, adenocarcinoma | 0/26 | 0/24 | 1/23 | 0/25 | 1/98
Tissue NOS,
Sarcoma | 1/26 | 0/24 | 0/25 | 0/25 | 1/100
Abdominal sarcoma | 0/27 | 0/24 | 1/25 | 0/25 | 1/101
All organs
Lymphoma, malignant | 1/27 | 0/24 | 1/25 | 1/25 | 3/101

a Data as of November 18, 2011. The AZT and AZT/3TC/NVP studies involved transplacental dosing and may not be comparable to the senna study.

b Control F_1_ mice received 0.2% methylcellulose/0.1% Tween^®^ 80 aqueous solution by once-daily gavage from postnatal day (PND) 1 through 28 then 5 days/week until the end of study. F_0_ dams received 0.2% methylcellulose/0.1% Tween^®^ 80 aqueous solution by once-daily gavage from gestational days (GDs) 12 through 18. Mice were fed NIH-31 pelleted diet.

c Control F_1_ mice received 0.2% methylcellulose/0.1% Tween^®^ 80 aqueous solution by once-daily gavage from PNDs 1 through 8. F_0_ dams received 0.2% methylcellulose/0.1% Tween^®^ 80 aqueous solution by once-daily gavage from GDs 12 through 18. Mice were fed NIH-31 pelleted diet.

d Control F_1_ mice received 0.2% methylcellulose/0.1% Tween^®^ 80 aqueous solution by twice-daily gavage from PNDs 1 through 28. F_0_ dams received 0.2% methylcellulose/0.1% Tween^®^ 80 aqueous solution by twice-daily gavage from GDs 12 through 18. Mice were fed NIH-31 pelleted diet.

e Control mice were not dosed (feed exposure study) and were 6 to 8 weeks of age when the study was initiated so that their age at the end of the study was 45 to 48 weeks. Mice were fed NTP-2000 meal diet.

f Number of neoplasm-bearing animals/number of animals examined microscopically

TABLE J2 Historical Incidences of Neoplasms in Control Female Heterozygous F1 p53^+/−^ Mice in the 30- and 45-Week NCTR Studies of AZT, the 45-Week NCTR Study of AZT/3TC/NVP, and the 40-Week NTP Study of Senna^a^

| AZT (45 Weeks)^b^ | AZT (45-Week Stop Study)^c^ | AZT/3TC/NVP (45 Weeks)^d^ | Senna (40 Weeks)^e^ | Overall
Adrenal medulla
Pheochromocytoma, benign^f^ | 0/25 | 0/26 | 0/23 | 1/25 | 1/99
Bone
Femur, osteosarcoma | 1/26 | 0/26 | 0/25 | 0/25 | 1/102
Rib, osteosarcoma | 0/26 | 0/26 | 0/25 | 1/25 | 1/102
Vertebra, osteosarcoma | 0/26 | 0/26 | 0/25 | 1/25 | 1/102
Any location, osteosarcoma | 1/26 | 0/26 | 0/25 | 2/25 | 3/102
Bone marrow
Sarcoma | 1/26 | 0/25 | 0/25 | 0/25 | 1/101
Brain
Cerebrum, sarcoma | 1/26 | 0/26 | 0/25 | 0/25 | 1/102
Large intestine
Cecum polyp | 0/25 | 0/25 | 0/25 | 0/25 | 0/100
Liver
Sarcoma | 1/26 | 0/25 | 0/25 | 0/25 | 1/101
Lung
Alveolar/bronchiolar adenoma | 0/26 | 0/26 | 1/25 | 0/25 | 1/102
Mediastium, sarcoma | 1/26 | 0/26 | 0/25 | 0/25 | 1/102
Lymph node
Mandibular, sarcoma | 1/26 | 0/25 | 0/25 | 0/25 | 1/101
Mesenteric, sarcoma | 1/26 | 0/25 | 0/25 | 0/23 | 1/99
Mammary gland
Adenoacanthoma | 0/25 | 0/26 | 0/25 | 0/25 | 0/101
Adenocarcinoma | 0/25 | 0/26 | 1/25 | 0/25 | 1/101
Adenoma | 0/25 | 1/26 | 0/25 | 0/25 | 1/101
Nose
Sarcoma | 1/26 | 0/26 | 0/25 | 0/25 | 1/102
Ovary
Cystadenoma | 0/26 | 0/26 | 0/25 | 1/25 | 1/102
Granuloma cell tumor, malignant | 0/26 | 0/26 | 0/25 | 1/25 | 1/102
Luteoma | 1/26 | 0/26 | 0/25 | 0/25 | 1/102
Teratoma malignant | 0/26 | 1/26 | 0/25 | 0/25 | 1/102
Yolk sac carcinoma | 0/26 | 1/26 | 0/25 | 0/25 | 1/102
Spleen
Sarcoma | 1/26 | 0/26 | 0/25 | 0/25 | 1/102
Uterus
Polyp stromal | 0/26 | 1/26 | 0/25 | 0/25 | 1/102
Endometrium, polyp stromal | 0/26 | 0/26 | 0/25 | 0/25 | 0/102
All organs
Lymphoma, malignant | 0/26 | 0/26 | 2/25 | 1/25 | 3/102
Mesothelioma, malignant | 1/26 | 0/26 | 0/25 | 0/25 | 1/102

a Data as of November 18, 2011. The AZT and AZT/3TC/NVP studies involved transplacental dosing and may not be comparable to the senna study.

b Control F_1_ mice received 0.2% methylcellulose/0.1% Tween^®^ 80 aqueous solution by once-daily gavage from postnatal day (PND) 1 through 28 then 5 days/week until the end of study. F_0_ dams received 0.2% methylcellulose/0.1% Tween^®^ 80 aqueous solution by once-daily gavage from gestational days (GDs) 12 through 18. Mice were fed NIH-31 pelleted diet.

c Control F_1_ mice received 0.2% methylcellulose/0.1% Tween^®^ 80 aqueous solution by once-daily gavage from PNDs 1 through 8. F_0_ dams received 0.2% methylcellulose/0.1% Tween^®^ 80 aqueous solution by once-daily gavage from GDs 12 through 18. Mice were fed NIH-31 pelleted diet.

d Control F_1_ mice received 0.2% methylcellulose/0.1% Tween^®^ 80 aqueous solution by twice-daily gavage from PNDs 1 through 28. F_0_ dams received 0.2% methylcellulose/0.1% Tween^®^ 80 aqueous solution by twice-daily gavage from GDs 12 through 18. Mice were fed NIH-31 pelleted diet.

e Control mice were not dosed (feed exposure study) and were 6 to 8 weeks of age when the study was initiated so that their age at the end of the study was 45 to 48 weeks. Mice were fed NTP-2000 meal diet.

f Number of neoplasm-bearing animals/number of animals examined microscopically