# APPENDIX I TOXICOKINETIC STUDIES

## Introduction

Toxicokinetic studies of AZT and 3TC were performed on B6C3F1/N mice as part of transplacental carcinogenicity studies of these Highly Active Antiretroviral Therapy (HAART) drugs (NTP, 2013); these studies are reported in detail with kinetic parameters in Williams et al. (2003). The current report describes evaluations of serum taken from heterozygous F1 p53^+/−^ mice that were used in range-finding studies associated with the studies reported in GMM 16. Serum samples were assayed for AZT and 3TC concentrations to determine how the doses used in the study compared to human therapeutic exposure.

## Materials and Methods

When pups were killed, blood samples were collected from pups treated with AZT alone or AZT in combination with 3TC. The pups were killed either on postnatal day (PND) 10 or on PND 28 following the pre- and postnatal treatments indicated in Tables I1 and I2. The blood samples were left on ice for 30 minutes and then centrifuged to prepare serum, which was stored at −80° C until analysis.

Serum was analyzed for AZT and 3TC concentrations by the methods of Williams et al. (2003), which utilize solid phase extraction of the samples followed by liquid chromatography-mass spectrometry (LC-MS). Details of these analyses are given below. The LC-MS system could also resolve and quantitate the AZT metabolites 3′-amino-3′-deoxythymidine (AMT) and 3′-azido-3′-deoxy-5′-O-β-D-glucopyranuronosylthymidine (GAZT).

Materials: AZT and 3TC were obtained from Cipla Ltd. (Mumbai, India); ^13^C_1_^15^N_1_d_3_-AZT and ^13^C_2_^15^N_3_-3TC internal standards were a gift to Dr. Dan Doerge (NCTR) from Burroughs-Wellcome Co. (Research Triangle Park, NC). AMT and GAZT standards were obtained from Sigma-Aldrich^®^ Corp. (St. Louis, MO). All solvents were HPLC grade, and Milli-Q^®^ water was used throughout.

Solid phase extraction: Solid phase extraction of the nucleoside analogues and their metabolites was carried out using the 96-well format under reduced pressure. Isolute ENV+^®^ cartridges (50 mg, 1 cm^3^, Jones Chromatography, Inc., Lakewood, CO) were used for the extraction. Activation of the cartridges was achieved with 2 × 1 mL washes of methanol, followed by 2 × 1 mL washes of 0.1% formic acid. Serum samples (10 µL) were spiked with the labeled internal standards [^13^C_1_^15^N_1_d_3_ -AZT (100 ng) and ^13^C_2_^15^N_3_ -3TC (either 100 ng for 3TC dosing studies or 10 ng for AZT dosing studies)] contained in 10 µL of water and diluted with 150 µL of 0.1% formic acid prior to extraction. The cartridges, containing sample, were then washed with 1 × 1 mL of water and 1 × 1 mL of water/methanol (90/10). Elution of the sample occurred with 3 × 400 µL washes of 10% ammonium acetate (100 mM, pH 4) in methanol. The eluate was reduced to dryness using a centrifugal vacuum concentrator and reconstituted into 200 µL of water.

Liquid chromatography: LC was performed using a Waters 2695 liquid handling system (Waters Assoc., Milford, MA). Chromatographic separation was achieved on a Polaris^®^ C_18_ analytical column (150 mm × 2.0 mm, 3 µm particle size; ANSYS Technologies, Lake Forest, CA), equipped with a C_18_ SecurityGuard^®^ column (4 mm × 2.0 mm; Phenomenex, Torrance, CA), at a flow rate of 200 µL/minute. The mobile phase consisted of 0.1% aqueous formic acid and acetonitrile. Initial conditions were set to 0% acetonitrile increasing to 31% over 4 minutes. This gradient was sufficient to separate the AMT peak from the unretained material at the beginning of the run. A fast gradient to 90% acetonitrile at 8.9 minutes was employed in order to elute 3TC, AZT, AMT, and GAZT in the shortest possible time. At 9 minutes, the gradient was programmed to initial conditions for column equilibration. Injection volumes ranged from 5 to 100 µL and all separations were performed at ambient temperature.

Mass spectrometry: The entire column effluent was directed into a Platform II single quadrupole mass spectrometer (Micromass UK Ltd., Manchester, UK) equipped with an electrospray interface for mass analysis. Because 3TC and AMT were ionized more effectively in positive ionization mode, while AZT and GAZT required negative ionization, the chromatographic run was split into three scan events. The first scan event was from 0 to 6 minutes and monitored positive ions in selected ion monitoring (SIM) mode for the protonated molecule of AMT and its major product ion (m/z 116). The protonated molecular ion [(M+ H)^+^] for AMT (m/z 242) had optimal ionization at a cone-skimmer potential of 15 volts (V), while the fragment ion required 25 V. The second scan event was from 6.1 to 8.1 minutes and used positive SIM for the protonated molecules of 3TC, ^13^C_2_^15^N_3_-3TC internal standard, and the major fragment ion. The (M+H)^+^ ion for 3TC (m/z 230) and its internal standard (m/z 235) had optimal ionization at a cone-skimmer potential of 15 V, while the fragment ion of 3TC (m/z 112) required 25 V. In the third scan event, which was from 8.2 to 11 minutes, the deprotonated molecular ions [(M−H)^–^] for AZT (m/z 266), GAZT (m/z 442), and ^13^C_1_^15^N_1_d_3_-AZT (m/z 271) were analyzed with a cone-skimmer potential of 25 V, while the AZT fragment ion (m/z 233) was analyzed at 40 V. Quality control procedures included concurrent analysis of spiked serum samples (0.1, 1, and 10 µg/mL), blank serum, and a mixture of labeled and unlabeled standards interspersed throughout each sample set. Full details of the assay validation are given in Williams et al. (2003).

The data were plotted in SigmaPlot^®^ 9.01 (Systat Software Inc., Chicago, IL) to derive kinetic parameters. Apparent half-lives and C_max_ values were obtained from linear regression of plots of the natural log of serum concentrations against time-after-dose, assuming a t_max_ of 15 minutes, as reported for B6C3F1/N mice by Williams et al. (2003). Integrated area-under-the-curve (AUC) values for each dose group were calculated using a SigmaPlot^®^ area transform of the serum concentration versus time-after-dose plots.

## Results and Discussion

Although both AMT and GAZT were present in serum from heterozygous F1 p53^+/−^ mouse pups that were exposed to AZT, their concentrations were relatively low, and unmetabolized AZT was the predominant form present.

Serum AZT concentrations evaluated on PND 10 and PND 28 are shown in Tables I3 and I4, respectively, and serum AZT profiles are plotted in Figure I1. Because no significant sex differences were observed, corresponding values for male and female mice were combined. On PND 10, the apparent serum half-life for AZT ranged from 0.99 to 1.20 hours for the four doses of AZT alone (mean=1.08 ± 0.05 hours). By PND 28, the apparent half-life of serum AZT had decreased to between 0.75 and 0.88 hours for the four doses of AZT alone (mean=0.80 ± 0.03 hours); this decrease was significant (P=0.0025) when tested by a one-tailed Student’s t-test.

Both AMT and GAZT were detected at levels that were close to the limit of detection for the assay, and so kinetic parameters could not be calculated with accuracy. Their concentrations and percentage of AZT concentration are shown in Table I5. Serum AMT concentrations increased as a percentage of AZT concentration with time-after-dose suggesting that it had a longer serum half-life than AZT and its concentration as a percentage of AZT concentration was significantly greater in 28-day-old mice than in 10-day-old mice. Serum GAZT concentrations were less than 2% of AZT concentrations for all doses and were not significantly different between mice evaluated on PND 10 and those evaluated on PND 28. Rodents are known to be much less efficient at glucuronidating AZT than humans and non-human primates (Nicolas et al., 1995). It is probable that the decrease in AZT serum half-life that occurs between PND 10 and PND 28 results from a combination of increased oxidation to AMT and increased rates of renal clearance of AZT, since the latter is the major route of AZT elimination in mice (Ayers et al., 1996).

Serum AZT and 3TC concentrations in heterozygous F1 p53^+/−^ mice that were exposed to combination doses of AZT and 3TC are shown in Table I6 and Figure I2. The serum concentrations and kinetic parameters for AZT in these animals were similar to those in mice administered the same doses of AZT alone (Tables I3 and I4), suggesting that coadministration of 3TC does not influence the absorption, distribution, metabolism, and excretion of AZT. Serum 3TC concentrations were lower than those of AZT, but its apparent half-life values were similar to those of AZT.

Donnerer et al. (2008) reported that plasma AZT concentrations in a series of patients receiving AZT alone or in combination with other HAART drugs ranged from 0.07 to 2.59 µg/mL when measured 1 to 3 hours after dose (300 mg bid) ingestion. The highest concentration in this range (2.59 µg/mL or 9.7 µM), which was obtained approximately 1 hour postdosing, was used to estimate a maximum human dose profile (Figure I3) in conjunction with the reported plasma half-life of 1.2 hours in humans. This was compared to the corresponding serum concentration curves for dosed heterozygous F1 p53^+/−^ mice as shown in Figure I1. The human dose curve exhibited a lower C_max_ and AUC than those of all the dosed mouse groups so it was directly compared with that of the PND 28 mouse group that received 40 mg AZT/kg once per day, because this dose group exhibited the lowest C_max_ and AUC values of all the dosed mouse groups. The kinetic parameters from this dose group (Table I4) were used to create the hypothetical serum concentration curve for PND 28 mice receiving two daily doses of 40 mg/kg, 6.5 hours apart (Figure I3). The AZT/3TC/NVP-L dose group of the main 45-week study received an equivalent dose of AZT. As shown in Table I7, while the apparent C_max_ value of the 40 mg/kg twice daily dose group was more than twofold greater (212.4%) than the human C_max_, the AUC value was only moderately greater (135.8%).

In conclusion, these toxicokinetic studies suggest that the doses of AZT used in the 45-week study would produce AUC values for serum concentrations of AZT that ranged from the maximum of the human therapeutic range for the AZT/3TC/NVP-L dose group up to approximately 25-fold greater than the maximum of the human therapeutic range for the AZT-H, AZT/3TC-H and AZT/3TC/NVP-H dose groups.

## References

Ayers, K.M., Clive, D., Tucker, W.E., Jr., Hajian, G., and de Miranda, P. (1996). Nonclinical toxicology studies with zidovudine: Genetic toxicity tests and carcinogenicity bioassays in mice and rats. Fundam. Appl. Toxicol. 32, 148–158.8921318
Donnerer, J., Haas, B.J., and Kessler, H.H. (2008). Single-measurement therapeutic drug monitoring of the HIV/AIDS drugs abacavir, zidovudine, lamivudine, efavirenz, nevirapine, lopinavir and nelfinavir. Pharmacology 82, 287–292.18931536
National Toxicology Program (NTP) (2013). Toxicology and Carcinogenesis Studies of Mixtures of 3′-Azido-3′-Deoxythymidine (AZT), Lamivudine (3TC), Nevirapine (NVP), and Nelfinavir Mesylate (NFV) (CAS Nos. 30516-87-1, 134678-17-4, 129618-40-2, 159989-65-8) in B6C3F1 Mice (Transplacental Exposure Studies). Technical Report Series No. 569. NIH Publication No. 13-5911. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
Nicolas, F., De Sousa, G., Thomas, P., Placidi, M., Lorenzon, G., and Rahmani, R. (1995). Comparative metabolism of 3′-azido-3′-deoxythymidine in cultured hepatocytes from rats, dogs, monkeys, and humans. Drug Metab. Dispos. 23, 308–313.7628294
Williams, L.D., Von Tungeln, L.S., Beland, F.A., and Doerge, D.R. (2003). Liquid chromatographic-mass spectrometric determination of the metabolism and disposition of the anti-retroviral nucleoside analogs zidovudine and lamivudine in C57BL/6N and B6C3F1 mice. J. Chromatogr. B Analyt. Technol. Biomed. Life Sci. 798, 55–62.

TABLE I1 Daily Doses for Heterozygous F1 p53^+/−^ Mice Evaluated on Postnatal Day 10^a^

Dose Group | Prenatal Treatment: Gestational Day 12 - 18 Maternal Gavage | Postnatal Treatment: Postnatal Day 1 - 10 Gavage
3 | 40 mg AZT/kg | 20 mg AZT/kg
4 | 80 mg AZT/kg | 40 mg AZT/kg
5 | 160 mg AZT/kg | 80 mg AZT/kg
6 | 160 mg AZT/kg + 100 mg 3TC/kg | 80 mg AZT/kg + 50 mg 3TC/kg
11 | 240 mg AZT/kg | 120 mg AZT/kg

a Mice were dosed once per day and were evaluated 1, 2, 4, 6, 10 and 12 hours after the final dose.

TABLE I2 Daily Doses for Heterozygous F1 p53^+/−^ Mice Evaluated on Postnatal Day 28^a^

Dose Group | Prenatal Treatment: Gestational Days 12 - 18 Maternal Gavage | Postnatal Treatment: Postnatal Day 1 - 10 Gavage | Postnatal Treatment: Postnatal Day 11 - 28 Gavage
3 | 40 mg AZT/kg | 20 mg AZT/kg | 40 mg AZT/kg
4 | 80 mg AZT/kg | 40 mg AZT/kg | 80 mg AZT/kg
5 | 160 mg AZT/kg | 80 mg AZT/kg | 160 mg AZT/kg
6 | 160 mg AZT/kg + 100 mg 3TC/kg | 80 mg AZT/kg + 50 mg 3TC/kg | 160 mg AZT/kg + 100 mg 3TC/kg
11 | 240 mg AZT/kg | 120 mg AZT/kg | 240 mg AZT/kg

a Mice were dosed once per day and were evaluated 1, 2, 4, 6, 10 and 12 hours after the final dose.

TABLE I3 Serum Concentrations of AZT and Kinetic Parameters for Heterozygous F1 p53^+/−^ Mice Administered Once Daily Doses of AZT and Evaluated on Postnatal Day 10^a^

| AZT 20 mg/kg | AZT 40 mg/kg | AZT 80 mg/kg | AZT 120 mg/kg
Serum Concentration (µM)^b^
Hours after final dose
1 | 28.5 ± 1.5 (8) | 52.5 ± 6.0 (10) | 157 ± 7 (7) | 619 ± 51 (9)
2 | 15.5 ± 1.2 (8) | 27.6 ± 2.6 (7) | 84.8 ± 9.7 (8) | 206 ± 39 (10)
4 | 4.4 ± 1.7 (8) | 9.2 ± 0.9 (7) | 20.7 ± 3.4 (9) | 73 ± 11.6 (10)
6 | —^c^ | — | 5.5 ± 1.0 (8) | 21.7 ± 5.7 (9)
10 | — | — | 1.8 ± 0.5 (6) | 4.29 ± 1.5 (9)
24 | — | — | 0.2 ± 0.1 (7) | 0.5 ± 0.3 (8)
Kinetic Parameter^d^
AUC (µM•hour) | 84.6 | 156.1 | 487.1 | 1,544.0
Apparent C_max_ (µM) | 45.7 | 78.7 | 294.8 | 879.1
Apparent t_½_ (hour) | 1.11 | 1.20 | 0.99 | 1.01

a Dose groups are listed according to the final dose on PND 10. Serum concentration values are given as mean ± standard error (n).

b Each serum sample was prepared from trunk blood from a single mouse; serum concentrations in male and female mice were combined because the values were not significantly different within the dose groups.

c Not determined

d Kinetic calculations assume a t_max_ of 15 minutes (Williams et al., 2003).

TABLE I4 Serum Concentrations of AZT and Kinetic Parameters for Heterozygous F1 p53^+/−^ Mice Administered Once Daily Doses of AZT and Evaluated on Postnatal Day 28^a^

| AZT 40 mg/kg | AZT 80 mg/kg | AZT 160 mg/kg | AZT 240 mg/kg
Serum Concentration (µM)^b^
Hours after final dose
1 | 12.7 ± 1.7 (6) | 33.8 ± 6.0 (10) | 78.6 ± 6.4 (8) | 293 ± 50 (10)
2 | 4.4 ± 1.5 (6) | 15.6 ± 9.0 (10) | 31.8 ± 7.8 (10) | 161 ± 67 (10)
4 | 1.1 ± 0.4 (5) | 2.5 ± 0.8 (10) | 5.5 ± 2.0 (10) | 30.5 ± 11.8 (8)
6 | —^c^ | — | 1.9 ± 0.5 (9) | 3.0 ± 1.3 (7)
10 | — | — | 0.6 ± 0.3 (6) | 3.3 ± 1.4 (6)
24 | — | — | 0.5 ± 0.4 (6) | 0.4 ± 0.4 (8)
Kinetic Parameter^d^
AUC (µM•hour) | 31.0 | 93.2 | 218 | 958
Apparent C_max_ (µM) | 20.6 | 68 | 152 | 718
Apparent t_½_ (hour) | 0.88 | 0.79 | 0.78 | 0.75

a Dose groups are listed according to the final dose on PND 28. Serum concentration values are given as mean ± standard error (n).

b Each serum sample was prepared from trunk blood from a single mouse; serum concentrations in male and female mice were combined because the values were not significantly different within the dose groups.

c Not determined

d Kinetic calculations assume a t_max_ of 15 minutes (Williams et al., 2003).

FIGURE I1 Serum Concentrations of AZT in Heterozygous F1 p53^+/−^ Mice Administered Once Daily Doses of AZT and Evaluated on Postnatal Day 10 or 28

Serum Concentrations of AZT in Heterozygous F1 p53+/− Mice Administered Once Daily Doses of AZT and Evaluated on Postnatal Day 10

Serum Concentrations of AZT in Heterozygous F1 p53+/− Mice Administered Once Daily Doses of AZT and Evaluated on Postnatal Day 28

TABLE I5 Percent of AZT Dose Converted to AMT or GAZT in Heterozygous F1 p53^+/−^ Mice Administered Once Daily Doses of AZT or AZT/3TC and Evaluated on Postnatal Day 10 or 28^a^

Dose^b^ | AMT concentration as % of AZT concentration | | GAZT concentration as % of AZT concentration
| 1 Hour^c^ | All^d^ | 1 Hour | All
PND 10
20 mg AZT/kg | 0.49% | 1.01% | 0.50% | 0.34%
40 mg AZT/kg | 0.29% | 0.83% | 0.40% | 0.21%
80 mg AZT/kg | 0.27% | 1.38% | 0.73% | 0.38%
80 mg AZT/kg + 50 mg 3TC/kg | 0.33% | 1.05% | 0.64% | 0.94%
120 mg AZT/kg | 0.50% | 2.91% | 0.92% | 0.22%
Overall mean ± standard error^e^ | 0.38% ± 0.05% | 1.44% ± 0.038% | 0.64% ± 0.09% | 0.42% ± 0.13%
PND 28
40 mg AZT/kg | 1.04% | 9.88% | 0.00% | 0.00%
80 mg AZT/kg | 0.93% | 4.89% | 0.45% | 1.42%
160 mg AZT/kg | 0.72% | 7.72% | 0.13% | 0.18%
160 mg AZT/kg + 100 mg 3TC/kg | 1.13% | 3.97% | 0.72% | 0.37%
240 mg AZT/kg | 0.52% | 26.61% | 0.00% | 0.07%
Overall mean ± standard error | 0.87% ± 0.11% | 10.61% ± 4.13% | 0.26% ± 0.14% | 0.41% ± 0.26%
P value^f^ | 0.0097 | 0.0359 | 0.060 | 0.490

a Percentages were calculated on the molar concentrations of AZT, AMT, and GAZT in serum.

b The dose groups are listed according to final dose on PND 10 or PND 28.

c One hour after the final dose for the dose group

d Mean for all six postdosing time points evaluated for the dose group

e Mean for all five dose groups on the indicated postnatal day

f Probability of significant difference between the overall mean PND 10 and PND 28 values by a one-tailed Student’s t-test.

TABLE I6 Serum Concentrations of AZT and 3TC and Kinetic Parameters for Heterozygous F1 p53^+/−^ Mice Administered Once Daily Doses of AZT/3TC and Evaluated on Postnatal Day 10 or 28^a^

| AZT/3TC 80/50 mg/kg; PND 10 | | AZT/3TC 160/100 mg/kg; PND 28
| AZT | 3TC | AZT | 3TC
Serum Concentration (µM)^b^
Hours after final dose
1 | 154 ± 9.5 (8) | 111 ± 4.7 (8) | 78.9 ± 14.3 (9) | 45.7 ± 9.2 (9)
2 | 98.6 ± 9.0 (9) | 55.4 ± 4.6 (9) | 38.2 ± 13.4 (6) | 16.6 ± 4.2 (6)
4 | 20.6 ± 2.6 (9) | 8.8 ± 1.0 (9) | 6.1 ± 2.0 (6) | 5.0 ± 1.5 (6)
Kinetic Parameter^c^
AUC (µM•hour) | 488 | 317 | 216 | 114
Apparent C_max_ (µM) | 287 | 227 | 154 | 69.8
Apparent t_½_ (hour) | 1.01 | 0.81 | 0.81 | 0.96

a Dose groups are listed according to the final dose on PND 10 or PND 28. Serum concentration values are given as mean standard ± error (n).

b Each serum sample was prepared from trunk blood from a single mouse; serum concentrations in male and female mice were combined because the values were not significantly different within the dose groups.

c Kinetic calculations assume a t_max_ of 15 minutes (Williams et al., 2003).

FIGURE I2 Serum Concentrations of AZT and 3TC in Heterozygous F1 p53^+/−^ Mice Administered Once Daily Doses of AZT/3TC and Evaluated on Postnatal Day 10 or 28

(Dose concentrations are given in Tables I1 and I2)

Serum Concentrations of AZT and 3TC in Heterozygous F1 p53+/− Mice Administered Once Daily Doses of AZT/3TC and Evaluated on Postnatal Day 10 or 28 (Dose concentrations are given in Tables I1 and I2)

FIGURE I3 Simulated Serum Concentrations of AZT in Humans Administered 300 mg Twice Daily Therapeutic Doses of AZT Resulting in a C_max_ of 9.7 µM and in Heterozygous F1 p53^+/−^ Mice Administered Twice Daily Doses of 40 mg/kg AZT on PND 28

Simulated Serum Concentrations of AZT in Humans Administered 300 mg Twice Daily Therapeutic Doses of AZT Resulting in a Cmax of 9.7 μM and in Heterozygous F1 p53+/− Mice Administered Twice Daily Doses of 40 mg/kg AZT on PND 28

TABLE I7 Simulated Kinetic Parameters for AZT in Humans and Heterozygous F1 p53^+/−^ Mice Administered Twice Daily Doses of AZT

Kinetic Parameter | Humans; AZT 4 mg/kg Twice Daily^a^ | Mice; AZT 40 mg/kg Twice Daily on PND 28
AUC (µM•hour)^b^ | 44.38 | 60.28 (135.8%)^e^
Apparent C_max_ (µM)^c^ | 9.7^d^ | 20.6 (212.4%)^e^
Apparent t_½_ [t_max_](hour)^c^ | 1.2 [1.0] | 0.88 [0.25]

a Reported dose was 300 mg twice daily, corresponding to 4.3 mg/kg twice daily for a 70 kg person (Donnerer et al., 2008)

b AUC values calculated from both doses shown in Figure I3.

c Human values are taken from Donnerer et al. (2008) and correspond to values observed in a patient exhibiting high AZT plasma concentrations following AZT therapy; mouse values are derived from the parameter estimates resulting from a single daily dose as shown in Table I4.

d 9.7 µM = 2.59 µg/mL

e Parenthetical value is percent of human value