# APPENDIX H LITTER SUCCESS AND SURVIVAL

TABLE H1 Litter Parameters and Pup Survival to 28 Days for Mouse Pups in the In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Total dams pregnant^b^ | 30 | 26 | 24 | 37
Dams that did not litter | 2 | 2 | 1 | 2
Total litters | 28 | 24 | 23 | 35
Total pups born | 204 | 180 | 156 | 208
Average per litter | 7.29 | 7.5 | 6.78 | 5.94
Number of males born | 105 | 85 | 71 | 93
Sex ratio of live pups (female:male) | 1:1.18 | 1:1.10 | 1:0.90 | 1:0.89
Pups born dead (%) | 10 (4.9) | 18 (10.0) | 6 (3.8) | 11 (5.3)
Percent survival PND 1 - PND 10^c^ | 82.74% | 78.70% | 90.58% | 81.03%
Survival analysis^d^ | NS | NS | NS | NS
Percent survival PND 11 - PND 28^e^ | 96.54% | 98.02% | 81.52% | 48.82%
Survival analysis^f^ | P<0.001 | NS | P=0.006 | P<0.001
Pups assigned to 45-week study | 50 | 50 | 50 | 50
Litters used for 45-week study | 24 | 16 | 16 | 24

a AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg.

b Plug positive dams were randomly assigned to dose groups on gestational day (GD) 0 (day plug was observed), and their weight gain was monitored to confirm pregnancy. Dams that did not gain sufficient weight to indicate pregnancy by GD 11 were returned to the breeding pool and are not included in this table.

c Excludes pups that were culled on postnatal day (PND) 1, and includes both males and females

d Overall survival within litters to PND 10. Beneath the vehicle control group is the P value associated with a linear trend test. Beneath the dosed groups are the P values corresponding to pairwise comparisons by Dunnett’s test. NS=not significant

e Excludes pups that died or were culled before PND 11, and includes both males and females

f Beneath the vehicle control group is the P value associated with a linear trend test. Beneath the dosed groups are the P values corresponding to pairwise comparisons by Dunnett-Hsu adjusted comparisons among groups in log-rank analysis between the vehicle controls and that dosed group.

TABLE H2 Litter Parameters and Pup Survival to 28 Days for Mouse Pups in the In Utero/Postnatal Gavage Study a of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
Total dams pregnant^b^ | 30 | 29 | 28 | 26 | 28 | 37
Dams that did not litter | 2 | 0 | 3 | 3 | 1 | 2
Total litters | 28 | 29 | 25 | 23 | 27 | 35
Total pups born | 204 | 206 | 147 | 155 | 184 | 208
Average per litter | 7.29 | 7.10 | 5.88 | 6.74 | 6.81 | 5.94
Number of males born | 105 | 100 | 64 | 74 | 91 | 93
Sex ratio of live pups (female:male) | 1:1.18 | 1:0.99 | 1:0.84 | 1:0.94 | 1:1.12 | 1:0.89
Pups born dead (%) | 10 (4.9) | 5 (2.4) | 7 (4.8) | 2 (1.3) | 12 (6.5) | 11 (5.3)
Percent survival PND 1 - PND 10^c^ | 82.74% | 83.10% | 86.11% | 86.23% | 94.00% | 81.03%
Survival analysis [vs. vehicle control]^d^ | | NS | NS | NS | NS | NS
Survival analysis [vs. AZT/3TC/NVP-H]^d^ | NS | NS | NS | NS | NS
Percent survival PND 11 - PND 28^e^ | 96.54% | 80.60% | 99.09% | 99.24% | 71.47% | 48.82%
Survival analysis [vs. vehicle control]^f^ | | P=0.037 | NS | NS | P<0.001 | P<0.001
Survival analysis [vs. AZT/3TC/NVP-H]^f^ | P<0.001 | P<0.001 | P<0.001 | P<0.001 | P<0.001
Pups assigned to 45-week study | 50 | 50 | 50 | 51 | 50 | 50
Litters used for study | 24 | 22 | 17 | 19 | 20 | 24

a AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b Plug positive dams were randomly assigned to dose groups on gestational day (GD) 0 (day plug was observed), and their weight gain was monitored to confirm pregnancy. Dams that did not gain sufficient weight to indicate pregnancy by GD 11 were returned to the breeding pool and are not included in this table.

c Excludes pups that were culled on postnatal day (PND) 1, and includes both males and females

d Overall survival within litters to PND 10. P values represent pairwise comparisons with a Tukey’s test. NS=not significant

e Excludes pups that died or were culled before PND 11, and includes both males and females

f P values represent Tukey-Kramer adjusted comparisons among groups in log-ranked analysis. NS=not significant

TABLE H3 Effect of Dose on Survival from Postnatal Day 11 to PND 28 in Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Hazard Ratio^b^ | 100% | 42.9% | 545.1% | 2207.7%
P Value^c^ | <0.001*** | 0.908 | 0.006** | <0.001***

a Includes mice that were culled from the study at PND 28; AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg.

b The Hazard Ratio represents the treatment group hazard relative to vehicle controls. The ratio for the vehicle control group is always 100%.

c The P values presented are from the Dunnett-Hsu adjusted comparisons among groups in the log-rank analysis.

TABLE H4 Effect of Dose on Survival from Postnatal Day 11 to PND 28 in Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
Vehicle Control | 0.037* | 1.000 | 1.000 | <0.001*** | <0.001***
569.9% | AZT-H | 0.031* | 0.037* | 0.287 | <0.001***
13.4% | 2.3% | 3TC-H | 1.000 | <0.001*** | <0.001***
38.7% | 6.8% | 289.5% | NVP-H | <0.001*** | <0.001***
965.7% | 169.4% | 7,224.1% | 2,495.3% | AZT/3TC-H | <0.001***
2,178.2% | 382.2% | 16,294.2% | 5,628.1% | 225.6% | AZT/3TC/NVP-H

a Includes mice that were culled from the study at PND 28; P values are two-sided Tukey-Kramer comparisons among groups in the log-rank analysis; comparisons are between column dose group listed above the value and the row dose group listed to the left of it. Percentages represent the hazard ratio of the column dose group listed above the value compared to the row dose group listed to the right of it. AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

FIGURE H1 Pup Survival from Postnatal Day 1 to PND 28 for Mouse Pups in the In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison

Line at PND 10 marks the change from the neonatal to the adult dose

Pup Survival from Postnatal Day 1 to PND 28 for Mouse Pups in the In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison

FIGURE H2 Pup Survival from Postnatal Day 1 to PND 28 for Mouse Pups in the In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison

Line at PND 10 marks the change from the neonatal to the adult dose

Pup Survival from Postnatal Day 1 to PND 28 for Mouse Pups in the In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison

TABLE H5 Effects of Dose on Gestational Weight Gain in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison (Comparisons Adjusted for Litter Size)^a,b^

Gestational Day | Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
2 | 0.1 ± 0.2 | 0.2 ± 0.2 | 0.2 ± 0.2 | 0.2 ± 0.2
| 0.365 | 0.451 | 0.460 | 0.351
3 | 0.5 ± 0.2 | 0.5 ± 0.3 | 0.4 ± 0.2 | 0.4 ± 0.2
| 0.362N | 0.418N | 0.323N | 0.385N
4 | 0.9 ± 0.2 | 0.9 ± 0.3 | 0.9 ± 0.3 | 0.8 ± 0.2
| 0.389N | 0.479N | 0.482 | 0.367N
5 | 1.0 ± 0.3 | 1.1 ± 0.3 | 1.0 ± 0.3 | 1.0 ± 0.2
| 0.459N | 0.471 | 0.432N | 0.490N
6 | 1.3 ± 0.3 | 1.4 ± 0.3 | 1.2 ± 0.3 | 1.3 ± 0.2
| 0.415N | 0.372 | 0.411N | 0.486N
7 | 1.5 ± 0.3 | 1.7 ± 0.3 | 1.5 ± 0.3 | 1.9 ± 0.3
| 0.293 | 0.359 | 0.445N | 0.222
8 | 1.8 ± 0.3 | 2.1 ± 0.3 | 1.8 ± 0.3 | 2.3 ± 0.3
| 0.195 | 0.228 | 0.493 | 0.116
9 | 2.2 ± 0.3 | 2.4 ± 0.3 | 2.3 ± 0.3 | 2.7 ± 0.3
| 0.148 | 0.339 | 0.417 | 0.114
10 | 3.0 ± 0.3 | 3.3 ± 0.3 | 3.1 ± 0.3 | 3.3 ± 0.3
| 0.281 | 0.252 | 0.343 | 0.235
11 | 3.9 ± 0.3 | 4.1 ± 0.3 | 3.9 ± 0.3 | 4.2 ± 0.3
| 0.263 | 0.282 | 0.496 | 0.187
12 | 4.9 ± 0.3 | 5.4 ± 0.3 | 5.0 ± 0.3 | 5.4 ± 0.2
| 0.177 | 0.113 | 0.361 | 0.095
13 | 6.8 ± 0.1 | 6.6 ± 0.1 | 6.6 ± 0.1 | 6.6 ± 0.1
| 0.191N | 0.186N | 0.193N | 0.171N
14 | 8.0 ± 0.2 | 7.9 ± 0.2 | 7.9 ± 0.2 | 7.9 ± 0.2
| 0.494 | 0.339N | 0.481N | 0.456N
15 | 9.5 ± 0.2 | 9.2 ± 0.2 | 9.4 ± 0.2 | 9.2 ± 0.2
| 0.230N | 0.157N | 0.419N | 0.140N
16 | 11.1 ± 0.2 | 10.9 ± 0.2 | 11.0 ± 0.2 | 10.6 ± 0.2
| 0.061N | 0.251N | 0.395N | 0.034N*
17 | 12.9 ± 0.2 | 12.6 ± 0.3 | 12.9 ± 0.3 | 12.4 ± 0.2
| 0.094N | 0.195N | 0.468 | 0.039N*
18 | 14.8 ± 0.3 | 14.6 ± 0.3 | 14.8 ± 0.3 | 14.0 ± 0.3
| 0.033N* | 0.255N | 0.416N | 0.015N*
19 | 16.7 ± 0.3 | 16.1 ± 0.4 | 16.7 ± 0.4 | 16.0 ± 0.3
| 0.152N | 0.139N | 0.495N | 0.067N

a The first line for a gestational day represents cumulative weight gain ± standard error, expressed in grams.

AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg.

b Beneath the vehicle control weight is the P value associated with the trend test. Beneath the dosed group weights are P values representing pairwise comparisons to the vehicle control group by Dunnett’s test with no multiple comparison adjustment. A negative trend or lower weight in a dosed group is indicated by N.

TABLE H6 Effects of Dose on Gestational Weight Gain in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison (Comparisons Adjusted for Litter Size)^a,b^

Gestational Day | Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
2 | 0.1 ± 0.2 | 0.2 ± 0.2 | 0.4 ± 0.2 | 0.2 ± 0.2 | 0.2 ± 0.2 | 0.2 ± 0.2
| Vehicle control | 0.413 | 0.202 | 0.421 | 0.410 | 0.408
| | AZT-H | 0.262 | 0.497N | 0.495 | 0.495
| | | 3TC-H | 0.270N | 0.271N | 0.257N
| | | | NVP-H | 0.492 | 0.492
| | | | | AZT/3TC-H | 0.499N
3 | 0.6 ± 0.2 | 0.4 ± 0.2 | 0.6 ± 0.2 | 0.6 ± 0.2 | 0.6 ± 0.2 | 0.4 ± 0.2
| Vehicle control | 0.350N | 0.411 | 0.435 | 0.426 | 0.300N
| | AZT-H | 0.276 | 0.298 | 0.286 | 0.445N
| | | 3TC-H | 0.478N | 0.484N | 0.223N
| | | | NVP-H | 0.493 | 0.249N
| | | | | AZT/3TC-H | 0.238N
4 | 1.0 ± 0.2 | 1.0 ± 0.2 | 1.0 ± 0.2 | 1.1 ± 0.2 | 1.2 ± 0.2 | 0.8 ± 0.2
| Vehicle control | 0.499 | 0.390 | 0.361 | 0.205 | 0.293N
| | AZT-H | 0.389 | 0.361 | 0.203 | 0.289N
| | | 3TC-H | 0.470 | 0.303 | 0.199N
| | | | NVP-H | 0.332 | 0.185N
| | | | | AZT/3TC-H | 0.082N
5 | 1.1 ± 0.2 | 1.1 ± 0.2 | 1.2 ± 0.2 | 1.1 ± 0.2 | 1.4 ± 0.2 | 1.0 ± 0.2
| Vehicle control | 0.459 | 0.293 | 0.423 | 0.145 | 0.427N
| | AZT-H | 0.325 | 0.460 | 0.168 | 0.385N
| | | 3TC-H | 0.369N | 0.316 | 0.222N
| | | | NVP-H | 0.208 | 0.351N
| | | | | AZT/3TC-H | 0.101N
6 | 1.3 ± 0.2 | 1.4 ± 0.2 | 1.4 ± 0.2 | 1.4 ± 0.2 | 1.7 ± 0.2 | 1.3 ± 0.2
| Vehicle control | 0.323 | 0.402 | 0.370 | 0.086 | 0.479N
| | AZT-H | 0.425N | 0.461N | 0.177 | 0.300N
| | | 3TC-H | 0.467 | 0.143 | 0.376N
| | | | NVP-H | 0.166 | 0.346N
| | | | | AZT/3TC-H | 0.072N
7 | 1.6 ± 0.2 | 1.8 ± 0.2 | 1.6 ± 0.3 | 1.7 ± 0.3 | 2.2 ± 0.2 | 1.8 ± 0.2
| Vehicle control | 0.248 | 0.468 | 0.386 | 0.036* | 0.264
| | AZT-H | 0.284N | 0.363N | 0.126 | 0.476N
| | | 3TC-H | 0.419 | 0.049* | 0.293
| | | | NVP-H | 0.077 | 0.380
| | | | | AZT/3TC-H | 0.108N
8 | 1.8 ± 0.2 | 2.1 ± 0.2 | 2.1 ± 0.2 | 2.2 ± 0.3 | 2.5 ± 0.2 | 2.2 ± 0.2
| Vehicle control | 0.151 | 0.178 | 0.108 | 0.013* | 0.100
| | AZT-H | 0.477N | 0.394 | 0.111 | 0.406
| | | 3TC-H | 0.377 | 0.110 | 0.384
| | | | NVP-H | 0.185 | 0.480N
| | | | | AZT/3TC-H | 0.153N
9 | 2.2 ± 0.3 | 2.6 ± 0.2 | 2.7 ± 0.3 | 2.8 ± 0.3 | 2.9 ± 0.3 | 2.7 ± 0.2
| Vehicle control | 0.173 | 0.117 | 0.054 | 0.030* | 0.079
| | AZT-H | 0.381 | 0.233 | 0.165 | 0.322
| | | 3TC-H | 0.340 | 0.262 | 0.447
| | | | NVP-H | 0.416 | 0.377N
| | | | | AZT/3TC-H | 0.291N
10 | 3.0 ± 0.2 | 3.2 ± 0.2 | 3.4 ± 0.3 | 3.4 ± 0.3 | 3.7 ± 0.3 | 3.2 ± 0.2
| Vehicle control | 0.236 | 0.113 | 0.103 | 0.013* | 0.206
| | AZT-H | 0.296 | 0.278 | 0.063 | 0.464
| | | 3TC-H | 0.477 | 0.173 | 0.317N
| | | | NVP-H | 0.192 | 0.300N
| | | | | AZT/3TC-H | 0.069N
11 | 3.9 ± 0.2 | 4.1 ± 0.2 | 4.1 ± 0.3 | 4.5 ± 0.3 | 4.6 ± 0.3 | 4.2 ± 0.2
| Vehicle control | 0.261 | 0.283 | 0.032* | 0.023* | 0.182
| | AZT-H | 0.488N | 0.105 | 0.083 | 0.396
| | | 3TC-H | 0.108 | 0.088 | 0.385
| | | | NVP-H | 0.467 | 0.149N
| | | | | AZT/3TC-H | 0.123N
12 | 4.9 ± 0.3 | 5.1 ± 0.2 | 5.3 ± 0.3 | 5.6 ± 0.3 | 5.5 ± 0.3 | 5.4 ± 0.2
| Vehicle control | 0.232 | 0.096 | 0.017* | 0.030* | 0.055
| | AZT-H | 0.269 | 0.075 | 0.121 | 0.195
| | | 3TC-H | 0.213 | 0.304 | 0.423
| | | | NVP-H | 0.381N | 0.253N
| | | | | AZT/3TC-H | 0.361N
13 | 6.9 ± 0.1 | 6.7 ± 0.1 | 6.7 ± 0.1 | 6.7 ± 0.1 | 7.0 ± 0.1 | 6.8 ± 0.11
| Vehicle control | 0.182N | 0.116N | 0.196N | 0.258 | 0.221N
| | AZT-H | 0.371N | 0.496 | 0.063 | 0.437
| | | 3TC-H | 0.371 | 0.036* | 0.306
| | | | NVP-H | 0.072 | 0.443
| | | | | AZT/3TC-H | 0.077N
14 | 8.1 ± 0.2 | 7.8 ± 0.2 | 8.0 ± 0.2 | 7.9 ± 0.2 | 8.2 ± 0.2 | 8.0 ± 0.2
| Vehicle control | 0.087N | 0.375N | 0.247N | 0.330 | 0.387N
| | AZT-H | 0.166 | 0.272 | 0.038* | 0.137
| | | 3TC-H | 0.363N | 0.231 | 0.479
| | | | NVP-H | 0.137 | 0.334
| | | | | AZT/3TC-H | 0.231N
15 | 9.6 ± 0.2 | 9.2 ± 0.2 | 9.5 ± 0.2 | 9.5 ± 0.2 | 9.6 ± 0.2 | 9.3 ± 0.2
| Vehicle control | 0.096N | 0.453N | 0.431N | 0.413 | 0.168N
| | AZT-H | 0.131 | 0.143 | 0.067 | 0.356
| | | 3TC-H | 0.478N | 0.372 | 0.204N
| | | | NVP-H | 0.351 | 0.227N
| | | | | AZT/3TC-H | 0.118N
16 | 11.2 ± 0.4 | 10.8 ± 0.4 | 11.1 ± 0.4 | 11.1 ± 0.4 | 12.0 ± 0.4 | 10.7 ± 0.3
| Vehicle control | 0.201N | 0.418N | 0.459N | 0.047* | 0.145N
| | AZT-H | 0.278 | 0.244 | 0.006** | 0.419N
| | | 3TC-H | 0.460 | 0.036* | 0.204N
| | | | NVP-H | 0.045* | 0.180N
| | | | | AZT/3TC-H | 0.003N**
17 | 13.0 ± 0.2 | 12.7 ± 0.2 | 12.9 ± 0.3 | 13.0 ± 0.3 | 13.3 ± 0.3 | 12.5 ± 0.2
| Vehicle control | 0.186N | 0.467N | 0.423 | 0.153 | 0.063N
| | AZT-H | 0.224 | 0.150 | 0.029* | 0.268N
| | | 3TC-H | 0.395 | 0.146 | 0.079N
| | | | NVP-H | 0.217 | 0.047N*
| | | | | AZT/3TC-H | 0.005N**
18 | 14.9 ± 0.2 | 14.6 ± 0.2 | 14.8 ± 0.3 | 15.0 ± 0.3 | 15.2 ± 0.3 | 14.1 ± 0.2
| Vehicle control | 0.198N | 0.421N | 0.392 | 0.221 | 0.008N**
| | AZT-H | 0.273 | 0.141 | 0.056 | 0.061N
| | | 3TC-H | 0.324 | 0.177 | 0.015N*
| | | | NVP-H | 0.323 | 0.005N**
| | | | | AZT/3TC-H | <0.001N***
19 | 16.7 ± 0.3 | 16.4 ± 0.3 | 17.0 ± 0.3 | 16.9 ± 0.3 | 17.0 ± 0.3 | 16.0 ± 0.3
| Vehicle control | 0.263N | 0.198 | 0.335 | 0.233 | 0.047N*
| | AZT-H | 0.074 | 0.154 | 0.090 | 0.151N
| | | 3TC-H | 0.340N | 0.440N | 0.005N**
| | | | NVP-H | 0.393 | 0.020N*
| | | | | AZT/3TC-H | 0.008N**

a AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b The first line of a gestational day represents mean body weight ± standard error expressed in grams. The remaining lines represent P values from the pairwise comparisons, here the comparison is between the group listed in the column header and the group listed to the left. A lower body weight in a dose group is indicated by N.

FIGURE H3 Pup Body Weights to Postnatal Day 10 for Mouse Pups in the In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison

Pup Body Weights to Postnatal Day 10 for Mouse Pups in the In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison

FIGURE H4 Pup Body Weights to Postnatal Day 10 for Mouse Pups in the In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison

Pup Body Weights to Postnatal Day 10 for Mouse Pups in the In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison