# APPENDIX G LITTER EFFECTS ON SURVIVAL, BODY WEIGHT, AND PATHOLOGY

## Background

The study design consisted of eight dose groups which were compared in two evaluations: (1) the combination dose comparison compared the vehicle control group to the different dose level group of the AZT/3TC/NVP-L, AZT/3TC/NVP-M, and AZT/3TC/NVP-H groups; and (2) the high dose comparison compared the vehicle control group with the AZT-H, 3TC-H, NVP-H, AZT/3TC-H and AZT/3TC/NVP-H groups. There were 25 heterozygous F1 p53^+/−^ mice per sex initially assigned to each dose group.

Female C3H/HeNTac wild-type mice were mated with male homozygous, p53-null C57BL/6(N12)Trp53^(−/−)^ mice in order to produce heterozygous F1 p53^+/−^ offspring. Each male was mated consecutively with up to eight females. The pregnant females were randomized to the treatment groups and their heterozygous F1 p53^+/−^ pups were bred into the study. The mice were dosed by gavage. The pregnant females were dosed daily from gestational day (GD) 12 through GD 18. On postnatal day (PND) 1, heterozygous F1 p53^+/−^ mice were culled to six pups (three males and three females, where possible) and postnatal dosing was initiated. The pups were dosed with half the adult dose in half the dosing volume until PND 10, then the full adult volume and dose until PND 28. In addition, the NVP component of the dose was further reduced fourfold for doses administered on PNDs 1 to 3 because of neonatal toxicity considerations. A full description of the doses is given in Table 1 of the main Materials and Methods section of this Report.

The heterozygous F1 p53^+/−^ mice were weaned on PND 21 and assigned to either stay on study or to be culled on PND 28 for genotoxicity evaluation (see Appendix B). Either one or two mice of each sex from the same litter were assigned to each study. The litter and sire assignments of all pups in the study are shown in Tables G1 and G2. The primary experimental unit in this study was the heterozygous F1 p53^+/−^ pup. However, because the male C57BL/6(N12)Trp53^(−/−)^ mice used in these studies sired multiple litters and more than one pup per litter was loaded into the studies, two potential clustering factors existed: common litter origin and common sire. While all pups within a litter received the same treatment (i.e., litter implies treatment group), pups from the same sire were not restricted to the same litter (i.e. sire does not imply treatment group).

Additional analyses were performed as outlined below to determine whether these clustering factors had any significant influence on the outcomes of the survival, body weight, and pathology evaluations.

## Methods

### Survival

A proportional hazards model (Cox, 1972) was run by Sex and Group using Days-On-Study, the censor flag, and AZT dose level as the predictor. For this study, a linear trend estimate was formed using contrasts.

The proportional hazards assumption was checked using the method of Lin et al. (1993). The litter or sire effect clustering was adjusted for by using the aggregated sandwich estimate of variance (Lin and Wei, 1989; Binder, 1992). Ties were handled by Efron’s (1977) method.

All tests of interest were single degree-of-freedom tests and were transformed into Estimate ± Standard Error and given a Z-score testing against zero and a single-sided P value following the NTP convention of appending an “N” for negative dose effects.

The combination dose comparison compared the vehicle control group to the different dose level group of the AZT/3TC/NVP-L, AZT/3TC/NVP-M, and AZT/3TC/NVP-H groups and the high dose comparison compared the vehicle control group with the AZT-H, 3TC-H, NVP-H, AZT/3TC-H, and AZT/3TC/NVP-H groups.

### Body Weight

The basic body weight analysis typically consisted of a repeated-measures mixed model predicting body weight based on a fixed treatment group effect and age (Appendix D). This study required the addition of a random litter effect to account for correlation among littermates. Furthermore, since the correlation can be negative within litters, the mixed model should specify the litter effect in the “R” matrix rather than the “Z” matrix. In this study, pups share the dam and so littermates (implicitly dam-mates) are one possible correlation. However, multiple litters can share a common sire and so sire-mates are another possible correlation. Therefore, three correlation models were run: unadjusted (assumes pup independence), litter-adjusted (assumes correlation among dam/littermates but independence among litters), and sire-adjusted (assumes pups from different sires are independent). The combination of the heteroscedastic variance over time coupled with the litter correlation makes a repeated-measures model difficult. Therefore, since the time course is not really of great concern, a basic mixed model was run by time point. Dunnett’s adjustment was used to compare to vehicle controls.

The combination dose comparison compared the vehicle control group to the different dose level group of the AZT/3TC/NVP-L, AZT/3TC/NVP-M, and AZT/3TC/NVP-H dose groups. The levels were referred to as low, medium, and high since the levels of all components in the combination were raised proportionally. Combined with vehicle, this formed a standard control+3 design and is referred to below as the Dose Level sub-design or the Trio Dose Level sub-design. The high dose comparison compared the vehicle control group with the AZT-H, 3TC-H, NVP-H, AZT/3TC-H, and AZT/3TC/NVP-H dose groups.

The body weight data for each animal were rasterized to evenly-spaced time points (every week) via LOESS (Locally Weighted Scatterplot Smoothing) scoring (Cleveland, 1979; Cleveland et al., 1988). This process reduces the number of time points for the mixed-effects model, reduces the effects of outliers, and creates a grid of regularly spaced time points. The scored data were then treated as primary data for the mixed effects model in order to correct for possible correlation among littermates and this study was long enough to demonstrate variance heterogeneity over time. Therefore, a choice was necessary because of the difficulty in simultaneously adjusting for litters and for variance heterogeneity. The analysis opted to keep litter adjustments and to estimate the model at each time point. These models were run separately for each sex. The model treated body weight as a function of treatment group. Observations within each litter (dam- or sire-determined) were presumed to be correlated at a given time point. Since separate analyses were performed at each time point, the variance was allowed to change.

In order to better summarize the results, a two-stage analysis was also conducted for each Sex × Study Duration combination on two aspects of the growth curve: early growth rate (slope between 2 to 5 weeks for all studies) and late growth rate (slope between 38 to 44 weeks for 45-week studies). These analyses determined whether there was any treatment-related effects on early growth or late growth.

Dunnett’s (1955) method was used to compare dose levels to control within each drug combination at each age. A polynomial contrast was used to test for linear trend with dose at each age. Contrasts were used to compare drug combinations within dose levels at each age.

### Pathology

For neopla stic lesions, the Poly-k method of Bailer and Portier (1988) as modified by Bieler and Williams (1993) and NIEHS (continuity-correction) was used to analyze age-adjusted incidences. Bieler and Williams (1993), in the derivation of their variance correction, used the fact that the Cochran-Armitage test can be envisioned as a binomial-weighted regression. If we begin with a weighted regression paradigm with binomial weights, we can generalize this framework and view the Cochran-Armitage test as a generalized linear model with binomial variation and an identity link function. If this analysis is performed with the Poly-k weights, then the resulting analysis can be used with more complex designs, including litter correlations and factorial effects as well as alternative link functions.

Correlation among littermates (litter-adjusted) was achieved by using the generalized linear model described above with estimation using generalized estimating equations (Liang and Zeger, 1986) and an exchangeable correlation among littermates. Sire-adjusted analyses were generated in the same manner differing only in the specification of the correlation group variable.

It should be noted that the implementation details of this method are different from the Bieler and Williams variance-adjusted Poly-k test (Bieler and Williams, 1993). Particularly, the variance is not quantal-adjusted and all comparisons are estimated within a single analysis of variance model rather than multiple regression models. Suitable contrasts were used to test the relevant hypotheses. One-sided results were generated and, per NTP custom, an “N” was suffixed to indicate negative trends. Since the variance structure is group specific, rather than estimated from the null hypothesis, uniform treatment groups were dealt with by adding an uncorrelated dummy lesion observation to all groups (if necessary for any group) with value=0.005 and Poly-3 weight=0.005.

The presented results include the usual unadjusted Bieler-and-Williams quantal-adjusted Poly-3, Poly-3 weighted binomial/identity-link GLIM with litter-adjusted GEE correlation, and Poly-3 weighted binomial/identity-link GLIM with sire-adjusted GEE correlation.

For nonneoplastic lesions, the Poly-k method was used with k=3 to analyze age-adjusted incidence and the non-zero severity score averages were computed. The cluster-adjusted model was used here, also. In addition, to incorporate lesion severity scores, the distribution-free (but unadjusted for age) method of Jonckheere (1954) and Terpstra (1952) was used to compute monotonic trend tests, and the method of Shirley (1977) as modified by Williams (1986) was used to compute comparisons to controls. No attempt was made to adjust JT/SW for correlation among clusters.

## Results

### Survival

There are mildly significant negative results when comparing the low and medium doses of AZT/3TC/NVP to the vehicle control group in males. In females, the unadjusted standard analysis indicates no significant differences but the use of the empirical variance probably understates the variability due to the uniform vehicle group and finds significant positive results when comparing all dose levels to the vehicle control group. As above, a single event would destroy the significance. Cluster analysis for either litter or sire effects did not alter the empirical variance or its significance (Table G3). Likewise, cluster analysis for either litter or sire effects did not alter the empirical variance or its significance for the high dose comparison.

### Body Weight

The unadjusted body weight Tables are shown in Appendix D. The two adjusted analyses were generally identical to the unadjusted analysis.

### Pathology

The following results refer to the litter-adjusted analysis unless otherwise stated. The only nonsystemic neoplasm found within male subjects in sufficient quantity to justify analysis was liver hepatocellular adenoma. Hepatocellular carcinomas were also found in males (although in insufficient numbers to justify its own analysis). Therefore, the hepatocellular adenoma or carcinoma pool was also analyzed. The only neoplastic lesion found within female subjects in sufficient quantity to justify analysis was malignant lymphoma, a systemic lesion.

#### Neoplasms

Major neoplasms occurring in individual heterozygous F1 p53^+/−^ mice in the study (hepatocellular tumors in males and lymphomas and sarcomas in females) are listed in Tables G1 and G2. In both males and females, incidences of lesions did not appear to cluster with common litters or common sires. Conversely, there was some evidence that lesions were negatively associated with common litters or sires, which resulted in increased statistical significance when common litter or common sire was used as a covariant in the Poly-3 evaluations of incidences. For example, the incidence of hepatocellular adenoma was increased in the male AZT/3TC/NVP-L group relative to the vehicle control group with a Poly-3 significance that increased from 0.03 to 0.005 or <0.001 when the evaluation was adjusted for dam or sire, respectively (Table G4). In males, adjusting for dam resulted in significant differences in the incidences of malignant lymphoma between the 3TC-H (0/25) and NVP-H (0/26) dose groups and the AZT-H (3/24) and AZT/3TC-H (3/25) dose groups. These differences did not reach statistical significance in the naive evaluation (Table G5).

The male AZT/3TC/NVP-H dose group provides an example where the negative association of hepatic lesions with common litters can be easily visualized. In this group, there are 12 mice out of 24 that expressed a liver lesion (hepatocellular adenoma, hepatocellular carcinoma, or foci) and 12 that did not. Half the mice (12) were derived as pairs from six litters, whereas the other 12 mice represented individual litters. The lesions were distributed between the two groups so that five lesions were expressed in the six pairs of mice that were derived from common litters. A totally neutral effect of litter clustering would predict that the liver lesions would be distributed evenly across the litters so that there would be a similar number of litters with both pups expressing either a lesion or no lesion, and those where one pup expressed a liver lesion and the other did not. Clustering would produce a greater proportion of litters exhibiting either a lesion present in both pups or absence of lesions from both pups. However, as shown in Table G1, five of six litters had only one of the two pups exhibiting a liver lesion and one litter has neither pup exhibiting a lesion.

A similar negative association of hepatic lesions with common sire is also apparent in the AZT/3TC/NVP-H group where only one sire contributed to more than one litter. Of the three F1 p53^+/−^ mice sharing this common sire, two exhibited a liver lesion and one did not.

In females, where only low rates of neoplasm incidences were observed, adjusting for litter or sire in the combination dose comparison did not change the statistical significance of the incidences of any neoplastic lesion in any dose group relative to the vehicle controls (Table G6), but the incidence of mammary gland adenocarcinoma did become significantly greater in the 3TC-H group (3/25) than those in the AZT-H (0/25) and NVP-H (0/23) groups when adjusted for litter (Table G7).

#### Nonneoplastic Lesions

In general, exposure to the AZT/3TC/NVP drug combinations or their high dose components significantly changed the incidence or severity of several nonneoplastic endpoints, when analyzed by naive Poly-3 tests not adjusting for litter or sire correlation. Because in most cases nonneoplastic lesions were not clustered in litters, adjusting for either litter or sire increased the number of significant lesions.

For the drug combinations in males, these changes included incidences of hepatic basophilic foci and inflammation, adrenal hypoplasia, nasal hyaline droplets, and renal hydronephrosis, where adjusting for litter or sire clustering produced statistically significant (P<0.05) increases in individual dose comparisons or in dose trends that had not reached statistical significance in the evaluation that did not adjust for litter or sire clustering effects; and incidences of bone marrow hyperplasia, pancreatic hyperplasia, and thymic atrophy, where adjusting for litter or sire clustering produced statistically significant (P<0.05) decreases in individual dose comparisons or in dose trends that had not reached statistical significance in the evaluation that did not adjust for litter or sire clustering effects (Table G8). Similar changes in statistical significance were observed in the high dose comparison evaluations (Table G9).

For the drug combinations in females, these changes included hepatic centrilobular degeneration and cellular infiltration, pancreatic cellular infiltration, infiltration of hemopoietic cells into the spleen, and renal hydronephrosis, where adjusting for litter or sire clustering produced statistically significant (P<0.05) increases in individual dose comparisons or in dose trends that had not reached statistical significance in the evaluation that did not adjust for litter or sire clustering effects; incidences of cellular infiltration of the salivary glands, where adjusting for litter or sire clustering produced statistically significant (P<0.05) decreases in individual dose comparisons or in dose trends that had not reached statistical significance in the evaluation that did not adjust for litter or sire clustering effects; and incidences of nasal hyaline droplets and cellular infiltration of the lung, where adjusting for litter or sire clustering eliminated statistically significant (P<0.05) increases in individual dose comparisons or in dose trends that were observed in the evaluation that did not adjust for litter or sire clustering effects (Table G10). Similar changes in statistical significance were observed in the high dose comparison evaluations (Table G11).

## Conclusions

The use of common sires and more than one pup per litter to populate dose groups did not confound the sensitivity of these studies to detect neoplastic lesions. There appeared to be a slightly negative rather than positive correlation between littermates and pathological endpoints. This suggests that in these mice, which are derived from inbred parent strains, the epigenetic effects of intrauterine position override genetic differences between litters.

TABLE G1 Distribution of Male Heterozygous F1 p53^+/−^ Mouse Pups in the 45-Week In Utero/Postnatal Gavage Studies of AZT, 3TC, and NVP

Treatment^a^ | F1 Mouse UIN^b^ | Dam UIN | Sire UIN^c^ | Litter UIN | Lesion^d^ | CID^e^
Vehicle control
| 7G000002304 | 7F000000444 | 7E000000057 | 7G000002303 | | 138
| 7G000002303 | 7F000000444 | 7E000000057 | 7G000002303 | | 86
| 7G000002025 | 7F000000369 | 7E000000060 | 7G000002022 | | 6
| 7G000002024 | 7F000000369 | 7E000000060 | 7G000002022 | | 28
| 7G000002050 | 7F000000382 | 7E000000061 | 7G000002048 | | 51
| 7G000002168 | 7F000000401 | 7E000000062 | 7G000002162 | | 74
| 7G000002082 | 7F000000389 | 7E000000065 | 7G000002079 | | 12
| 7G000002084 | 7F000000389 | 7E000000065 | 7G000002079 | | 52
| 7G000002417 | 7F000000434 | 7E000000067 | 7G000002413 | | 189
| 7G000002418 | 7F000000434 | 7E000000067 | 7G000002413 | | 190
| 7G000002349 | 7F000000455 | 7E000000068 | 7G000002349 | | 172
| 7G000002227 | 7F000000381 | 7E000000070 | 7G000002226 | | 97
| 7G000002228 | 7F000000381 | 7E000000070 | 7G000002226 | | 43
| 7G000002909 | 7F000000529 | 7E000000072 | 7G000002906 | | 340
| 7G000002474 | 7F000000428 | 7E000000075 | 7G000002471 | | 208
| 7G000002475 | 7F000000428 | 7E000000075 | 7G000002471 | | 209
| 7G000002551 | 7F000000467 | 7E000000076 | 7G000002550 | | 239
| 7G000003077 | 7F000000546 | 7E000000078 | 7G000003074 | | 350
| 7G000003415 | 7F000000495 | 7E000000079 | 7G000003413 | | 382
| 7G000003401 | 7F000000592 | 7E000000081 | 7G000003400 | | 360
| 7G000002869 | 7F000000446 | 7E000000082 | 7G000002865 | | 307
| 7G000002870 | 7F000000446 | 7E000000082 | 7G000002865 | L | 297
| 7G000002786 | 7F000000486 | 7E000000082 | 7G000002780 | | 308
| 7G000003068 | 7F000000555 | 7E000000083 | 7G000003066 | | 351
| 7G000003493 | 7F000000585 | 7E000000087 | 7G000003485 | | 401
Mice per group | 25 | | | Number with lesions | 1 | =4.0%
AZT-H
| 7G000002186 | 7F000000417 | 7E000000057 | 7G000002185 | | 10
| 7G000002187 | 7F000000417 | 7E000000057 | 7G000002185 | | 102
| 7G000001986 | 7F000000367 | 7E000000058 | 7G000001983 | L | 33
| 7G000001987 | 7F000000367 | 7E000000058 | 7G000001983 | | 34
| 7G000002319 | 7F000000422 | 7E000000060 | 7G000002318 | | 154
| 7G000002318 | 7F000000422 | 7E000000060 | 7G000002318 | | 153
| 7G000002492 | 7F000000380 | 7E000000061 | 7G000002488 | | 206
| 7G000002032 | 7F000000385 | 7E000000063 | 7G000002028 | | 16
| 7G000002091 | 7F000000371 | 7E000000066 | 7G000002088 | | 60
| 7G000002090 | 7F000000371 | 7E000000066 | 7G000002088 | L | 59
| 7G000002777 | 7F000000516 | 7E000000068 | 7G000002773 | | 198
| 7G000002423 | 7F000000427 | 7E000000069 | 7G000002422 | | 184
| 7G000002424 | 7F000000427 | 7E000000069 | 7G000002422 | | 188
| 7G000002571 | 7F000000497 | 7E000000071 | 7G000002569 | | 237
| 7G000002239 | 7F000000405 | 7E000000072 | 7G000002233 | L | 104
| 7G000002238 | 7F000000405 | 7E000000072 | 7G000002233 | | 103
| 7G000002808 | 7F000000521 | 7E000000074 | 7G000002806 | L | 303
| 7G000002482 | 7F000000458 | 7E000000076 | 7G000002480 | | 88
| 7G000003501 | 7F000000562 | 7E000000080 | 7G000003495 | | 221
| 7G000002946 | 7F000000475 | 7E000000082 | 7G000002944 | L | 345
| 7G000002932 | 7F000000484 | 7E000000083 | 7G000002925 | L | 329
| 7G000003006 | 7F000000522 | 7E000000085 | 7G000003004 | L | 344
| 7G000003353 | 7F000000599 | 7E000000086 | 7G000003348 | L | 363
| 7G000003362 | 7F000000574 | 7E000000093 | 7G000003357 | | 26
Mice per group | 24 | | | Number with lesions | 8 | =33.3%
3TC-H
| 7G000002451 | 7F000000462 | 7E000000057 | 7G000002451 | | 199
| 7G000002452 | 7F000000462 | 7E000000057 | 7G000002451 | | 200
| 7G000002764 | 7F000000395 | 7E000000058 | 7G000002763 | | 275
| 7G000002763 | 7F000000395 | 7E000000058 | 7G000002763 | L | 274
| 7G000002098 | 7F000000370 | 7E000000059 | 7G000002096 | | 8
| 7G000002099 | 7F000000370 | 7E000000059 | 7G000002096 | | 71
| 7G000001991 | 7F000000402 | 7E000000063 | 7G000001991 | | 24
| 7G000002671 | 7F000000503 | 7E000000066 | 7G000002669 | L | 262
| 7G000002670 | 7F000000503 | 7E000000066 | 7G000002669 | | 261
| 7G000002264 | 7F000000368 | 7E000000067 | 7G000002260 | | 92
| 7G000002263 | 7F000000368 | 7E000000067 | 7G000002260 | | 91
| 7G000002655 | 7F000000505 | 7E000000068 | 7G000002653 | | 260
| 7G000002654 | 7F000000505 | 7E000000068 | 7G000002653 | | 259
| 7G000002193 | 7F000000379 | 7E000000071 | 7G000002191 | L | 90
| 7G000002374 | 7F000000421 | 7E000000075 | 7G000002370 | | 163
| 7G000002373 | 7F000000421 | 7E000000075 | 7G000002370 | | 162
| 7G000002894 | 7F000000498 | 7E000000079 | 7G000002891 | L | 333
| 7G000002939 | 7F000000452 | 7E000000081 | 7G000002936 | | 335
| 7G000002938 | 7F000000452 | 7E000000081 | 7G000002936 | | 334
| 7G000002948 | 7F000000404 | 7E000000082 | 7G000002948 | | 332
| 7G000003549 | 7F000000564 | 7E000000086 | 7G000003545 | | 355
| 7G000003548 | 7F000000564 | 7E000000086 | 7G000003545 | | 406
| 7G000003449 | 7F000000583 | 7E000000087 | 7G000003447 | | 396
| 7G000003423 | 7F000000577 | 7E000000089 | 7G000003421 | | 395
| 7G000003372 | 7F000000578 | 7E000000095 | 7G000003366 | | 377
Mice per group | 25 | | | Number with lesions | 4 | =16.0%
NVP-H
| 7G000002323 | 7F000000420 | 7E000000059 | 7G000002323 | | 157
| 7G000002829 | 7F000000514 | 7E000000060 | 7G000002823 | | 310
| 7G000002179 | 7F000000425 | 7E000000061 | 7G000002179 | L | 107
| 7G000002180 | 7F000000425 | 7E000000061 | 7G000002179 | L | 108
| 7G000002733 | 7F000000453 | 7E000000062 | 7G000002729 | | 277
| 7G000002732 | 7F000000453 | 7E000000062 | 7G000002729 | | 276
| 7G000002114 | 7F000000376 | 7E000000063 | 7G000002110 | | 80
| 7G000002115 | 7F000000376 | 7E000000063 | 7G000002110 | | 15
| 7G000001997 | 7F000000373 | 7E000000064 | 7G000001996 | | 36
| 7G000002039 | 7F000000413 | 7E000000065 | 7G000002034 | | 64
| 7G000002038 | 7F000000413 | 7E000000065 | 7G000002034 | L | 63
| 7G000002390 | 7F000000435 | 7E000000067 | 7G000002388 | | 173
| 7G000002391 | 7F000000435 | 7E000000067 | 7G000002388 | | 174
| 7G000002875 | 7F000000515 | 7E000000068 | 7G000002874 | | 21
| 7G000002645 | 7F000000511 | 7E000000071 | 7G000002643 | | 263
| 7G000002295 | 7F000000441 | 7E000000072 | 7G000002294 | | 142
| 7G000002747 | 7F000000509 | 7E000000073 | 7G000002747 | | 2
| 7G000002439 | 7F000000451 | 7E000000075 | 7G000002434 | | 213
| 7G000002438 | 7F000000451 | 7E000000075 | 7G000002434 | | 212
| 7G000002196 | 7F000000388 | 7E000000076 | 7G000002196 | | 109
| 7G000002197 | 7F000000388 | 7E000000076 | 7G000002196 | | 19
| 7G000003408 | 7F000000551 | 7E000000083 | 7G000003406 | | 387
| 7G000003409 | 7F000000551 | 7E000000083 | 7G000003406 | | 388
| 7G000002795 | 7F000000478 | 7E000000085 | 7G000002788 | | 309
| 7G000003337 | 7F000000561 | 7E000000088 | 7G000003335 | | 370
| 7G000003338 | 7F000000561 | 7E000000088 | 7G000003335 | | 371
Mice per group | 26 | | | Number with lesions | 3 | =11.5%
AZT/3TC-H
| 7G000002204 | 7F000000416 | 7E000000057 | 7G000002201 | | 134
| 7G000002205 | 7F000000416 | 7E000000057 | 7G000002201 | | 135
| 7G000002682 | 7F000000501 | 7E000000060 | 7G000002682 | | 265
| 7G000002683 | 7F000000501 | 7E000000060 | 7G000002682 | L | 266
| 7G000002269 | 7F000000424 | 7E000000061 | 7G000002267 | | 149
| 7G000002270 | 7F000000424 | 7E000000061 | 7G000002267 | | 150
| 7G000002834 | 7F000000525 | 7E000000062 | 7G000002831 | L | 318
| 7G000002005 | 7F000000374 | 7E000000065 | 7G000002001 | | 42
| 7G000002004 | 7F000000374 | 7E000000065 | 7G000002001 | L | 41
| 7G000002055 | 7F000000390 | 7E000000066 | 7G000002055 | L | 68
| 7G000002802 | 7F000000517 | 7E000000067 | 7G000002799 | | 11
| 7G000002335 | 7F000000415 | 7E000000068 | 7G000002335 | L | 151
| 7G000002336 | 7F000000415 | 7E000000068 | 7G000002335 | | 152
| 7G000002758 | 7F000000400 | 7E000000069 | 7G000002758 | L | 271
| 7G000002382 | 7F000000412 | 7E000000070 | 7G000002379 | L | 177
| 7G000002383 | 7F000000412 | 7E000000070 | 7G000002379 | | 178
| 7G000002701 | 7F000000480 | 7E000000075 | 7G000002699 | L | 281
| 7G000002700 | 7F000000480 | 7E000000075 | 7G000002699 | L | 280
| 7G000002744 | 7F000000496 | 7E000000075 | 7G000002738 | | 282
| 7G000003057 | 7F000000553 | 7E000000082 | 7G000003052 | | 354
| 7G000002915 | 7F000000460 | 7E000000085 | 7G000002913 | L | 69
| 7G000003329 | 7F000000567 | 7E000000089 | 7G000003326 | | 85
| 7G000003330 | 7F000000567 | 7E000000089 | 7G000003326 | L | 379
| 7G000003481 | 7F000000597 | 7E000000092 | 7G000003475 | | 380
| 7G000003470 | 7F000000575 | 7E000000095 | 7G000003467 | | 397
Mice per group | 25 | | | Number with lesions | 11 | =44.0%
AZT/3TC/NVP-L
| 7G000002010 | 7F000000366 | 7E000000057 | 7G000002008 | L | 30
| 7G000002011 | 7F000000366 | 7E000000057 | 7G000002008 | | 31
| 7G000002820 | 7F000000526 | 7E000000057 | 7G000002814 | | 311
| 7G000002841 | 7F000000513 | 7E000000058 | 7G000002837 | | 313
| 7G000002840 | 7F000000513 | 7E000000058 | 7G000002837 | | 312
| 7G000002396 | 7F000000457 | 7E000000059 | 7G000002396 | | 191
| 7G000002397 | 7F000000457 | 7E000000059 | 7G000002396 | L | 192
| 7G000002300 | 7F000000449 | 7E000000060 | 7G000002297 | L | 139
| 7G000002299 | 7F000000449 | 7E000000060 | 7G000002297 | | 50
| 7G000002067 | 7F000000407 | 7E000000062 | 7G000002062 | | 57
| 7G000002213 | 7F000000429 | 7E000000064 | 7G000002209 | | 99
| 7G000002212 | 7F000000429 | 7E000000064 | 7G000002209 | | 98
| 7G000002129 | 7F000000408 | 7E000000066 | 7G000002127 | L | 78
| 7G000002128 | 7F000000408 | 7E000000066 | 7G000002127 | | 77
| 7G000002466 | 7F000000440 | 7E000000069 | 7G000002461 | | 216
| 7G000002465 | 7F000000440 | 7E000000069 | 7G000002461 | | 215
| 7G000002581 | 7F000000499 | 7E000000075 | 7G000002579 | L | 247
| 7G000002580 | 7F000000499 | 7E000000075 | 7G000002579 | | 222
| 7G000002966 | 7F000000500 | 7E000000079 | 7G000002963 | L | 336
| 7G000003015 | 7F000000539 | 7E000000082 | 7G000003012 | L | 337
| 7G000003048 | 7F000000558 | 7E000000084 | 7G000003044 | L | 353
| 7G000003460 | 7F000000540 | 7E000000088 | 7G000003455 | | 391
| 7G000003343 | 7F000000570 | 7E000000090 | 7G000003341 | | 375
| 7G000003344 | 7F000000570 | 7E000000090 | 7G000003341 | L | 376
| 7G000003392 | 7F000000573 | 7E000000093 | 7G000003387 | | 374
Mice per group | 25 | | | Number with lesions | 9 | =36.0%
AZT/3TC/NVP-M
| 7G000002147 | 7F000000397 | 7E000000059 | 7G000002143 | L | 83
| 7G000002148 | 7F000000397 | 7E000000059 | 7G000002143 | | 84
| 7G000002280 | 7F000000423 | 7E000000060 | 7G000002278 | | 130
| 7G000002281 | 7F000000423 | 7E000000060 | 7G000002278 | L | 131
| 7G000002694 | 7F000000450 | 7E000000062 | 7G000002688 | | 288
| 7G000002693 | 7F000000450 | 7E000000062 | 7G000002688 | L | 287
| 7G000002314 | 7F000000431 | 7E000000065 | 7G000002314 | | 146
| 7G000002248 | 7F000000432 | 7E000000066 | 7G000002243 | L | 127
| 7G000002247 | 7F000000432 | 7E000000066 | 7G000002243 | | 126
| 7G000002604 | 7F000000488 | 7E000000068 | 7G000002604 | | 249
| 7G000002501 | 7F000000410 | 7E000000069 | 7G000002497 | L | 218
| 7G000002500 | 7F000000410 | 7E000000069 | 7G000002497 | L | 205
| 7G000002537 | 7F000000465 | 7E000000070 | 7G000002537 | | 233
| 7G000002538 | 7F000000465 | 7E000000070 | 7G000002537 | L | 234
| 7G000002409 | 7F000000459 | 7E000000071 | 7G000002408 | | 194
| 7G000002408 | 7F000000459 | 7E000000071 | 7G000002408 | | 193
| 7G000002254 | 7F000000409 | 7E000000073 | 7G000002252 | | 128
| 7G000002255 | 7F000000409 | 7E000000073 | 7G000002252 | L | 129
| 7G000002999 | 7F000000538 | 7E000000079 | 7G000002996 | | 347
| 7G000002857 | 7F000000375 | 7E000000080 | 7G000002855 | | 320
| 7G000002856 | 7F000000375 | 7E000000080 | 7G000002855 | | 300
| 7G000003431 | 7F000000584 | 7E000000087 | 7G000003431 | L | 385
| 7G000003463 | 7F000000590 | 7E000000096 | 7G000003463 | L | 386
Mice per group | 23 | | | Number with lesions | 10 | =43.5%
AZT/3TC/NVP-H
| 7G000002344 | 7F000000384 | 7E000000057 | 7G000002342 | L | 168
| 7G000002343 | 7F000000384 | 7E000000057 | 7G000002342 | | 167
| 7G000002273 | 7F000000419 | 7E000000058 | 7G000002273 | | 114
| 7G000002521 | 7F000000483 | 7E000000060 | 7G000002521 | | 223
| 7G000002403 | 7F000000443 | 7E000000061 | 7G000002402 | | 187
| 7G000002402 | 7F000000443 | 7E000000061 | 7G000002402 | L | 186
| 7G000002564 | 7F000000477 | 7E000000062 | 7G000002562 | | 243
| 7G000002565 | 7F000000477 | 7E000000062 | 7G000002562 | L | 244
| 7G000002526 | 7F000000476 | 7E000000063 | 7G000002524 | L | 232
| 7G000002073 | 7F000000414 | 7E000000066 | 7G000002071 | L | 66
| 7G000002577 | 7F000000481 | 7E000000066 | 7G000002576 | L | 246
| 7G000002576 | 7F000000481 | 7E000000066 | 7G000002576 | | 245
| 7G000002220 | 7F000000399 | 7E000000068 | 7G000002218 | | 115
| 7G000002221 | 7F000000399 | 7E000000068 | 7G000002218 | L | 116
| 7G000002888 | 7F000000520 | 7E000000069 | 7G000002887 | L | 319
| 7G000002310 | 7F000000445 | 7E000000071 | 7G000002308 | L | 144
| 7G000002557 | 7F000000494 | 7E000000073 | 7G000002556 | | 4
| 7G000002556 | 7F000000494 | 7E000000073 | 7G000002556 | | 242
| 7G000002518 | 7F000000490 | 7E000000074 | 7G000002517 | | 220
| 7G000002534 | 7F000000468 | 7E000000076 | 7G000002531 | L | 231
| 7G000002921 | 7F000000528 | 7E000000077 | 7G000002918 | | 346
| 7G000003525 | 7F000000589 | 7E000000085 | 7G000003521 | L | 405
| 7G000003308 | 7F000000571 | 7E000000092 | 7G000003307 | | 367
| 7G000003557 | 7F000000600 | 7E000000093 | 7G000003553 | L | 407
Mice per group | 24 | | | Number with lesions | 12 | =50.0%

a AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; AZT/3TC/NVP-M = 160/100/112 mg/kg AZT/3TC/NVP; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b UIN = unique identification number

c Adjacent cells within a column with the same shading share the same sire or litter.

d L = hepatocellular adenoma, hepatocellular carcinoma or basophilic foci

e CDD = carcass identification number for pathological evaluation

TABLE G2 Distribution of Female Heterozygous F1 p53^+/−^ Mouse Pups in the 45-Week In Utero/Postnatal Gavage Studies of AZT, 3TC, and NVP

Treatment^a^ | F1 Mouse UIN^b^ | Dam UIN | Sire UIN^c^ | Litter UIN | Lesion^d^ | CID^e^
Vehicle control
| 7G000002306 | 7F000000444 | 7E000000057 | 7G000002303 | Ma | 155
| 7G000002307 | 7F000000444 | 7E000000057 | 7G000002303 | | 156
| 7G000002027 | 7F000000369 | 7E000000060 | 7G000002022 | | 29
| 7G000002054 | 7F000000382 | 7E000000061 | 7G000002048 | | 54
| 7G000002053 | 7F000000382 | 7E000000061 | 7G000002048 | | 53
| 7G000002169 | 7F000000401 | 7E000000062 | 7G000002162 | | 75
| 7G000002170 | 7F000000401 | 7E000000062 | 7G000002162 | | 76
| 7G000002086 | 7F000000389 | 7E000000065 | 7G000002079 | | 55
| 7G000002087 | 7F000000389 | 7E000000065 | 7G000002079 | L | 56
| 7G000002354 | 7F000000455 | 7E000000068 | 7G000002349 | | 166
| 7G000002360 | 7F000000426 | 7E000000069 | 7G000002355 | | 171
| 7G000002232 | 7F000000381 | 7E000000070 | 7G000002226 | | 137
| 7G000002231 | 7F000000381 | 7E000000070 | 7G000002226 | | 136
| 7G000002911 | 7F000000529 | 7E000000072 | 7G000002906 | | 341
| 7G000002477 | 7F000000428 | 7E000000075 | 7G000002471 | | 207
| 7G000002552 | 7F000000467 | 7E000000076 | 7G000002550 | | 238
| 7G000002994 | 7F000000532 | 7E000000077 | 7G000002988 | | 342
| 7G000002995 | 7F000000532 | 7E000000077 | 7G000002988 | | 343
| 7G000003537 | 7F000000591 | 7E000000078 | 7G000003528 | | 402
| 7G000002873 | 7F000000446 | 7E000000082 | 7G000002865 | | 306
| 7G000002872 | 7F000000446 | 7E000000082 | 7G000002865 | L | 305
| 7G000002787 | 7F000000486 | 7E000000082 | 7G000002780 | | 304
| 7G000003539 | 7F000000595 | 7E000000090 | 7G000003538 | | 403
| 7G000003297 | 7F000000586 | 7E000000091 | 7G000003293 | | 362
| 7G000003281 | 7F000000580 | 7E000000096 | 7G000003278 | | 361
Mice per group | 25 | | | Number with lesions | 3 | =12.0%
AZT-H
| 7G000002190 | 7F000000417 | 7E000000057 | 7G000002185 | | 105
| 7G000001988 | 7F000000367 | 7E000000058 | 7G000001983 | Mc | 22
| 7G000001989 | 7F000000367 | 7E000000058 | 7G000001983 | | 35
| 7G000002494 | 7F000000380 | 7E000000061 | 7G000002488 | | 202
| 7G000002495 | 7F000000380 | 7E000000061 | 7G000002488 | L | 158
| 7G000002640 | 7F000000487 | 7E000000062 | 7G000002637 | | 257
| 7G000002642 | 7F000000487 | 7E000000062 | 7G000002637 | | 254
| 7G000002093 | 7F000000371 | 7E000000066 | 7G000002088 | | 61
| 7G000002094 | 7F000000371 | 7E000000066 | 7G000002088 | | 62
| 7G000002426 | 7F000000427 | 7E000000069 | 7G000002422 | | 185
| 7G000002573 | 7F000000497 | 7E000000071 | 7G000002569 | | 227
| 7G000002572 | 7F000000497 | 7E000000071 | 7G000002569 | L | 159
| 7G000002242 | 7F000000405 | 7E000000072 | 7G000002233 | | 106
| 7G000002813 | 7F000000521 | 7E000000074 | 7G000002806 | | 301
| 7G000002486 | 7F000000458 | 7E000000076 | 7G000002480 | | 203
| 7G000002487 | 7F000000458 | 7E000000076 | 7G000002480 | | 201
| 7G000002853 | 7F000000461 | 7E000000079 | 7G000002845 | | 302
| 7G000003502 | 7F000000562 | 7E000000080 | 7G000003495 | | 404
| 7G000002947 | 7F000000475 | 7E000000082 | 7G000002944 | | 299
| 7G000002934 | 7F000000484 | 7E000000083 | 7G000002925 | | 327
| 7G000003011 | 7F000000522 | 7E000000085 | 7G000003004 | | 328
| 7G000003351 | 7F000000599 | 7E000000086 | 7G000003348 | | 364
| 7G000003288 | 7F000000563 | 7E000000087 | 7G000003283 | | 356
| 7G000003361 | 7F000000574 | 7E000000093 | 7G000003357 | | 365
| 7G000003565 | 7F000000541 | 7E000000094 | 7G000003561 | | 399
Mice per group | 25 | | | Number with lesions | 3 | =12.0%
3TC-H
| 7G000002765 | 7F000000395 | 7E000000058 | 7G000002763 | | 252
| 7G000002102 | 7F000000370 | 7E000000059 | 7G000002096 | Ma | 72
| 7G000002103 | 7F000000370 | 7E000000059 | 7G000002096 | | 73
| 7G000002430 | 7F000000430 | 7E000000062 | 7G000002428 | | 211
| 7G000002429 | 7F000000430 | 7E000000062 | 7G000002428 | | 210
| 7G000001995 | 7F000000402 | 7E000000063 | 7G000001991 | | 27
| 7G000001994 | 7F000000402 | 7E000000063 | 7G000001991 | | 25
| 7G000002674 | 7F000000503 | 7E000000066 | 7G000002669 | | 256
| 7G000002675 | 7F000000503 | 7E000000066 | 7G000002669 | | 258
| 7G000002265 | 7F000000368 | 7E000000067 | 7G000002260 | | 95
| 7G000002266 | 7F000000368 | 7E000000067 | 7G000002260 | | 96
| 7G000002657 | 7F000000505 | 7E000000068 | 7G000002653 | Ma | 255
| 7G000002658 | 7F000000505 | 7E000000068 | 7G000002653 | Mc | 160
| 7G000002194 | 7F000000379 | 7E000000071 | 7G000002191 | | 93
| 7G000002195 | 7F000000379 | 7E000000071 | 7G000002191 | | 94
| 7G000002377 | 7F000000421 | 7E000000075 | 7G000002370 | | 165
| 7G000002376 | 7F000000421 | 7E000000075 | 7G000002370 | | 164
| 7G000002895 | 7F000000498 | 7E000000079 | 7G000002891 | | 331
| 7G000002941 | 7F000000452 | 7E000000081 | 7G000002936 | Ma | 269
| 7G000002953 | 7F000000404 | 7E000000082 | 7G000002948 | | 294
| 7G000003552 | 7F000000564 | 7E000000086 | 7G000003545 | L | 357
| 7G000003454 | 7F000000583 | 7E000000087 | 7G000003447 | | 392
| 7G000003424 | 7F000000577 | 7E000000089 | 7G000003421 | | 393
| 7G000003425 | 7F000000577 | 7E000000089 | 7G000003421 | | 394
| 7G000003370 | 7F000000578 | 7E000000095 | 7G000003366 | | 359
Mice per group | 25 | | | Number with lesions | 5 | =20.0%
NVP-H
| 7G000002706 | 7F000000447 | 7E000000057 | 7G000002705 | | 278
| 7G000002707 | 7F000000447 | 7E000000057 | 7G000002705 | | 279
| 7G000002326 | 7F000000420 | 7E000000059 | 7G000002323 | S | 23
| 7G000002327 | 7F000000420 | 7E000000059 | 7G000002323 | | 70
| 7G000002830 | 7F000000514 | 7E000000060 | 7G000002823 | | 295
| 7G000002184 | 7F000000425 | 7E000000061 | 7G000002179 | | 111
| 7G000002183 | 7F000000425 | 7E000000061 | 7G000002179 | | 110
| 7G000002737 | 7F000000453 | 7E000000062 | 7G000002729 | | 291
| 7G000002118 | 7F000000376 | 7E000000063 | 7G000002110 | | 81
| 7G000001999 | 7F000000373 | 7E000000064 | 7G000001996 | | 37
| 7G000002000 | 7F000000373 | 7E000000064 | 7G000001996 | Lu | 17
| 7G000002042 | 7F000000413 | 7E000000065 | 7G000002034 | L | 65
| 7G000002447 | 7F000000391 | 7E000000066 | 7G000002443 | L | 204
| 7G000002448 | 7F000000391 | 7E000000066 | 7G000002443 | L | 44
| 7G000002394 | 7F000000435 | 7E000000067 | 7G000002388 | | 175
| 7G000002395 | 7F000000435 | 7E000000067 | 7G000002388 | | 176
| 7G000002647 | 7F000000511 | 7E000000071 | 7G000002643 | | 264
| 7G000002296 | 7F000000441 | 7E000000072 | 7G000002294 | | 143
| 7G000002752 | 7F000000509 | 7E000000073 | 7G000002747 | | 293
| 7G000002751 | 7F000000509 | 7E000000073 | 7G000002747 | L | 292
| 7G000002440 | 7F000000451 | 7E000000075 | 7G000002434 | L | 214
| 7G000002200 | 7F000000388 | 7E000000076 | 7G000002196 | | 113
| 7G000002199 | 7F000000388 | 7E000000076 | 7G000002196 | | 112
| 7G000003339 | 7F000000561 | 7E000000088 | 7G000003335 | | 368
| 7G000003340 | 7F000000561 | 7E000000088 | 7G000003335 | | 369
Mice per group | 25 | | | Number with lesions | 7 | =28.0%
AZT/3TC-H
| 7G000002206 | 7F000000416 | 7E000000057 | 7G000002201 | | 132
| 7G000002207 | 7F000000416 | 7E000000057 | 7G000002201 | Ma | 133
| 7G000002687 | 7F000000501 | 7E000000060 | 7G000002682 | | 268
| 7G000002272 | 7F000000424 | 7E000000061 | 7G000002267 | | 148
| 7G000002271 | 7F000000424 | 7E000000061 | 7G000002267 | S | 147
| 7G000002007 | 7F000000374 | 7E000000065 | 7G000002001 | | 40
| 7G000002059 | 7F000000390 | 7E000000066 | 7G000002055 | L | 18
| 7G000002060 | 7F000000390 | 7E000000066 | 7G000002055 | | 67
| 7G000002804 | 7F000000517 | 7E000000067 | 7G000002799 | | 321
| 7G000002339 | 7F000000415 | 7E000000068 | 7G000002335 | L | 3
| 7G000002340 | 7F000000415 | 7E000000068 | 7G000002335 | Ma | 49
| 7G000002762 | 7F000000400 | 7E000000069 | 7G000002758 | | 286
| 7G000002761 | 7F000000400 | 7E000000069 | 7G000002758 | | 285
| 7G000002386 | 7F000000412 | 7E000000070 | 7G000002379 | | 179
| 7G000002387 | 7F000000412 | 7E000000070 | 7G000002379 | | 180
| 7G000002666 | 7F000000512 | 7E000000071 | 7G000002659 | | 267
| 7G000002703 | 7F000000480 | 7E000000075 | 7G000002699 | | 283
| 7G000002704 | 7F000000480 | 7E000000075 | 7G000002699 | | 284
| 7G000002746 | 7F000000496 | 7E000000075 | 7G000002738 | L | 9
| 7G000002745 | 7F000000496 | 7E000000075 | 7G000002738 | L | 161
| 7G000002652 | 7F000000489 | 7E000000076 | 7G000002649 | | 253
| 7G000002917 | 7F000000460 | 7E000000085 | 7G000002913 | | 348
| 7G000003570 | 7F000000508 | 7E000000087 | 7G000003567 | | 410
| 7G000003333 | 7F000000567 | 7E000000089 | 7G000003326 | | 378
Mice per group | 24 | | | Number with lesions | 7 | =29.2%
AZT/3TC/NVP-L
| 7G000002012 | 7F000000366 | 7E000000057 | 7G000002008 | | 32
| 7G000002822 | 7F000000526 | 7E000000057 | 7G000002814 | | 315
| 7G000002821 | 7F000000526 | 7E000000057 | 7G000002814 | | 314
| 7G000002843 | 7F000000513 | 7E000000058 | 7G000002837 | | 316
| 7G000002844 | 7F000000513 | 7E000000058 | 7G000002837 | | 317
| 7G000002399 | 7F000000457 | 7E000000059 | 7G000002396 | | 183
| 7G000002398 | 7F000000457 | 7E000000059 | 7G000002396 | | 182
| 7G000002301 | 7F000000449 | 7E000000060 | 7G000002297 | | 140
| 7G000002302 | 7F000000449 | 7E000000060 | 7G000002297 | | 141
| 7G000002070 | 7F000000407 | 7E000000062 | 7G000002062 | L | 7
| 7G000002069 | 7F000000407 | 7E000000062 | 7G000002062 | | 58
| 7G000002216 | 7F000000429 | 7E000000064 | 7G000002209 | | 100
| 7G000002217 | 7F000000429 | 7E000000064 | 7G000002209 | | 101
| 7G000002132 | 7F000000408 | 7E000000066 | 7G000002127 | | 79
| 7G000002470 | 7F000000440 | 7E000000069 | 7G000002461 | | 217
| 7G000002469 | 7F000000440 | 7E000000069 | 7G000002461 | | 45
| 7G000002585 | 7F000000499 | 7E000000075 | 7G000002579 | | 248
| 7G000002584 | 7F000000499 | 7E000000075 | 7G000002579 | L | 181
| 7G000002971 | 7F000000500 | 7E000000079 | 7G000002963 | | 339
| 7G000003016 | 7F000000539 | 7E000000082 | 7G000003012 | | 338
| 7G000003050 | 7F000000558 | 7E000000084 | 7G000003044 | | 352
| 7G000003461 | 7F000000540 | 7E000000088 | 7G000003455 | | 389
| 7G000003462 | 7F000000540 | 7E000000088 | 7G000003455 | | 390
| 7G000003345 | 7F000000570 | 7E000000090 | 7G000003341 | | 372
| 7G000003346 | 7F000000570 | 7E000000090 | 7G000003341 | | 373
Mice per group | 25 | | | Number with lesions | 2 | =8.0%
AZT/3TC/NVP-M
| 7G000002014 | 7F000000394 | 7E000000058 | 7G000002013 | S | 38
| 7G000002015 | 7F000000394 | 7E000000058 | 7G000002013 | L | 39
| 7G000002150 | 7F000000397 | 7E000000059 | 7G000002143 | L | 20
| 7G000002151 | 7F000000397 | 7E000000059 | 7G000002143 | | 82
| 7G000002259 | 7F000000409 | 7E000000073 | 7G000002252 | | 123
| 7G000002257 | 7F000000409 | 7E000000073 | 7G000002252 | | 122
| 7G000002505 | 7F000000410 | 7E000000069 | 7G000002497 | L | 5
| 7G000002504 | 7F000000410 | 7E000000069 | 7G000002497 | | 219
| 7G000002285 | 7F000000423 | 7E000000060 | 7G000002278 | | 125
| 7G000002284 | 7F000000423 | 7E000000060 | 7G000002278 | | 124
| 7G000002251 | 7F000000432 | 7E000000066 | 7G000002243 | | 121
| 7G000002250 | 7F000000432 | 7E000000066 | 7G000002243 | | 120
| 7G000002698 | 7F000000450 | 7E000000062 | 7G000002688 | | 290
| 7G000002697 | 7F000000450 | 7E000000062 | 7G000002688 | | 289
| 7G000002412 | 7F000000459 | 7E000000071 | 7G000002408 | | 195
| 7G000002540 | 7F000000465 | 7E000000070 | 7G000002537 | | 235
| 7G000002541 | 7F000000465 | 7E000000070 | 7G000002537 | | 236
| 7G000002606 | 7F000000488 | 7E000000068 | 7G000002604 | | 251
| 7G000002605 | 7F000000488 | 7E000000068 | 7G000002604 | | 250
| 7G000003435 | 7F000000584 | 7E000000087 | 7G000003431 | | 383
| 7G000003465 | 7F000000590 | 7E000000096 | 7G000003463 | L | 87
| 7G000003466 | 7F000000590 | 7E000000096 | 7G000003463 | | 384
Mice per group | 22 | | | Vumber with lesions | 5 | =22.7%
AZT/3TC/NVP-H
| 7G000002347 | 7F000000384 | 7E000000057 | 7G000002342 | | 169
| 7G000002348 | 7F000000384 | 7E000000057 | 7G000002342 | | 170
| 7G000002277 | 7F000000419 | 7E000000058 | 7G000002273 | | 119
| 7G000002523 | 7F000000483 | 7E000000060 | 7G000002521 | L | 225
| 7G000002522 | 7F000000483 | 7E000000060 | 7G000002521 | | 224
| 7G000002406 | 7F000000443 | 7E000000061 | 7G000002402 | | 196
| 7G000002407 | 7F000000443 | 7E000000061 | 7G000002402 | | 197
| 7G000002529 | 7F000000476 | 7E000000063 | 7G000002524 | L | 230
| 7G000002528 | 7F000000476 | 7E000000063 | 7G000002524 | | 229
| 7G000002578 | 7F000000481 | 7E000000066 | 7G000002576 | | 240
| 7G000002224 | 7F000000399 | 7E000000068 | 7G000002218 | | 117
| 7G000002225 | 7F000000399 | 7E000000068 | 7G000002218 | | 118
| 7G000002633 | 7F000000466 | 7E000000070 | 7G000002629 | | 241
| 7G000002312 | 7F000000445 | 7E000000071 | 7G000002308 | | 145
| 7G000002757 | 7F000000463 | 7E000000072 | 7G000002753 | | 273
| 7G000002756 | 7F000000463 | 7E000000072 | 7G000002753 | | 272
| 7G000002520 | 7F000000490 | 7E000000074 | 7G000002517 | | 228
| 7G000002548 | 7F000000473 | 7E000000075 | 7G000002543 | S | 89
| 7G000002547 | 7F000000473 | 7E000000075 | 7G000002543 | | 226
| 7G000002924 | 7F000000528 | 7E000000077 | 7G000002918 | | 330
| 7G000003519 | 7F000000587 | 7E000000080 | 7G000003513 | L,Mc | 381
| 7G000003316 | 7F000000593 | 7E000000082 | 7G000003313 | | 366
| 7G000003309 | 7F000000571 | 7E000000092 | 7G000003307 | L | 298
| 7G000003310 | 7F000000571 | 7E000000092 | 7G000003307 | | 358
| 7G000003573 | 7F000000566 | 7E000000095 | 7G000003571 | | 400
Mice per group | 25 | | | Number with lesions | 5 | =20.0%

a AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; AZT/3TC/NVP-M = 160/100/112 mg/kg AZT/3TC/NVP; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b UIN = unique identification number

c Adjacent cells within a column with the same shading share the same sire or litter.

d L = malignant lymphoma, Lu = granulocytic leukemia,, Ma = mammary gland adenocarcinoma, Me = mammary gland adenoacanthoma, S = histocytic sarcoma

e CID = carcass identification number for pathological evaluation

TABLE G3 Effects of Combination Doses on the Survival of Heterozygous p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Studies of AZT, 3TC, and NVP^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Male
Linear trend | −2.1 | — | — | —
Relative hazard^b^ | — | 16% | 16% | 49%
Unadjusted standard | 0.206N | 0.043N^*^ | 0.047N^*^ | 0.157N
Unadjusted empirical | 0.203N | 0.041N^*^ | 0.039N^*^ | 0.158N
Litter-adjusted empirical | 0.185N | 0.034N^*^ | 0.032N^*^ | 0.135N
Sire-adjusted empirical | 0.201N | 0.023N^*^ | 0.035N^*^ | 0.138N
Female
Linear trend | 6.5 | — | — | —
Relative hazard | — | 675% | 776% | 820%
Unadjusted standard | 0.078 | 0.104 | 0.088 | 0.079
Unadjusted empirical | 0.030^*^ | 0.046^*^ | 0.037^*^ | 0.030^*^
Litter-adjusted empirical | 0.036^*^ | 0.037^*^ | 0.032^*^ | 0.035^*^
Sire-adjusted empirical | 0.033^*^ | 0.040^*^ | 0.033^*^ | 0.033^*^

* P≤0.05

a P values are presented unadjusted for litter clusters using the standard model-based variance estimate, unadjusted for litter clusters using the empirical variance estimate, litter-adjusted where the empirical variance is aggregated over litters, and sire-adjusted where the empirical variance is aggregated over sires. Significant negative trends or changes in hazard comparisons are appended with N.

b The relative hazard represents the treatment group hazard relative to vehicle controls. Vehicle control group results represent linear dose trend in the hazards and not the relative hazard estimate, which is implicitly 100% for this group.

TABLE G4 Litter-adjusted Statistical Analysis of Primary Neoplasms in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Bone: Osteosarcoma
Overall rate^b^ | 3/25 (12.0%) | 0/25 (0.0%) | 0/23 (0.0%) | 1/24 (4.2%)
Adjusted rate^c^ | 3/23.9 (12.6%) | 0/24.8 (0.0%) | 0/22.9 (0.0%) | 1/22.9 (4.4%)
Terminal rate^d^ | 1/20 (5.0%) | 0/24 (0.0%) | 0/22 (0.0%) | 1/22 (4.5%)
First incidence (days) | 207 | —^f^ | — | 326 (T)
Poly-3 test^e^ | 0.137N | 0.107N | 0.121N | 0.319N
Litter-adjusted correlation | −0.12
Litter-adjusted Poly-3 rate | 13.3% | 0.0% | 0.0% | 4.7%
Litter-adjusted Poly-3 test | 0.129N | 0.017N* | 0.017N* | 0.129N
Sire-adjusted correlation | −0.03
Sire-adjusted Poly-3 rate | 12.7% | 0.0% | 0.0% | 4.3%
Sire-adjusted Poly-3 test | 0.133N | 0.019N* | 0.019N* | 0.132N
Liver: Hepatocellular Adenoma
Overall rate | 1/25 (4.0%) | 7/25 (28.0%) | 7/23 (30.4%) | 9/23 (39.1%)
Adjusted rate | 1/22.9 (4.4%) | 7/24.8 (28.3%) | 7/22.9 (30.5%) | 9/22.8 (39.4%)
Terminal rate | 0/20 (0.0%) | 7/24 (29.2%) | 7/22 (31.8%) | 9/22 (40.9%)
First incidence (days) | 313 | 315 (T) | 318 (T) | 316 (T)
Poly-3 test | 0.006** | 0.030* | 0.021* | 0.003**
Litter-adjusted correlation | −0.30
Litter-adjusted Poly-3 rate | 5.1% | 28.1% | 29.9% | 36.4%
Litter-adjusted Poly-3 test | 0.003 ** | 0.005 ** | 0.004 ** | 0.002 **
Sire-adjusted correlation | 0.02
Sire-adjusted Poly-3 rate | 4.3% | 28.1% | 30.6% | 39.7%
Sire-adjusted Poly-3 test | 0.001** | <0.001 *** | 0.002 ** | <0.001 ***
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 1/25 (4.0%) | 9/25 (36.0%) | 8/23 (34.8%) | 10/23 (43.5%)
Adjusted rate | 1/22.9 (4.4%) | 9/24.8 (36.4%) | 8/22.9 (34.9%) | 10/22.8 (43.8%)
Terminal rate | 0/20 (0.0%) | 9/24 (37.5%) | 8/22 (36.4%) | 10/22 (45.5%)
First incidence (days) | 313 | 315 (T) | 318 (T) | 316 (T)
Poly-3 test | 0.004** | 0.006** | 0.009** | 0.001**
Litter-adjusted correlation | −0.25
Litter-adjusted Poly-3 rate | 5.0% | 35.7% | 34.6% | 42.0%
Litter-adjusted Poly-3 test | <0.001*** | <0.001*** | 0.004** | <0.001***
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 4.5% | 36.5% | 34.8% | 43.6%
Sire-adjusted Poly-3 test | 0.001** | <0.001*** | 0.002** | <0.001***
Lung: Alveolar/Bronchiolar Adenoma
Overall rate | 0/25 (0.0%) | 0/25 (0.0%) | 2/23 (8.7%) | 0/23 (0.0%)
Adjusted rate | 0/22.8 (0.0%) | 0/24.8 (0.0%) | 2/22.9 (8.7%) | 0/22.8 (0.0%)
Terminal rate | 0/20 (0.0%) | 0/24 (0.0%) | 2/22 (9.1%) | 0/22 (0.0%)
First incidence (days) | — | — | 318 (T) | —
Poly-3 test | 0.379 | —^g^ | 0.236 | —
Litter-adjusted correlation | −0.05
Litter-adjusted Poly-3 rate | 0.0% | 0.0% | 8.8% | 0.0%
Litter-adjusted Poly-3 test | 0.057 | — | 0.057 | —
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 0.0% | 0.0% | 8.8% | 0.0%
Sire-adjusted Poly-3 test | 0.058 | — | 0.058 | —
All Organs: Lymphoma Malignant
Overall rate | 1/25 (4.0%) | 0/25 (0.0%) | 1/23 (4.3%) | 2/24 (8.3%)
Adjusted rate | 1/23.6 (4.2%) | 0/24.8 (0.0%) | 1/22.9 (4.4%) | 2/23.0 (8.7%)
Terminal rate | 0/20 (0.0%) | 0/24 (0.0%) | 1/22 (4.5%) | 1/22 (4.5%)
First incidence (days) | 176 | — | 325 (T) | 307
Poly-3 test | 0.238 | 0.491N | 0.754 | 0.491
Litter-adjusted correlation | −0.08
Litter-adjusted Poly-3 rate | 4.4% | 0.0% | 4.5% | 8.7%
Litter-adjusted Poly-3 test | 0.210 | 0.144N | 0.497 | 0.270
Sire-adjusted correlation | −0.06
Sire-adjusted Poly-3 rate | 4.0% | 0.0% | 5.0% | 9.2%
Sire-adjusted Poly-3 test | 0.166 | 0.165N | 0.433 | 0.231
All Organs: Malignant Neoplasms
Overall rate | 7/25 (28.0%) | 4/25 (16.0%) | 5/23 (21.7%) | 4/24 (16.7%)
Adjusted rate | 7/25.0 (28.0%) | 4/25.0 (16.0%) | 5/23.0 (21.7%) | 4/23.0 (17.4%)
Terminal rate | 2/20 (10.0%) | 3/24 (12.5%) | 4/22 (18.2%) | 3/22 (13.6%)
First incidence (days) | 176 | 297 | 318 (T) | 307
Poly-3 test | 0.278N | 0.249N | 0.435N | 0.300N
Litter-adjusted correlation | −0.47
Litter-adjusted Poly-3 rate | 32.9% | 14.1% | 24.2% | 20.6%
Litter-adjusted Poly-3 test | 0.195N | 0.020N* | 0.186N | 0.107N
Sire-adjusted correlation | −0.14
Sire-adjusted Poly-3 rate | 33.7% | 20.3% | 28.6% | 23.2%
Sire-adjusted Poly-3 test | 0.245N | 0.056N | 0.291N | 0.159N
All Organs: Osteosarcoma
Overall rate | 3/25 (12.0%) | 0/25 (0.0%) | 0/23 (0.0%) | 1/24 (4.2%)
Adjusted rate | 3/23.9 (12.6%) | 0/24.8 (0.0%) | 0/22.9 (0.0%) | 1/22.9 (4.4%)
Terminal rate | 1/20 (5.0%) | 0/24 (0.0%) | 0/22 (0.0%) | 1/22 (4.5%)
First incidence (days) | 207 | — | — | 326 (T)
Poly-3 test | 0.137N | 0.107N | 0.121N | 0.319N
Litter-adjusted correlation | −0.12
Litter-adjusted Poly-3 rate | 13.3% | 0.0% | 0.0% | 4.7%
Litter-adjusted Poly-3 test | 0.129N | 0.017N* | 0.017N* | 0.129N
Sire-adjusted correlation | −0.03
Sire-adjusted Poly-3 rate | 12.7% | 0.0% | 0.0% | 4.3%
Sire-adjusted Poly-3 test | 0.133N | 0.019N* | 0.019N* | 0.132N
All Organs: Benign Neoplasms
Overall rate | 1/25 (4.0%) | 7/25 (28.0%) | 11/23 (47.8%) | 10/24 (41.7%)
Adjusted rate | 1/22.9 (4.4%) | 7/24.8 (28.3%) | 11/23.0 (47.8%) | 10/22.9 (43.8%)
Terminal rate | 0/20 (0.0%) | 7/24 (29.2%) | 10/22 (45.5%) | 10/22 (45.5%)
First incidence (days) | 313 | 315 (T) | 318 (T) | 316 (T)
Poly-3 test | <0.001*** | 0.030* | <0.001*** | 0.001***
Litter-adjusted correlation | −0.18
Litter-adjusted Poly-3 rate | 4.8% | 28.2% | 48.1% | 41.5%
Litter-adjusted Poly-3 test | <0.001*** | 0.004** | <0.001*** | <0.001***
Sire-adjusted correlation | 0.05
Sire-adjusted Poly-3 rate | 4.2% | 27.7% | 47.7% | 44.4%
Sire-adjusted Poly-3 test | <0.001*** | <0.001*** | <0.001*** | <0.001***
All Organs: Benign or Malignant Neoplasms
Overall rate | 7/25 (28.0%) | 11/25 (44.0%) | 13/23 (56.5%) | 14/24 (58.3%)
Adjusted rate | 7/25.0 (28.0%) | 11/25.0 (44.0%) | 13/23.0 (56.5%) | 14/23.0 (60.8%)
Terminal rate | 2/20 (10.0%) | 10/24 (41.7%) | 12/22 (54.5%) | 13/22 (59.1%)
First incidence (days) | 176 | 297 | 318 (T) | 307
Poly-3 test | 0.009** | 0.190 | 0.040* | 0.019*
Litter-adjusted correlation | −0.49
Litter-adjusted Poly-3 rate | 33.1% | 41.9% | 58.5% | 56.8%
Litter-adjusted Poly-3 test | 0.010* | 0.218 | 0.003** | 0.024*
Sire-adjusted correlation | −0.02
Sire-adjusted Poly-3 rate | 28.3% | 44.4% | 57.3% | 61.0%
Sire-adjusted Poly-3 test | 0.003** | 0.074 | <0.001*** | 0.003**

(T) Terminal kill

a AZT/3TC/NVP-L = 80/50/56 mg/kg; AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg

b Number of neoplasm-bearing animals/number of animals with tissue examined microscopically.

c Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

d Observed incidence at terminal kill

e Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

f Not applicable; no neoplasms in animal group

g Value of statistic cannot be computed.

TABLE G5 Litter-adjusted Statistical Analysis of Primary Neoplasms in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
Bone: Osteosarcoma
Overall rate^b^ | 3/25 (12.0%) | 0/24 (0.0%) | 1/25 (4.0%) | 1/26 (3.8%) | 0/25 (0.0%) | 1/24 (4.2%)
Adjusted rate^c^ | 3/23.9 (12.6%) | 0/19.9 (0.0%) | 1/23.6 (4.2%) | 1/22.9 (4.4%) | 0/22.2 (0.0%) | 1/22.9 (4.4%)
Terminal rate^d^ | 1/20 (5.0%) | 0/18 (0.0%) | 1/23 (4.3%) | 1/22 (4.5%) | 0/21 (0.0%) | 1/22 (4.5%)
First incidence (days) | 207 | —^f^ | 318 (T) | 322 (T) | — | 326 (T)
| Vehicle Control | 0.150N | 0.307N | 0.319N | 0.127N | 0.319N
| | AZT-H | 0.534 | 0.528 | —^g^ | 0.528
Poly-3 test^e^ | | | 3TC-H | 0.753 | 0.512N | 0.753
| | | | NVP-H | 0.506N | 0.761
| | | | | AZT/3TC-H | 0.506
Litter-adjusted correlation | 0.10
Litter-adjusted Poly-3 rate | 13.2% | 0.0% | 3.9% | 4.5% | 0.0% | 4.7%
| Vehicle Control | 0.017N* | 0.104N | 0.124N | 0.017N* | 0.129N
| | AZT-H | 0.158 | 0.145 | — | 0.143
Litter-adjusted Poly-3 test | | | 3TC-H | 0.461 | 0.158N | 0.452
| | | | NVP-H | 0.145N | 0.492
| | | | | AZT/3TC-H | 0.143
Sire-adjusted correlation | —^g^
Sire-adjusted Poly-3 rate | — | — | — | — | — | —
| Vehicle Control | — | — | — | — | —
| | AZT-H | — | — | — | —
Sire-adjusted Poly-3 test | | | 3TC-H | — | — | —
| | | | NVP-H | — | —
| | | | | AZT/3TC-H | —
Liver: Hepatocellular Adenoma
Overall rate | 1/25 (4.0%) | 8/23 (34.8%) | 3/25 (12.0%) | 2/25 (8.0%) | 9/25 (36.0%) | 9/23 (39.1%)
Adjusted rate | 1/22.9 (4.4%) | 8/19.9 (40.2%) | 3/23.6 (12.7%) | 2/22.4 (8.9%) | 9/22.2 (40.5%) | 9/22.8 (39.4%)
Terminal rate | 0/20 (0.0%) | 8/18 (44.4%) | 3/23 (13.0%) | 2/22 (9.1%) | 9/21 (42.9%) | 9/22 (40.9%)
First incidence (days) | 313 | 316 (T) | 318 (T) | 322 (T) | 316 (T) | 316 (T)
| Vehicle Control | 0.004** | 0.313 | 0.493 | 0.003** | 0.003**
| | AZT-H | 0.038N* | 0.017N* | 0.615 | 0.601N
Poly-3 test | | | 3TC-H | 0.524N | 0.031* | 0.036*
| | | | NVP-H | 0.014* | 0.016*
| | | | | AZT/3TC-H | 0.589N
Litter-adjusted correlation | 0.23
Litter-adjusted Poly-3 rate | 3.9% | 41.6% | 13.6% | 8.3% | 40.3% | 41.1%
| Vehicle Control | <0.001*** | 0.118 | 0.307 | <0.001*** | <0.001***
| | AZT-H | 0.013N* | 0.005N** | 0.464N | 0.488N
Litter-adjusted Poly-3 test | | | 3TC-H | 0.309N | 0.015* | 0.015*
| | | | NVP-H | 0.006** | 0.006**
| | | | | AZT/3TC-H | 0.476
Sire-adjusted correlation | 0.05
Sire-adjusted Poly-3 rate | 4.0% | 41.5% | 12.3% | 8.3% | 38.6% | 38.6%
| Vehicle Control | <0.001*** | 0.154 | 0.324 | <0.001*** | 0.001**
| | AZT-H | 0.009N** | 0.009N** | 0.410N | 0.420N
Sire-adjusted Poly-3 test | | | 3TC-H | 0.355N | 0.008** | 0.016*
| | | | NVP-H | 0.014* | 0.020*
| | | | | AZT/3TC-H | 0.499
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 1/25 (4.0%) | 8/23 (34.8%) | 3/25 (12.0%) | 2/25 (8.0%) | 10/25 (40.0%) | 10/23 (43.5%)
Adjusted rate | 1/22.9 (4.4%) | 8/19.9 (40.2%) | 3/23.6 (12.7%) | 2/22.4 (8.9%) | 10/22.2 (45.0%) | 10/22.8 (43.8%)
Terminal rate | 0/20 (0.0%) | 8/18 (44.4%) | 3/23 (13.0%) | 2/22 (9.1%) | 10/21 (47.6%) | 10/22 (45.5%)
First incidence (days) | 313 | 316 (T) | 318 (T) | 322 (T) | 316 (T) | 316 (T)
| Vehicle Control | 0.004** | 0.313 | 0.493 | <0.001*** | 0.001**
| | AZT-H | 0.038N* | 0.017N* | 0.499 | 0.529
Poly-3 test | | | 3TC-H | 0.524N | 0.014* | 0.017*
| | | | NVP-H | 0.006** | 0.007**
| | | | | AZT/3TC-H | 0.585N
Litter-adjusted correlation | 0.19
Litter-adjusted Poly-3 rate | 4.0% | 41.3% | 13.5% | 8.4% | 45.3% | 44.8%
| Vehicle Control | <0.001*** | 0.122 | 0.309 | <0.001*** | <0.001***
| | AZT-H | 0.013N* | 0.005N** | 0.390 | 0.404
Litter-adjusted Poly-3 test | | | 3TC-H | 0.319N | 0.005** | 0.005**
| | | | NVP-H | 0.002** | 0.002**
| | | | | AZT/3TC-H | 0.486N
Sire-adjusted correlation | −0.04
Sire-adjusted Poly-3 rate | 4.1% | 41.1% | 12.1% | 8.7% | 43.5% | 43.5%
| Vehicle Control | <0.001*** | 0.160 | 0.313 | <0.001*** | <0.001***
| | AZT-H | 0.009N** | 0.011N* | 0.427 | 0.436
Sire-adjusted Poly-3 test | | | 3TC-H | 0.377N | 0.002** | 0.004**
| | | | NVP-H | 0.008** | 0.002**
| | | | | AZT/3TC-H | 0.500N
Lung: Alveolar/Bronchiolar Adenoma or Carcinoma
Overall rate | 0/25 (0.0%) | 1/24 (4.2%) | 2/25 (8.0%) | 1/25 (4.0%) | 0/24 (0.0%) | 0/23 (0.0%)
Adjusted rate | 0/22.8 (0.0%) | 1/19.9 (5.0%) | 2/24.2 (8.3%) | 1/22.4 (4.5%) | 0/21.4 (0.0%) | 0/22.8 (0.0%)
Terminal rate | 0/20 (0.0%) | 1/18 (5.6%) | 1/23 (4.3%) | 1/22 (4.5%) | 0/21 (0.0%) | 0/22 (0.0%)
First incidence (days) | — | 319 (T) | 250 | 320 (T) | — | —
| Vehicle Control | 0.473 | 0.248 | 0.497 | — | —
| | AZT-H | 0.568 | 0.734N | 0.486N | 0.473N
Poly-3 test | | | 3TC-H | 0.526N | 0.263N | 0.248N
| | | | NVP-H | 0.510N | 0.497N
| | | | | AZT/3TC-H | —
Litter-adjusted correlation | −0.05
Litter-adjusted Poly-3 rate | 0.0% | 4.9% | 8.4% | 4.6% | 0.0% | 0.0%
| Vehicle Control | 0.156 | 0.057 | 0.145 | — | —
| | AZT-H | 0.312 | 0.478N | 0.156N | 0.156N
Litter-adjusted Poly-3 test | | | 3TC-H | 0.286N | 0.057N | 0.057N
| | | | NVP-H | 0.145N | 0.145N
| | | | | AZT/3TC-H | —
Sire-adjusted correlation | 0.00
Sire-adjusted Poly-3 rate | 0.0% | 5.1% | 8.3% | 4.5% | 0.0% | 0.0%
| Vehicle Control | 0.155 | 0.057 | 0.145 | — | —
| | AZT-H | 0.326 | 0.464N | 0.155N | 0.155N
Sire-adjusted Poly-3 test | | | 3TC-H | 0.282N | 0.057N | 0.057N
| | | | NVP-H | 0.145N | 0.145N
| | | | | AZT/3TC-H | —
All Organs: Lymphoma Malignant
Overall rate | 1/25 (4.0%) | 3/24 (12.5%) | 0/25 (0.0%) | 0/26 (0.0%) | 3/25 (12.0%) | 2/24 (8.3%)
Adjusted rate | 1/23.6 (4.2%) | 3/22.1 (13.6%) | 0/23.6 (0.0%) | 0/22.9 (0.0%) | 3/24.8 (12.1%) | 2/23.0 (8.7%)
Terminal rate | 0/20 (0.0%) | 0/18 (0.0%) | 0/23 (0.0%) | 0/22 (0.0%) | 0/21 (0.0%) | 1/22 (4.5%)
First incidence (days) | 176 | 168 | — | — | 99 | 307
| Vehicle Control | 0.277 | 0.500N | 0.507N | 0.321 | 0.491
| | AZT-H | 0.101N | 0.106N | 0.609N | 0.480N
Poly-3 test | | | 3TC-H | — | 0.123 | 0.229
| | | | NVP-H | 0.130 | 0.236
| | | | | AZT/3TC-H | 0.535N
Litter-adjusted correlation | −0.04
Litter-adjusted Poly-3 rate | 4.3% | 13.5% | 0.0% | 0.0% | 11.9% | 8.7%
| Vehicle Control | 0.133 | 0.144N | 0.144N | 0.160 | 0.266
| | AZT-H | 0.030N* | 0.030N* | 0.436N | 0.302N
Litter-adjusted Poly-3 test | | | 3TC-H | — | 0.032* | 0.064
| | | | NVP-H | 0.032* | 0.064
| | | | | AZT/3TC-H | 0.355N
Sire-adjusted correlation | —
Sire-adjusted Poly-3 rate | — | — | — | — | — | —
| Vehicle Control | — | — | — | — | —
| | AZT-H | — | — | — | —
Sire-adjusted Poly-3 test | | | 3TC-H | — | — | —
| | | | NVP-H | — | —
| | | | | AZT/3TC-H | —
All Organs: Osteosarcoma
Overall rate | 3/25 (12.0%) | 1/24 (4.2%) | 2/25 (8.0%) | 1/26 (3.8%) | 0/25 (0.0%) | 1/24 (4.2%)
Adjusted rate | 3/23.9 (12.6%) | 1/19.9 (5.0%) | 2/23.6 (8.5%) | 1/22.9 (4.4%) | 0/22.2 (0.0%) | 1/22.9 (4.4%)
Terminal rate | 1/20 (5.0%) | 1/18 (5.6%) | 2/23 (8.7%) | 1/22 (4.5%) | 0/21 (0.0%) | 1/22 (4.5%)
First incidence (days) | 207 | 318 (T) | 318 (T) | 322 (T) | — | 326 (T)
| Vehicle Control | 0.371N | 0.505N | 0.319N | 0.127N | 0.319N
| | AZT-H | 0.560 | 0.730N | 0.478N | 0.729N
Poly-3 test | | | 3TC-H | 0.512N | 0.249N | 0.512N
| | | | NVP-H | 0.506N | 0.761
| | | | | AZT/3TC-H | 0.506
Litter-adjusted correlation | −0.11
Litter-adjusted Poly-3 rate | 13.3% | 4.7% | 8.3% | 4.5% | 0.0% | 4.7%
| Vehicle Control | 0.136N | 0.274N | 0.124N | 0.017N* | 0.129N
| | AZT-H | 0.310 | 0.488N | 0.157N | 0.498N
Litter-adjusted Poly-3 test | | | 3TC-H | 0.295N | 0.067N | 0.304N
| | | | NVP-H | 0.145N | 0.490
| | | | | AZT/3TC-H | 0.143
Sire-adjusted correlation | −0.04
Sire-adjusted Poly-3 rate | 12.4% | 4.6% | 8.1% | 4.6% | 0.0% | 4.6%
| Vehicle Control | 0.160N | 0.306N | 0.162N | 0.023N* | 0.150N
| | AZT-H | 0.327 | 0.499N | 0.171N | 0.496N
Sire-adjusted Poly-3 test | | | 3TC-H | 0.310N | 0.074N | 0.311N
| | | | NVP-H | 0.133N | 0.496N
| | | | | AZT/3TC-H | 0.136
All Organs: Malignant Neoplasms
Overall rate | 7/25 (28.0%) | 6/24 (25.0%) | 5/25 (20.0%) | 5/26 (19.2%) | 8/25 (32.0%) | 4/24 (16.7%)
Adjusted rate | 7/25.0 (28.0%) | 6/22.4 (26.8%) | 5/24.2 (20.7%) | 5/25.0 (20.0%) | 8/25.0 (32.0%) | 4/23.0 (17.4%)
Terminal rate | 2/20 (10.0%) | 2/18 (11.1%) | 4/23 (17.4%) | 2/22 (9.1%) | 4/21 (19.0%) | 3/22 (13.6%)
First incidence (days) | 176 | 168 | 250 | 177 | 99 | 307
| Vehicle Control | 0.590N | 0.397N | 0.372N | 0.500 | 0.300N
| | AZT-H | 0.444N | 0.419N | 0.471 | 0.344N
Poly-3 test | | | 3TC-H | 0.614N | 0.285 | 0.532N
| | | | NVP-H | 0.262 | 0.554N
| | | | | AZT/3TC-H | 0.203N
Litter-adjusted correlation | −0.32
Litter-adjusted Poly-3 rate | 31.1% | 23.0% | 19.9% | 20.6% | 28.9% | 19.4%
| Vehicle Control | 0.229N | 0.127N | 0.136N | 0.416N | 0.115N
| | AZT-H | 0.395N | 0.415N | 0.316 | 0.376N
Litter-adjusted Poly-3 test | | | 3TC-H | 0.476 | 0.213 | 0.479N
| | | | NVP-H | 0.226 | 0.454N
| | | | | AZT/3TC-H | 0.199N
Sire-adjusted correlation | −0.02
Sire-adjusted Poly-3 rate | 27.7% | 26.4% | 20.9% | 19.9% | 31.8% | 18.0%
| Vehicle Control | 0.456N | 0.237N | 0.205N | 0.360 | 0.165N
| | AZT-H | 0.311N | 0.260N | 0.336 | 0.236N
Sire-adjusted Poly-3 test | | | 3TC-H | 0.461N | 0.193 | 0.383N
| | | | NVP-H | 0.132 | 0.426N
| | | | | AZT/3TC-H | 0.078N
All Organs: Benign Neoplasms
Overall rate | 1/25 (4.0%) | 8/24 (33.3%) | 5/25 (20.0%) | 5/26 (19.2%) | 9/25 (36.0%) | 10/24 (41.7%)
Adjusted rate | 1/22.9 (4.4%) | 8/19.9 (40.2%) | 5/23.6 (21.2%) | 5/22.9 (21.9%) | 9/22.2 (40.5%) | 10/22.9 (43.8%)
Terminal rate | 0/20 (0.0%) | 8/18 (44.4%) | 5/23 (21.7%) | 5/22 (22.7%) | 9/21 (42.9%) | 10/22 (45.5%)
First incidence (days) | 313 | 316 (T) | 318 (T) | 320 (T) | 316 (T) | 316 (T)
| Vehicle Control | 0.004** | 0.099 | 0.091 | 0.003** | 0.001**
| | AZT-H | 0.150N | 0.166N | 0.615 | 0.530
Poly-3 test | | | 3TC-H | 0.615 | 0.135 | 0.089
| | | | NVP-H | 0.150 | 0.102
| | | | | AZT/3TC-H | 0.532
Litter-adjusted correlation | −0.05
Litter-adjusted Poly-3 rate | 4.5% | 39.8% | 21.1% | 22.0% | 40.6% | 43.2%
| Vehicle Control | <0.001*** | 0.029* | 0.049* | <0.001*** | <0.001***
| | AZT-H | 0.066N | 0.098N | 0.478 | 0.409
Litter-adjusted Poly-3 test | | | 3TC-H | 0.471 | 0.057 | 0.044*
| | | | NVP-H | 0.087 | 0.069
| | | | | AZT/3TC-H | 0.429
Sire-adjusted correlation | −0.07
Sire-adjusted Poly-3 rate | 4.0% | 43.6% | 19.8% | 19.6% | 36.4% | 40.7%
| Vehicle Control | <0.001*** | 0.041* | 0.071 | <0.001*** | 0.001**
| | AZT-H | 0.041N* | 0.038N* | 0.293N | 0.431N
Sire-adjusted Poly-3 test | | | 3TC-H | 0.493N | 0.096 | 0.054
| | | | NVP-H | 0.124 | 0.093
| | | | | AZT/3TC-H | 0.344
All Organs: Benign or Malignant Neoplasms
Overall rate | 7/25 (28.0%) | 12/24 (50.0%) | 9/25 (36.0%) | 9/26 (34.6%) | 17/25 (68.0%) | 14/24 (58.3%)
Adjusted rate | 7/25.0 (28.0%) | 12/22.4 (53.6%) | 9/24.2 (37.2%) | 9/25.0 (36.0%) | 17/25.0 (68.0%) | 14/23.0 (60.8%)
Terminal rate | 2/20 (10.0%) | 8/18 (44.4%) | 8/23 (34.8%) | 6/22 (27.3%) | 13/21 (61.9%) | 13/22 (59.1%)
First incidence (days) | 176 | 168 | 250 | 177 | 99 | 307
| Vehicle Control | 0.065 | 0.352 | 0.383 | 0.003** | 0.019*
| | AZT-H | 0.206N | 0.179N | 0.238 | 0.424
Poly-3 test | | | 3TC-H | 0.580N | 0.027* | 0.090
| | | | NVP-H | 0.020* | 0.074
| | | | | AZT/3TC-H | 0.415N
Litter-adjusted correlation | −0.51
Litter-adjusted Poly-3 rate | 33.4% | 46.4% | 36.5% | 37.2% | 65.8% | 56.5%
| Vehicle Control | 0.121 | 0.374 | 0.367 | <0.001*** | 0.027*
| | AZT-H | 0.194N | 0.240N | 0.043* | 0.228
Litter-adjusted Poly-3 test | | | 3TC-H | 0.474 | 0.001** | 0.053
| | | | NVP-H | 0.006** | 0.081
| | | | | AZT/3TC-H | 0.226N
Sire-adjusted correlation | −0.11
Sire-adjusted Poly-3 rate | 24.6% | 61.1% | 39.1% | 29.2% | 59.8% | 67.7%
| Vehicle Control | 0.004** | 0.054 | 0.332 | <0.001*** | 0.001**
| | AZT-H | 0.067N | 0.006N** | 0.454N | 0.352
Sire-adjusted Poly-3 test | | | 3TC-H | 0.160N | 0.024* | 0.016*
| | | | NVP-H | 0.004** | 0.003**
| | | | | AZT/3TC-H | 0.256

(T) Terminal kill

a AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b Number of neoplasm-bearing animals/number of animals with tissue examined microscopically

c Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

d Observed incidence at terminal kill

e Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between that dosed group and the group stated to the left on the same row. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in a dose group is indicated by N.

f Not applicable; no neoplasms in animal group

g Value of statistic cannot be computed.

TABLE G6 Litter-adjusted Statistical Analysis of Primary Neoplasms in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
All Organs : Malignant Lymphoma
Overall rate^b^ | 2/25 (8.0%) | 2/25 (8.0%) | 4/22 (18.2%) | 4/25 (16.0%)
Adjusted rate^c^ | 2/25.0 (8.0%) | 2/24.4 (8.2%) | 4/22.0 (18.2%) | 4/24.5 (16.3%)
Terminal rate^d^ | 2/25 (8.0%) | 0/22 (0.0%) | 1/19 (5.3%) | 2/21 (9.5%)
First incidence (days) | 316 (T) | 186 | 101 | 247
Poly-3 test^e^ | 0.156 | 0.687 | 0.274 | 0.324
Litter-adjusted correlation | −0.24
Litter-adjusted Poly-3 rate | 9.0% | 8.6% | 18.6% | 16.8%
Litter-adjusted Poly-3 test | 0.117 | 0.483N | 0.147 | 0.189
Sire-adjusted correlation | −0.11
Sire-adjusted Poly-3 rate | 7.9% | 8.1% | 17.8% | 14.3%
Sire-adjusted Poly-3 test | 0.153 | 0.488 | 0.136 | 0.233
All Organs : Benign Neoplasms
Overall rate | 1/25 (4.0%) | 0/25 (0.0%) | 2/22 (9.1%) | 4/25 (16.0%)
Adjusted rate | 1/25.0 (4.0%) | 0/23.4 (0.0%) | 2/19.7 (10.2%) | 4/24.1 (16.6%)
Terminal rate | 1/25 (4.0%) | 0/22 (0.0%) | 2/19 (10.5%) | 3/21 (14.3%)
First incidence (days) | 316 (T) | —^f^ | 318 (T) | 275
Poly-3 test | 0.036* | 0.513N | 0.417 | 0.162
Litter-adjusted correlation | 0.14
Litter-adjusted Poly-3 rate | 3.8% | 0.0% | 10.5% | 16.3%
Litter-adjusted Poly-3 test | 0.051 | 0.147N | 0.194 | 0.094
Sire-adjusted correlation | 0.02
Sire-adjusted Poly-3 rate | 3.9% | 0.0% | 10.5% | 16.8%
Sire-adjusted Poly-3 test | 0.055 | 0.153N | 0.192 | 0.098
All Organs : Malignant Neoplasms
Overall rate | 3/25 (12.0%) | 3/25 (12.0%) | 6/22 (27.3%) | 6/25 (24.0%)
Adjusted rate | 3/25.0 (12.0%) | 3/25.0 (12.0%) | 6/22.0 (27.3%) | 6/25.0 (24.0%)
Terminal rate | 3/25 (12.0%) | 0/22 (0.0%) | 3/19 (15.8%) | 2/21 (9.5%)
First incidence (days) | 316 (T) | 186 | 101 | 247
Poly-3 test | 0.092 | 0.665 | 0.170 | 0.233
Litter-adjusted correlation | −0.08
Litter-adjusted Poly-3 rate | 12.4% | 12.2% | 27.5% | 24.4%
Litter-adjusted Poly-3 test | 0.070 | 0.489N | 0.095 | 0.137
Sire-adjusted correlation | −0.05
Sire-adjusted Poly-3 rate | 11.9% | 13.2% | 26.8% | 24.2%
Sire-adjusted Poly-3 test | 0.075 | 0.446 | 0.090 | 0.138
All Organs: Benign or Malignant Neoplasms
Overall rate | 4/25 (16.0%) | 3/25 (12.0%) | 7/22 (31.8%) | 9/25 (36.0%)
Adjusted rate | 4/25.0 (16.0%) | 3/25.0 (12.0%) | 7/22.0 (31.8%) | 9/25.0 (36.0%)
Terminal rate | 4/25 (16.0%) | 0/22 (0.0%) | 4/19 (21.1%) | 5/21 (23.8%)
First incidence (days) | 316 (T) | 186 | 101 | 247
Poly-3 test | 0.023* | 0.500N | 0.176 | 0.097
Litter-adjusted correlation | 0.25
Litter-adjusted Poly-3 rate | 14.4% | 11.4% | 31.1% | 34.8%
Litter-adjusted Poly-3 test | 0.023 * | 0.379N | 0.111 | 0.056
Sire-adjusted correlation | 0.08
Sire-adjusted Poly-3 rate | 15.2% | 10.8% | 33.0% | 36.1%
Sire-adjusted Poly-3 test | 0.008** | 0.347N | 0.091 | 0.032*

(T) Terminal kill

a AZT/3TC/NVP-L = 80/50/56 mg/kg; AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg

b Number of neoplasm-bearing animals/number of animals with tissue examined microscopically

c Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

d Observed incidence at terminal kill

e Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in a dose group is indicated by N.

f Not applicable; no neoplasms in animal group

TABLE G7 Litter-adjusted Statistical Analysis of Primary Neoplasms in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
Bone: Osteosarcoma
Overall rate^b^ | 0/25 (0.0%) | 0/25 (0.0%) | 2/25 (8.0%) | 0/25 (0.0%) | 0/24 (0.0%) | 0/25 (0.0%)
Adjusted rate^c^ | 0/25.0 (0.0%) | 0/23.8 (0.0%) | 2/23.5 (8.5%) | 0/23.2 (0.0%) | 0/20.7 (0.0%) | 0/23.7 (0.0%)
Terminal rate^d^ | 0/25 (0.0%) | 0/20 (0.0%) | 1/20 (5.0%) | 0/20 (0.0%) | 0/19 (0.0%) | 0/21 (0.0%)
First incidence (days) | —^f^ | — | 297 | — | — | —
| Vehicle Control | —^g^ | 0.221 | — | — | —
| | AZT-H | 0.232 | — | — | —
Poly-3 test^e^ | | | 3TC-H | 0.237N | 0.263N | 0.232N
| | | | NVP-H | — | —
| | | | | AZT/3TC-H | —
Litter-adjusted correlation | −0.01
Litter-adjusted Poly-3 rate | 0.0% | 0.0% | 8.5% | 0.0% | 0.0% | 0.0%
| Vehicle Control | — | 0.067 | — | — | —
| | AZT-H | 0.067 | — | — | —
Litter-adjusted Poly-3 test | | | 3TC-H | 0.067N | 0.067N | 0.067N
| | | | NVP-H | — | —
| | | | | AZT/3TC-H | —
Sire-adjusted correlation | 0.00
Sire-adjusted Poly-3 rate | 0.0% | 0.0% | 8.5% | 0.0% | 0.0% | 0.0%
| Vehicle Control | — | 0.067 | — | — | —
| | AZT-H | 0.067 | — | — | —
Sire-adjusted Poly-3 test | | | 3TC-H | 0.067N | 0.067N | 0.067N
| | | | NVP-H | — | —
| | | | | AZT/3TC-H | —
Harderian Gland: Adenoma
Overall rate | 0/25 (0.0%) | 1/24 (4.2%) | 0/25 (0.0%) | 2/25 (8.0%) | 0/23 (0.0%) | 1/24 (4.2%)
Adjusted rate | 0/25.0 (0.0%) | 1/23.1 (4.3%) | 0/23.2 (0.0%) | 2/23.2 (8.6%) | 0/20.7 (0.0%) | 1/23.3 (4.3%)
Terminal rate | 0/25 (0.0%) | 1/20 (5.0%) | 0/20 (0.0%) | 2/20 (10.0%) | 0/19 (0.0%) | 1/21 (4.8%)
First incidence (days) | — | 320 (T) | — | 320 (T) | — | 318 (T)
| Vehicle Control | 0.484 | — | 0.218 | — | 0.486
| | AZT-H | 0.499N | 0.501 | 0.522N | 0.759N
Poly-3 test | | | 3TC-H | 0.234 | — | 0.501
| | | | NVP-H | 0.260N | 0.498N
| | | | | AZT/3TC-H | 0.523
Litter-adjusted correlation | 0.01
Litter-adjusted Poly-3 rate | 0.0% | 4.4% | 0.0% | 8.7% | 0.0% | 4.3%
| Vehicle Control | 0.155 | — | 0.075 | — | 0.150
| | AZT-H | 0.156N | 0.279 | 0.156N | 0.495N
Litter-adjusted Poly-3 test | | | 3TC-H | 0.075 | — | 0.150
| | | | NVP-H | 0.075N | 0.272N
| | | | | AZT/3TC-H | 0.150
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 0.0% | 4.3% | 0.0% | 8.6% | 0.0% | 4.3%
| Vehicle Control | 0.156 | — | 0.076 | — | 0.149
| | AZT-H | 0.157N | 0.281 | 0.157N | 0.500N
Sire-adjusted Poly-3 test | | | 3TC-H | 0.076 | — | 0.150
| | | | NVP-H | 0.076N | 0.287N
| | | | | AZT/3TC-H | 0.150
Mammary Gland: Adenocarcinoma
Overall rate | 1/25 (4.0%) | 0/25 (0.0%) | 3/25 (12.0%) | 0/23 (0.0%) | 2/23 (8.7%) | 0/25 (0.0%)
Adjusted rate | 1/25.0 (4.0%) | 0/23.8 (0.0%) | 3/23.6 (12.7%) | 0/21.8 (0.0%) | 2/21.1 (9.5%) | 0/23.7 (0.0%)
Terminal rate | 1/25 (4.0%) | 0/20 (0.0%) | 2/20 (10.0%) | 0/20 (0.0%) | 1/19 (5.3%) | 0/21 (0.0%)
First incidence (days) | 319 (T) | — | 277 | — | 280 | —
| Vehicle Control | 0.510N | 0.282 | 0.527N | 0.440 | 0.510N
| | AZT-H | 0.112 | — | 0.208 | —
Poly-3 test | | | 3TC-H | 0.128N | 0.553N | 0.112N
| | | | NVP-H | 0.226 | —
| | | | | AZT/3TC-H | 0.208N
Litter-adjusted correlation | −0.05
Litter-adjusted Poly-3 rate | 4.1% | 0.0% | 12.6% | 0.0% | 9.5% | 0.0%
| Vehicle Control | 0.146N | 0.134 | 0.146N | 0.231 | 0.146N
| | AZT-H | 0.028* | — | 0.063 | —
Litter-adjusted Poly-3 test | | | 3TC-H | 0.028N* | 0.365N | 0.028N*
| | | | NVP-H | 0.063 | —
| | | | | AZT/3TC-H | 0.063N
Sire-adjusted correlation | —^g^
Sire-adjusted Poly-3 rate | — | — | — | — | — | —
| Vehicle Control | — | — | — | — | —
| | AZT-H | — | — | — | —
Sire-adjusted Poly-3 test | | | 3TC-H | — | — | —
| | | | NVP-H | — | —
| | | | | AZT/3TC-H | —
Mammary Gland: Adenoacanthoma or Adenocarcinoma
Overall rate | 1/25 (4.0%) | 1/25 (4.0%) | 4/25 (16.0%) | 0/23 (0.0%) | 2/23 (8.7%) | 1/25 (4.0%)
Adjusted rate | 1/25.0 (4.0%) | 1/23.9 (4.2%) | 4/24.0 (16.6%) | 0/21.8 (0.0%) | 2/21.1 (9.5%) | 1/23.9 (4.2%)
Terminal rate | 1/25 (4.0%) | 0/20 (0.0%) | 2/20 (10.0%) | 0/20 (0.0%) | 1/19 (5.3%) | 0/21 (0.0%)
First incidence (days) | 319 (T) | 313 | 271 | — | 280 | 302
| Vehicle Control | 0.750 | 0.161 | 0.527N | 0.440 | 0.751
| | AZT-H | 0.174 | 0.518N | 0.456 | 0.760N
Poly-3 test | | | 3TC-H | 0.066N | 0.397N | 0.173N
| | | | NVP-H | 0.226 | 0.519
| | | | | AZT/3TC-H | 0.455N
Litter-adjusted correlation | 0.10
Litter-adjusted Poly-3 rate | 3.9% | 4.0% | 16.7% | 0.0% | 9.6% | 4.4%
| Vehicle Control | 0.489 | 0.095 | 0.147N | 0.215 | 0.458
| | AZT-H | 0.099 | 0.146N | 0.223 | 0.469
Litter-adjusted Poly-3 test | | | 3TC-H | 0.033N* | 0.260N | 0.112N
| | | | NVP-H | 0.064 | 0.156
| | | | | AZT/3TC-H | 0.251N
Sire-adjusted correlation | 0.10
Sire-adjusted Poly-3 rate | 4.4% | 4.3% | 17.0% | 0.1% | 10.4% | 3.5%
| Vehicle Control | 0.496N | 0.092 | 0.126N | 0.116 | 0.442N
| | AZT-H | 0.090 | 0.131N | 0.184 | 0.449N
Sire-adjusted Poly-3 test | | | 3TC-H | 0.027N* | 0.156N | 0.087N
| | | | NVP-H | 0.041* | 0.211
| | | | | AZT/3TC-H | 0.186N
All Organs: Malignant Lymphoma
Overall rate | 2/25 (8.0%) | 2/25 (8.0%) | 1/25 (4.0%) | 5/25 (20.0%) | 4/24 (16.7%) | 4/25 (16.0%)
Adjusted rate | 2/25.0 (8.0%) | 2/24.4 (8.2%) | 1/23.7 (4.2%) | 5/23.7 (21.1%) | 4/23.6 (16.9%) | 4/24.5 (16.3%)
Terminal rate | 2/25 (8.0%) | 0/20 (0.0%) | 0/20 (0.0%) | 4/20 (20.0%) | 0/19 (0.0%) | 2/21 (9.5%)
First incidence (days) | 316 (T) | 277 | 258 | 251 | 102 | 247
| Vehicle Control | 0.686 | 0.518N | 0.186 | 0.307 | 0.324
| | AZT-H | 0.509N | 0.196 | 0.319 | 0.336
Poly-3 test | | | 3TC-H | 0.092 | 0.171 | 0.182
| | | | NVP-H | 0.502N | 0.479N
| | | | | AZT/3TC-H | 0.628N
Litter-adjusted correlation | 0.09
Litter-adjusted Poly-3 rate | 7.7% | 7.8% | 4.5% | 21.3% | 16.5% | 16.2%
| Vehicle Control | 0.491 | 0.314N | 0.106 | 0.191 | 0.156
| | AZT-H | 0.308N | 0.109 | 0.196 | 0.161
Litter-adjusted Poly-3 test | | | 3TC-H | 0.058 | 0.112 | 0.075
| | | | NVP-H | 0.358N | 0.334N
| | | | | AZT/3TC-H | 0.489N
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 7.9% | 8.2% | 4.3% | 21.0% | 17.1% | 16.4%
| Vehicle Control | 0.488 | 0.289N | 0.087 | 0.167 | 0.154
| | AZT-H | 0.289N | 0.141 | 0.189 | 0.183
Sire-adjusted Poly-3 test | | | 3TC-H | 0.061 | 0.084 | 0.064
| | | | NVP-H | 0.321N | 0.356N
| | | | | AZT/3TC-H | 0.476N
All Organs: Benign Neoplasms
Overall rate | 1/25 (4.0%) | 1/25 (4.0%) | 0/25 (0.0%) | 3/25 (12.0%) | 0/24 (0.0%) | 4/25 (16.0%)
Adjusted rate | 1/25.0 (4.0%) | 1/23.8 (4.2%) | 0/23.2 (0.0%) | 3/23.2 (13.0%) | 0/20.7 (0.0%) | 4/24.1 (16.6%)
Terminal rate | 1/25 (4.0%) | 1/20 (5.0%) | 0/20 (0.0%) | 3/20 (15.0%) | 0/19 (0.0%) | 3/21 (14.3%)
First incidence (days) | 316 (T) | 320 (T) | — | 320 (T) | — | 275
| Vehicle Control | 0.749 | 0.515N | 0.275 | 0.537N | 0.162
| | AZT-H | 0.504N | 0.293 | 0.527N | 0.177
Poly-3 test | | | 3TC-H | 0.112 | — | 0.059
| | | | NVP-H | 0.134N | 0.523
| | | | | AZT/3TC-H | 0.075
Litter-adjusted correlation | 0.13
Litter-adjusted Poly-3 rate | 3.8% | 4.5% | 0.0% | 13.5% | 0.0% | 16.4%
| Vehicle Control | 0.454 | 0.147N | 0.114 | 0.147N | 0.094
| | AZT-H | 0.155N | 0.141 | 0.155N | 0.114
Litter-adjusted Poly-3 test | | | 3TC-H | 0.031* | — | 0.032*
| | | | NVP-H | 0.031N* | 0.403
| | | | | AZT/3TC-H | 0.032*
Sire-adjusted correlation | −0.02
Sire-adjusted Poly-3 rate | 4.1% | 4.1% | 0.0% | 12.9% | 0.0% | 16.7%
| Vehicle Control | 0.500 | 0.141N | 0.140 | 0.142N | 0.106
| | AZT-H | 0.159N | 0.141 | 0.161N | 0.104
Sire-adjusted Poly-3 test | | | 3TC-H | 0.030* | — | 0.032*
| | | | NVP-H | 0.031N* | 0.382
| | | | | AZT/3TC-H | 0.033*
All Organs: Malignant Neoplasms
Overall rate | 3/25 (12.0%) | 4/25 (16.0%) | 8/25 (32.0%) | 9/25 (36.0%) | 8/24 (33.3%) | 6/25 (24.0%)
Adjusted rate | 3/25.0 (12.0%) | 4/24.7 (16.2%) | 8/25.0 (32.0%) | 9/24.9 (36.2%) | 8/24.0 (33.3%) | 6/25.0 (24.0%)
Terminal rate | 3/25 (12.0%) | 0/20 (0.0%) | 3/20 (15.0%) | 5/20 (25.0%) | 3/19 (15.8%) | 2/21 (9.5%)
First incidence (days) | 316 (T) | 277 | 258 | 251 | 102 | 247
| Vehicle Control | 0.493 | 0.084 | 0.044 | 0.071 | 0.233
| | AZT-H | 0.167 | 0.100 | 0.146 | 0.373
Poly-3 test | | | 3TC-H | 0.495 | 0.580 | 0.378N
| | | | NVP-H | 0.536N | 0.267N
| | | | | AZT/3TC-H | 0.344N
Litter-adjusted correlation | 0.08
Litter-adjusted Poly-3 rate | 11.6% | 15.9% | 32.6% | 36.0% | 32.5% | 23.6%
| Vehicle Control | 0.311 | 0.039* | 0.021* | 0.034* | 0.127
| | AZT-H | 0.088 | 0.053 | 0.082 | 0.242
Litter-adjusted Poly-3 test | | | 3TC-H | 0.408 | 0.498N | 0.258N
| | | | NVP-H | 0.403N | 0.186N
| | | | | AZT/3TC-H | 0.254N
Sire-adjusted correlation | 0.02
Sire-adjusted Poly-3 rate | 12.0% | 16.5% | 31.7% | 36.3% | 33.2% | 23.7%
| Vehicle Control | 0.282 | 0.037* | 0.018* | 0.018* | 0.142
| | AZT-H | 0.082 | 0.069 | 0.057 | 0.278
Sire-adjusted Poly-3 test | | | 3TC-H | 0.378 | 0.444 | 0.299N
| | | | NVP-H | 0.405N | 0.170N
| | | | | AZT/3TC-H | 0.234N
All Organs: Benign or Malignant Neoplasms
Overall rate | 4/25 (16.0%) | 6/25 (24.0%) | 8/25 (32.0%) | 12/25 (48.0%) | 8/24 (33.3%) | 9/25 (36.0%)
Adjusted rate | 4/25.0 (16.0%) | 6/25.0 (24.0%) | 8/25.0 (32.0%) | 12/24.9 (48.2%) | 8/24.0 (33.3%) | 9/25.0 (36.0%)
Terminal rate | 4/25 (16.0%) | 1/20 (5.0%) | 3/20 (15.0%) | 8/20 (40.0%) | 3/19 (15.8%) | 5/21 (23.8%)
First incidence (days) | 316 (T) | 277 | 258 | 251 | 102 | 247
| Vehicle Control | 0.364 | 0.161 | 0.013* | 0.141 | 0.097
| | AZT-H | 0.378 | 0.066 | 0.344 | 0.271
Poly-3 test | | | 3TC-H | 0.191 | 0.580 | 0.500
| | | | NVP-H | 0.223N | 0.281N
| | | | | AZT/3TC-H | 0.541
Litter-adjusted correlation | 0.23
Litter-adjusted Poly-3 rate | 14.5% | 23.9% | 33.5% | 48.8% | 30.9% | 34.9%
| Vehicle Control | 0.200 | 0.073 | 0.004** | 0.094 | 0.056
| | AZT-H | 0.233 | 0.029* | 0.288 | 0.198
Litter-adjusted Poly-3 test | | | 3TC-H | 0.151 | 0.428N | 0.462
| | | | NVP-H | 0.104N | 0.170N
| | | | | AZT/3TC-H | 0.388
Sire-adjusted correlation | 0.06
Sire-adjusted Poly-3 rate | 15.6% | 25.2% | 30.7% | 48.9% | 32.6% | 35.0%
| Vehicle Control | 0.184 | 0.114 | 0.004** | 0.079 | 0.048*
| | AZT-H | 0.320 | 0.021* | 0.259 | 0.225
Sire-adjusted Poly-3 test | | | 3TC-H | 0.120 | 0.431 | 0.396
| | | | NVP-H | 0.091N | 0.166N
| | | | | AZT/3TC-H | 0.430

(T) Terminal kill

a AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b Number of neoplasm-bearing animals/number of animals with tissue examined microscopically

c Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

d Observed incidence at terminal kill

e Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between that dosed group and the group stated to the left on the same row. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in a dose group is indicated by N.

f Not applicable; no neoplasms in animal group

g Value of statistic cannot be computed.

TABLE G8 Litter-adjusted Statistical Analysis of Selected Nonneoplastic Lesions in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Adrenal Cortex: Hypertrophy
Overall rate^b^ | 0/25 (0.0%) | 0/25 (0.0%) | 1/23 (4.3%) | 2/23 (8.7%)
Adjusted rate^c^ | 0/22.8 (0.0%) | 0/24.8 (0.0%) | 1/22.9 (4.4%) | 2/22.8 (8.8%)
Terminal rate^d^ | 0/20 (0.0%) | 0/24 (0.0%) | 1/22 (4.5%) | 2/22 (9.1%)
First incidence (days) | —^g^ | — | 318 (T) | 318 (T)
Average severity | —^g^ | — | 2.0 | 1.5
Poly-3 test^e^ | 0.055 | —^h^ | 0.501 | 0.235
Litter-adjusted correlation | −0.01
Litter-adjusted Poly-3 rate | 0.0% | 0.0% | 4.4% | 8.8%
Litter-adjusted Poly-3 test | 0.043* | — | 0.158 | 0.064
Sire-adjusted correlation | 0.01
Sire-adjusted Poly-3 rate | 0.0% | 0.0% | 4.5% | 8.9%
Sire-adjusted Poly-3 test | 0.045* | — | 0.153 | 0.064
JT/SW test^f^ | 0.031* | 0.500 | 0.118 | 0.053
Bone Marrow: Hyperplasia
Overall rate | 3/23 (13.0%) | 2/25 (8.0%) | 4/23 (17.4%) | 0/23 (0.0%)
Adjusted rate | 3/21.9 (13.7%) | 2/24.8 (8.1%) | 4/23.0 (17.4%) | 0/22.8 (0.0%)
Terminal rate | 2/20 (10.0%) | 2/24 (8.3%) | 3/22 (13.6%) | 0/22 (0.0%)
First incidence (days) | 313 | 317 (T) | 318 | —
Average severity | 3.3 | 3.5 | 3.0 | —
Poly-3 test | 0.167N | 0.443N | 0.528 | 0.105N
Litter-adjusted correlation | −0.15
Litter-adjusted Poly-3 rate | 14.4% | 7.8% | 17.3% | 0.0%
Litter-adjusted Poly-3 test | 0.069N | 0.225N | 0.384 | 0.019N*
Sire-adjusted correlation | −0.08
Sire-adjusted Poly-3 rate | 14.2% | 7.1% | 17.3% | 0.0%
Sire-adjusted Poly-3 test | 0.068N | 0.205N | 0.380 | 0.014N*
JT/SW test | 0.137N | 0.286N | 0.548N | 0.082N
Kidney: Hydronephrosis
Overall rate | 1/25 (4.0%) | 13/25 (52.0%) | 5/23 (21.7%) | 12/23 (52.2%)
Adjusted rate | 1/22.8 (4.4%) | 13/24.8 (52.5%) | 5/22.9 (21.8%) | 12/23.0 (52.2%)
Terminal rate | 1/20 (5.0%) | 13/24 (54.2%) | 5/22 (22.7%) | 11/22 (50.0%)
First incidence (days) | 320 (T) | 315 (T) | 318 (T) | 307
Average severity | 2.0 | 1.2 | 1.2 | 2.0
Poly-3 test | 0.006** | <0.001*** | 0.093 | <0.001***
Litter-adjusted correlation | 0.30
Litter-adjusted Poly-3 rate | 4.9% | 52.9% | 21.8% | 52.4%
Litter-adjusted Poly-3 test | 0.003** | <0.001*** | 0.033* | <0.001***
Sire-adjusted correlation | 0.27
Sire-adjusted Poly-3 rate | 7.3% | 57.3% | 17.7% | 53.3%
Sire-adjusted Poly-3 test | 0.001** | <0.001*** | 0.129 | <0.001***
JT/SW test | 0.002** | <0.001*** | 0.007** | <0.001***
Liver: Basophilic Focus
Overall rate | 0/25 (0.0%) | 0/25 (0.0%) | 2/23 (8.7%) | 2/23 (8.7%)
Adjusted rate | 0/22.8 (0.0%) | 0/24.8 (0.0%) | 2/22.9 (8.7%) | 2/22.8 (8.8%)
Terminal rate | 0/20 (0.0%) | 0/24 (0.0%) | 2/22 (9.1%) | 2/22 (9.1%)
First incidence (days) | — | — | 320 (T) | 321 (T)
Average severity | — | — | 5.0 | 5.0
Poly-3 test | 0.052 | — | 0.236 | 0.235
Litter-adjusted correlation | −0.12
Litter-adjusted Poly-3 rate | 0.0% | 0.0% | 9.0% | 9.4%
Litter-adjusted Poly-3 test | 0.021* | — | 0.057 | 0.052
Sire-adjusted correlation | −0.05
Sire-adjusted Poly-3 rate | 0.0% | 0.0% | 9.1% | 9.0%
Sire-adjusted Poly-3 test | 0.017* | — | 0.051 | 0.055
JT/SW test | 0.029* | 0.500 | 0.039* | 0.083
Liver: Cytoplasmic Vacuolization
Overall rate | 19/25 (76.0%) | 21/25 (84.0%) | 19/23 (82.6%) | 20/23 (87.0%)
Adjusted rate | 19/23.9 (79.5%) | 21/24.8 (84.8%) | 19/23.0 (82.6%) | 20/22.8 (87.6%)
Terminal rate | 17/20 (85.0%) | 21/24 (87.5%) | 18/22 (81.8%) | 20/22 (90.9%)
First incidence (days) | 207 | 315 (T) | 316 (T) | 316 (T)
Average severity | 1.9 | 2.1 | 2.4 | 2.8
Poly-3 test | 0.305 | 0.455 | 0.540 | 0.361
Litter-adjusted correlation | 0.20
Litter-adjusted Poly-3 rate | 80.1% | 84.2% | 83.3% | 88.2%
Litter-adjusted Poly-3 test | 0.247 | 0.359 | 0.397 | 0.226
Sire-adjusted correlation | 0.19
Sire-adjusted Poly-3 rate | 80.8% | 86.7% | 84.3% | 90.2%
Sire-adjusted Poly-3 test | 0.147 | 0.253 | 0.391 | 0.115
JT/SW test | <0.001*** | 0.112 | 0.047* | <0.001***
Liver: Inflammation
Overall rate | 0/25 (0.0%) | 1/25 (4.0%) | 2/23 (8.7%) | 1/23 (4.3%)
Adjusted rate | 0/22.8 (0.0%) | 1/24.8 (4.0%) | 2/23.0 (8.7%) | 1/22.8 (4.4%)
Terminal rate | 0/20 (0.0%) | 1/24 (4.2%) | 1/22 (4.5%) | 1/22 (4.5%)
First incidence (days) | — | 325 (T) | 318 | 320 (T)
Average severity | — | 1.0 | 1.5 | 2.0
Poly-3 test | 0.253 | 0.517 | 0.237 | 0.500
Litter-adjusted correlation | −0.03
Litter-adjusted Poly-3 rate | 0.0% | 4.1% | 8.6% | 4.3%
Litter-adjusted Poly-3 test | 0.115 | 0.147 | 0.067 | 0.156
Sire-adjusted correlation | −0.05
Sire-adjusted Poly-3 rate | 0.0% | 4.0% | 9.5% | 4.0%
Sire-adjusted Poly-3 test | 0.111 | 0.149 | 0.048* | 0.171
JT/SW test | 0.151 | 0.159 | 0.076 | 0.164
Nose: Hyaline Droplet
Overall rate | 0/25 (0.0%) | 3/25 (12.0%) | 2/23 (8.7%) | 0/24 (0.0%)
Adjusted rate | 0/22.8 (0.0%) | 3/25.0 (12.0%) | 2/22.9 (8.7%) | 0/22.9 (0.0%)
Terminal rate | 0/20 (0.0%) | 2/24 (8.3%) | 2/22 (9.1%) | 0/22 (0.0%)
First incidence (days) | — | 297 | 320 (T) | —
Average severity | — | 1.3 | 1.5 | —
Poly-3 test | 0.495N | 0.131 | 0.236 | —
Litter-adjusted correlation | −0.13
Litter-adjusted Poly-3 rate | 0.0% | 12.5% | 9.0% | 0.0%
Litter-adjusted Poly-3 test | 0.338N | 0.020* | 0.057 | —
Sire-adjusted correlation | −0.05
Sire-adjusted Poly-3 rate | 0.0% | 11.9% | 9.2% | 0.0%
Sire-adjusted Poly-3 test | 0.376N | 0.024* | 0.049* | —
JT/SW test | 0.456N | 0.961N | 0.937N | 0.618N
Pancreatic Islets: Hyperplasia
Overall rate | 13/24 (54.2%) | 9/25 (36.0%) | 13/23 (56.5%) | 6/23 (26.1%)
Adjusted rate | 13/23.3 (55.9%) | 9/25.0 (36.0%) | 13/23.0 (56.5%) | 6/22.8 (26.3%)
Terminal rate | 10/20 (50.0%) | 8/24 (33.3%) | 12/22 (54.5%) | 6/22 (27.3%)
First incidence (days) | 279 | 297 | 318 (T) | 316 (T)
Average severity | 1.5 | 1.4 | 1.3 | 1.8
Poly-3 test | 0.085N | 0.136N | 0.598 | 0.037N*
Litter-adjusted correlation | 0.08
Litter-adjusted Poly-3 rate | 55.2% | 36.1% | 56.2% | 26.5%
Litter-adjusted Poly-3 test | 0.065N | 0.106N | 0.469 | 0.018N*
Sire-adjusted correlation | −0.04
Sire-adjusted Poly-3 rate | 55.8% | 35.9% | 58.1% | 25.9%
Sire-adjusted Poly-3 test | 0.042N* | 0.138N | 0.432 | 0.013N*
JT/SW test | 0.108N | 0.111N | 0.291N | 0.057N
Thymus: Atrophy
Overall rate | 2/24 (8.3%) | 1/25 (4.0%) | 0/20 (0.0%) | 1/20 (5.0%)
Adjusted rate | 2/22.0 (9.1%) | 1/24.8 (4.0%) | 0/19.9 (0.0%) | 1/20.0 (5.0%)
Terminal rate | 1/20 (5.0%) | 1/24 (4.2%) | 0/19 (0.0%) | 1/20 (5.0%)
First incidence (days) | 310 | 315 (T) | — | 326 (T)
Average severity | 3.5 | 4.0 | — | 3.0
Poly-3 test | 0.297N | 0.459N | 0.257N | 0.534N
Litter-adjusted correlation | 0.00
Litter-adjusted Poly-3 rate | 9.1% | 4.1% | 0.0% | 5.0%
Litter-adjusted Poly-3 test | 0.244N | 0.240N | 0.062N | 0.298N
Sire-adjusted correlation | −0.05
Sire-adjusted Poly-3 rate | 9.7% | 4.1% | 0.0% | 4.8%
Sire-adjusted Poly-3 test | 0.212N | 0.221N | 0.048N* | 0.264N
JT/SW test | 0.212N | 0.274N | 0.109N | 0.224N

(T) Terminal kill

a AZT/3TC/NVP-L = 80/50/56 mg/kg; AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg

b Number of lesion-bearing animals/number of animals examined microscopically

c Poly-3 estimated lesion incidence after adjustment for intercurrent mortality

d Observed incidence at terminal kill

e Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

f Beneath the vehicle control incidence is the P value associated with the Jonckheere/Terpstra monotonic trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group by William’s modified Shirley’s test. A negative trend or lower incidence in a dose group is indicated by N.

g Not applicable, no lesions in animal group

h Value of statistic cannot be computed.

TABLE G9 Litter-adjusted Statistical Analysis of Selected Nonneoplastic Lesions in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
Adrenal Cortex: Subcapsular Hyperplasia
Overall rate^b^ | 13/25 (52.0%) | 11/23 (47.8%) | 13/25 (52.0%) | 7/25 (28.0%) | 11/23 (47.8%) | 12/23 (52.2%)
Adjusted rate^c^ | 13/23.3 (55.8%) | 11/21.3 (51.6%) | 13/24.2 (53.8%) | 7/22.4 (31.2%) | 11/20.4 (54.0%) | 12/22.8 (52.6%)
Terminal incidence^d^ | 11/20 (55.0%) | 9/18 (50.0%) | 12/23 (52.2%) | 7/22 (31.8%) | 11/20 (55.0%) | 12/22 (54.5%)
First incidence (days) | 279 | 176 | 250 | 320 (T) | 316 (T) | 318 (T)
Average severity | 1.0 | 1.0 | 1.0 | 1.0 | 1.1 | 1.1
| Vehicle Control | 0.507N | 0.560N | 0.081N | 0.572N | 0.529N
| | AZT-H | 0.558 | 0.142N | 0.560 | 0.592
Poly-3 test^e^ | | | 3TC-H | 0.102N | 0.611 | 0.581N
| | | | NVP-H | 0.113 | 0.123
| | | | | AZT/3TC-H | 0.582N
Litter-adjusted correlation | 0.08
Litter-adjusted Poly-3 rate | 56.4% | 50.9% | 54.0% | 31.2% | 54.5% | 52.6%
| Vehicle Control | 0.371N | 0.438N | 0.044N* | 0.454N | 0.404N
| | AZT-H | 0.421 | 0.085N | 0.411 | 0.456
Litter-adjusted Poly-3 test | | | 3TC-H | 0.042N* | 0.485 | 0.462N
| | | | NVP-H | 0.047* | 0.051
| | | | | AZT/3TC-H | 0.449N
Sire-adjusted correlation | 0.04
Sire-adjusted Poly-3 rate | 56.8% | 52.6% | 54.4% | 31.6% | 55.1% | 52.5%
| Vehicle Control | 0.393N | 0.425N | 0.025N* | 0.461N | 0.380N
| | AZT-H | 0.452 | 0.090N | 0.436 | 0.499N
Sire-adjusted Poly-3 test | | | 3TC-H | 0.041N* | 0.482 | 0.445N
| | | | NVP-H | 0.039* | 0.043*
| | | | | AZT/3TC-H | 0.426N
Bone Marrow: Hyperplasia
Overall rate | 3/23 (13.0%) | 3/24 (12.5%) | 1/24 (4.2%) | 2/25 (8.0%) | 2/24 (8.3%) | 0/23 (0.0%)
Adjusted rate | 3/21.9 (13.7%) | 3/22.2 (13.5%) | 1/23.5 (4.3%) | 2/24.2 (8.3%) | 2/21.4 (9.4%) | 0/22.8 (0.0%)
Terminal incidence | 2/20 (10.0%) | 0/18 (0.0%) | 1/23 (4.3%) | 0/22 (0.0%) | 2/21 (9.5%) | 0/22 (0.0%)
First incidence (days) | 313 | 42 | 320 (T) | 39 | 319 (T) | —^f^
Average severity | 3.3 | 3.3 | 3.0 | 3.0 | 2.0 | —^f^
| Vehicle Control | 0.659N | 0.277N | 0.454N | 0.511N | 0.105N
| | AZT-H | 0.283N | 0.461N | 0.518N | 0.108N
Poly-3 test | | | 3TC-H | 0.510 | 0.468 | 0.505N
| | | | NVP-H | 0.651 | 0.248N
| | | | | AZT/3TC-H | 0.220N
Litter-adjusted correlation | −0.07
Litter-adjusted Poly-3 rate | 14.0% | 13.0% | 4.4% | 8.2% | 9.3% | 0.0%
| Vehicle Control | 0.462N | 0.114N | 0.253N | 0.302N | 0.020N*
| | AZT-H | 0.151N | 0.297N | 0.345N | 0.037N*
Litter-adjusted Poly-3 test | | | 3TC-H | 0.289 | 0.255 | 0.145N
| | | | NVP-H | 0.449 | 0.067N
| | | | | AZT/3TC-H | 0.065N
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 13.7% | 13.3% | 4.3% | 8.3% | 9.3% | 0.0%
| Vehicle Control | 0.483N | 0.122N | 0.257N | 0.313N | 0.016N*
| | AZT-H | 0.075N | 0.292N | 0.333N | 0.038N*
Sire-adjusted Poly-3 test | | | 3TC-H | 0.283 | 0.249 | 0.145N
| | | | NVP-H | 0.450 | 0.066N
| | | | | AZT/3TC-H | 0.046N*
Kidney: Hydronephrosis
Overall rate | 1/25 (4.0%) | 8/23 (34.8%) | 7/25 (28.0%) | 5/25 (20.0%) | 9/24 (37.5%) | 12/23 (52.2%)
Adjusted rate | 1/22.8 (4.4%) | 8/19.9 (40.2%) | 7/24.5 (28.6%) | 5/23.2 (21.6%) | 9/21.4 (42.1%) | 12/23.0 (52.2%)
Terminal incidence | 1/20 (5.0%) | 8/18 (44.4%) | 6/23 (26.1%) | 4/22 (18.2%) | 9/21 (42.9%) | 11/22 (50.0%)
First incidence (days) | 320 (T) | 316 (T) | 182 | 215 | 317 (T) | 307
Average severity | 2.0 | 1.8 | 1.4 | 1.6 | 1.4 | 2.0
| Vehicle Control | 0.004** | 0.029* | 0.096 | 0.002** | <0.001***
| | AZT-H | 0.314N | 0.160N | 0.576 | 0.319
Poly-3 test | | | 3TC-H | 0.412N | 0.262 | 0.085
| | | | NVP-H | 0.124 | 0.028*
| | | | | AZT/3TC-H | 0.358
Litter-adjusted correlation | 0.07
Litter-adjusted Poly-3 rate | 4.5% | 40.0% | 28.6% | 21.1% | 43.3% | 52.2%
| Vehicle Control | <0.001*** | 0.003** | 0.050* | <0.001*** | <0.001***
| | AZT-H | 0.190N | 0.085N | 0.415 | 0.216
Litter-adjusted Poly-3 test | | | 3TC-H | 0.264N | 0.144 | 0.045*
| | | | NVP-H | 0.065 | 0.017*
| | | | | AZT/3TC-H | 0.293
Sire-adjusted correlation | 0.08
Sire-adjusted Poly-3 rate | 5.0% | 40.1% | 27.8% | 21.6% | 44.4% | 52.2%
| Vehicle Control | <0.001*** | 0.006** | 0.076 | <0.001*** | <0.001***
| | AZT-H | 0.163N | 0.095N | 0.386 | 0.208
Sire-adjusted Poly-3 test | | | 3TC-H | 0.306N | 0.097 | 0.038*
| | | | NVP-H | 0.065 | 0.013*
| | | | | AZT/3TC-H | 0.275
Kidney: Cellular Infiltration
Overall rate | 8/25 (32.0%) | 2/23 (8.7%) | 10/25 (40.0%) | 6/25 (24.0%) | 2/24 (8.3%) | 7/23 (30.4%)
Adjusted rate | 8/22.8 (35.1%) | 2/19.9 (10.1%) | 10/23.6 (42.3%) | 6/22.4 (26.7%) | 2/21.4 (9.4%) | 7/22.8 (30.7%)
Terminal incidence | 8/20 (40.0%) | 2/18 (11.1%) | 10/23 (43.5%) | 6/22 (27.3%) | 2/21 (9.5%) | 7/22 (31.8%)
First incidence (days) | 317 (T) | 316 (T) | 318 (T) | 319 (T) | 320 (T) | 316 (T)
Average severity | 1.1 | 1.0 | 1.1 | 1.0 | 1.0 | 1.7
| Vehicle Control | 0.054N | 0.420 | 0.388N | 0.042N* | 0.498N
| | AZT-H | 0.017* | 0.161 | 0.671N | 0.100
Poly-3 test | | | 3TC-H | 0.212N | 0.012N* | 0.303N
| | | | NVP-H | 0.135N | 0.514
| | | | | AZT/3TC-H | 0.081
Litter-adjusted correlation | −0.14
Litter-adjusted Poly-3 rate | 33.5% | 10.0% | 42.1% | 26.7% | 8.4% | 30.6%
| Vehicle Control | 0.025N* | 0.268 | 0.299N | 0.016N* | 0.414N
| | AZT-H | 0.003** | 0.052 | 0.430N | 0.027*
Litter-adjusted Poly-3 test | | | 3TC-H | 0.108N | 0.001 N** | 0.186N
| | | | NVP-H | 0.033N* | 0.369
| | | | | AZT/3TC-H | 0.017*
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 35.2% | 10.3% | 42.2% | 26.7% | 9.2% | 30.7%
| Vehicle Control | 0.014N* | 0.315 | 0.254N | 0.012N* | 0.371N
| | AZT-H | 0.007** | 0.039* | 0.440N | 0.028*
Sire-adjusted Poly-3 test | | | 3TC-H | 0.111N | 0.003N** | 0.186N
| | | | NVP-H | 0.047N* | 0.339
| | | | | AZT/3TC-H | 0.021*
Liver: Basophilic Focus
Overall rate | 0/25 (0.0%) | 0/23 (0.0%) | 1/25 (4.0%) | 1/25 (4.0%) | 1/25 (4.0%) | 2/23 (8.7%)
Adjusted rate | 0/22.8 (0.0%) | 0/19.9 (0.0%) | 1/23.6 (4.2%) | 1/22.4 (4.5%) | 1/23.0 (4.4%) | 2/22.8 (8.8%)
Terminal incidence | 0/20 (0.0%) | 0/18 (0.0%) | 1/23 (4.3%) | 1/22 (4.5%) | 0/21 (0.0%) | 2/22 (9.1%)
First incidence (days) | — | — | 319 (T) | 320 (T) | 203 | 321 (T)
| Vehicle Control | —^g^ | 0.507 | 0.497 | 0.502 | 0.235
| | AZT-H | 0.534 | 0.524 | 0.529 | 0.267
Poly-3 test | | | 3TC-H | 0.749 | 0.754 | 0.488
| | | | NVP-H | 0.756N | 0.506
| | | | | AZT/3TC-H | 0.498
Litter-adjusted correlation | −0.08
Litter-adjusted Poly-3 rate | 0.0% | 0.0% | 4.4% | 4.6% | 4.1% | 9.2%
| Vehicle Control | — | 0.146 | 0.145 | 0.157 | 0.053
| | AZT-H | 0.146 | 0.145 | 0.158 | 0.053
Litter-adjusted Poly-3 test | | | 3TC-H | 0.484 | 0.485N | 0.245
| | | | NVP-H | 0.470N | 0.259
| | | | | AZT/3TC-H | 0.235
Sire-adjusted correlation | −0.03
Sire-adjusted Poly-3 rate | 0.0% | 0.0% | 4.1% | 4.5% | 4.5% | 9.3%
| Vehicle Control | — | 0.155 | 0.143 | 0.143 | 0.043*
| | AZT-H | 0.155 | 0.144 | 0.143 | 0.044*
Sire-adjusted Poly-3 test | | | 3TC-H | 0.471 | 0.473 | 0.238
| | | | NVP-H | 0.498N | 0.249
| | | | | AZT/3TC-H | 0.252
Liver: Cytoplasmic Vacuolization
Overall rate | 19/25 (76.0%) | 18/23 (78.3%) | 20/25 (80.0%) | 20/25 (80.0%) | 21/25 (84.0%) | 20/23 (87.0%)
Adjusted rate | 19/23.9 (79.5%) | 18/19.9 (90.5%) | 20/23.6 (84.7%) | 20/22.4 (89.1%) | 21/22.2 (94.5%) | 20/22.8 (87.6%)
Terminal incidence | 17/20 (85.0%) | 18/18 (100.0%) | 20/23 (87.0%) | 20/22 (90.9%) | 21/21 (100.0%) | 20/22 (90.9%)
First incidence (days) | 207 | 316 (T) | 318 (T) | 319 (T) | 316 (T) | 316 (T)
Average severity | 1.9 | 2.5 | 2.4 | 2.3 | 2.3 | 2.8
| Vehicle Control | 0.265 | 0.465 | 0.306 | 0.127 | 0.361
| | AZT-H | 0.448N | 0.659N | 0.546 | 0.581N
Poly-3 test | | | 3TC-H | 0.496 | 0.256 | 0.555
| | | | NVP-H | 0.449 | 0.622N
| | | | | AZT/3TC-H | 0.378N
Litter-adjusted correlation | −0.09
Litter-adjusted Poly-3 rate | 79.2% | 90.8% | 84.0% | 88.7% | 94.7% | 87.3%
| Vehicle Control | 0.134 | 0.334 | 0.193 | 0.061 | 0.238
| | AZT-H | 0.193N | 0.390N | 0.259 | 0.328N
Litter-adjusted Poly-3 test | | | 3TC-H | 0.289 | 0.069 | 0.358
| | | | NVP-H | 0.190 | 0.432N
| | | | | AZT/3TC-H | 0.156N
Sire-adjusted correlation | −0.03
Sire-adjusted Poly-3 rate | 79.0% | 90.7% | 84.3% | 88.8% | 94.5% | 87.2%
| Vehicle Control | 0.131 | 0.334 | 0.172 | 0.051 | 0.174
| | AZT-H | 0.165N | 0.396N | 0.278 | 0.335N
Sire-adjusted Poly-3 test | | | 3TC-H | 0.301 | 0.087 | 0.374
| | | | NVP-H | 0.198 | 0.428N
| | | | | AZT/3TC-H | 0.179N
Lymph Node, Mesenteric: Hyperplasia
Overall rate | 9/24 (37.5%) | 5/23 (21.7%) | 12/25 (48.0%) | 11/25 (44.0%) | 11/24 (45.8%) | 9/23 (39.1%)
Adjusted rate | 9/22.3 (40.4%) | 5/20.7 (24.1%) | 12/23.6 (50.8%) | 11/22.4 (49.0%) | 11/22.1 (49.7%) | 9/22.8 (39.4%)
Terminal incidence | 8/20 (40.0%) | 4/18 (22.2%) | 12/23 (52.2%) | 11/22 (50.0%) | 10/21 (47.6%) | 9/22 (40.9%)
First incidence (days) | 279 | 176 | 318 (T) | 319 (T) | 203 | 316 (T)
Average severity | 2.0 | 1.6 | 1.7 | 2.4 | 1.9 | 1.6
| Vehicle Control | 0.208N | 0.342 | 0.392 | 0.376 | 0.592N
| | AZT-H | 0.061 | 0.081 | 0.075 | 0.226
Poly-3 test | | | 3TC-H | 0.568N | 0.586N | 0.316N
| | | | NVP-H | 0.599 | 0.365N
| | | | | AZT/3TC-H | 0.349N
Litter-adjusted correlation | −0.14
Litter-adjusted Poly-3 rate | 41.4% | 23.5% | 49.7% | 49.1% | 50.1% | 38.8%
| Vehicle Control | 0.084N | 0.272 | 0.274 | 0.265 | 0.431N
| | AZT-H | 0.023* | 0.019* | 0.024* | 0.144
Litter-adjusted Poly-3 test | | | 3TC-H | 0.482N | 0.488 | 0.234N
| | | | NVP-H | 0.470 | 0.235N
| | | | | AZT/3TC-H | 0.229N
Sire-adjusted correlation | 0.00
Sire-adjusted Poly-3 rate | 40.4% | 24.1% | 50.8% | 49.0% | 49.7% | 39.4%
| Vehicle Control | 0.108N | 0.234 | 0.262 | 0.267 | 0.468N
| | AZT-H | 0.032* | 0.020* | 0.030* | 0.182
Sire-adjusted Poly-3 test | | | 3TC-H | 0.442N | 0.469N | 0.215N
| | | | NVP-H | 0.475 | 0.230N
| | | | | AZT/3TC-H | 0.227N
Lymph Node, Mandibular: Hyperplasia
Overall rate | 2/25 (8.0%) | 1/23 (4.3%) | 2/25 (8.0%) | 2/25 (8.0%) | 2/24 (8.3%) | 5/23 (21.7%)
Adjusted rate | 2/22.8 (8.8%) | 1/19.9 (5.0%) | 2/24.2 (8.3%) | 2/22.4 (8.9%) | 2/21.4 (9.4%) | 5/22.8 (21.9%)
Terminal incidence | 2/20 (10.0%) | 1/18 (5.6%) | 1/23 (4.3%) | 2/22 (9.1%) | 2/21 (9.5%) | 5/22 (22.7%)
First incidence (days) | 315 (T) | 319 (T) | 250 | 319 (T) | 321 (T) | 316 (T)
Average severity | 1.5 | 1.0 | 1.0 | 1.0 | 2.0 | 2.2
| Vehicle Control | 0.548N | 0.674N | 0.691 | 0.673 | 0.207
| | AZT-H | 0.568 | 0.542 | 0.525 | 0.126
Poly-3 test | | | 3TC-H | 0.669 | 0.651 | 0.184
| | | | NVP-H | 0.679 | 0.214
| | | | | AZT/3TC-H | 0.235
Litter-adjusted correlation | −0.10
Litter-adjusted Poly-3 rate | 8.8% | 5.3% | 8.1% | 8.3% | 9.7% | 21.8%
| Vehicle Control | 0.321N | 0.466N | 0.476N | 0.458 | 0.095
| | AZT-H | 0.349 | 0.346 | 0.286 | 0.041*
Litter-adjusted Poly-3 test | | | 3TC-H | 0.491 | 0.424 | 0.080
| | | | NVP-H | 0.435 | 0.088
| | | | | AZT/3TC-H | 0.114
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 8.7% | 5.0% | 8.2% | 9.0% | 9.3% | 21.7%
| Vehicle Control | 0.312N | 0.473N | 0.489 | 0.472 | 0.101
| | AZT-H | 0.332 | 0.208 | 0.290 | 0.049*
Sire-adjusted Poly-3 test | | | 3TC-H | 0.460 | 0.442 | 0.080
| | | | NVP-H | 0.486 | 0.135
| | | | | AZT/3TC-H | 0.079
Lymph Node (All Sites): Hyperplasia
Overall rate | 10/25 (40.0%) | 6/23 (26.1%) | 13/25 (52.0%) | 14/25 (56.0%) | 11/24 (45.8%) | 11/23 (47.8%)
Adjusted rate | 10/23.3 (42.9%) | 6/20.7 (28.9%) | 13/24.2 (53.8%) | 14/22.4 (62.4%) | 11/22.1 (49.7%) | 11/22.8 (48.2%)
Terminal incidence | 8/20 (40.0%) | 5/18 (27.8%) | 12/23 (52.2%) | 14/22 (63.6%) | 10/21 (47.6%) | 11/22 (50.0%)
First incidence (days) | 279 | 176 | 250 | 319 (T) | 203 | 316 (T)
Average severity | 1.9 | 1.5 | 1.6 | 2.1 | 1.9 | 1.9
| Vehicle Control | 0.259N | 0.325 | 0.152 | 0.437 | 0.475
| | AZT-H | 0.081 | 0.024* | 0.139 | 0.161
Poly-3 test | | | 3TC-H | 0.385 | 0.506N | 0.464N
| | | | NVP-H | 0.292N | 0.255N
| | | | | AZT/3TC-H | 0.576N
Litter-adjusted correlation | −0.16
Litter-adjusted Poly-3 rate | 44.0% | 28.5% | 52.7% | 61.0% | 50.2% | 47.5%
| Vehicle Control | 0.134N | 0.272 | 0.110 | 0.338 | 0.410
| | AZT-H | 0.029* | 0.004** | 0.053 | 0.088
Litter-adjusted Poly-3 test | | | 3TC-H | 0.253 | 0.429N | 0.360N
| | | | NVP-H | 0.209N | 0.166N
| | | | | AZT/3TC-H | 0.428N
Sire-adjusted correlation | 0.01
Sire-adjusted Poly-3 rate | 42.9% | 28.8% | 53.8% | 62.4% | 49.6% | 48.1%
| Vehicle Control | 0.131N | 0.235 | 0.064 | 0.341 | 0.366
| | AZT-H | 0.031* | 0.004** | 0.083 | 0.100
Sire-adjusted Poly-3 test | | | 3TC-H | 0.225 | 0.375N | 0.326N
| | | | NVP-H | 0.159N | 0.106N
| | | | | AZT/3TC-H | 0.457N
Nose: Hyaline Droplet
Overall rate | 0/25 (0.0%) | 0/24 (0.0%) | 1/25 (4.0%) | 0/25 (0.0%) | 2/25 (8.0%) | 0/24 (0.0%)
Adjusted rate | 0/22.8 (0.0%) | 0/19.9 (0.0%) | 1/23.6 (4.2%) | 0/22.4 (0.0%) | 2/22.2 (9.0%) | 0/22.9 (0.0%)
Terminal incidence | 0/20 (0.0%) | 0/18 (0.0%) | 1/23 (4.3%) | 0/22 (0.0%) | 2/21 (9.5%) | 0/22 (0.0%)
First incidence (days) | — | — | 319 (T) | — | 321 (T) | —
Average severity | — | — | 2.0 | — | 1.5 | —
| Vehicle Control | — | 0.507 | — | 0.229 | —
| | AZT-H | 0.534 | — | 0.260 | —
Poly-3 test | | | 3TC-H | 0.510N | 0.478 | 0.507N
| | | | NVP-H | 0.232 | —
| | | | | AZT/3TC-H | 0.228N
Litter-adjusted correlation | −0.06
Litter-adjusted Poly-3 rate | 0.0% | 0.0% | 4.3% | 0.0% | 9.2% | 0.0%
| Vehicle Control | — | 0.146 | — | 0.055 | —
| | AZT-H | 0.146 | — | 0.055 | —
Litter-adjusted Poly-3 test | | | 3TC-H | 0.146N | 0.244 | 0.146N
| | | | NVP-H | 0.055 | —
| | | | | AZT/3TC-H | 0.055N
Sire-adjusted correlation | 0.03
Sire-adjusted Poly-3 rate | 0.0% | 0.0% | 4.1% | 0.0% | 8.8% | 0.0%
| Vehicle Control | — | 0.150 | — | 0.047* | —
| | AZT-H | 0.150 | — | 0.047* | —
Sire-adjusted Poly-3 test | | | 3TC-H | 0.150N | 0.130 | 0.150N
| | | | NVP-H | 0.047* | —
| | | | | AZT/3TC-H | 0.047N*
Preputial Gland: Acinus Degeneration
Overall rate | 3/25 (12.0%) | 2/24 (8.3%) | 3/25 (12.0%) | 3/25 (12.0%) | 1/24 (4.2%) | 5/23 (21.7%)
Adjusted rate | 3/22.9 (13.1%) | 2/20.2 (9.9%) | 3/23.6 (12.7%) | 3/22.4 (13.4%) | 1/21.4 (4.7%) | 5/23.0 (21.7%)
Terminal incidence | 2/20 (10.0%) | 1/18 (5.6%) | 3/23 (13.0%) | 3/22 (13.6%) | 1/21 (4.8%) | 4/22 (18.2%)
First incidence (days) | 310 | 285 | 319 (T) | 319 (T) | 318 (T) | 307
Average severity | 3.7 | 3.0 | 3.0 | 2.0 | 3.0 | 2.4
| Vehicle Control | 0.558N | 0.652N | 0.657 | 0.328N | 0.352
| | AZT-H | 0.572 | 0.548 | 0.480N | 0.263
Poly-3 test | | | 3TC-H | 0.642 | 0.339N | 0.336
| | | | NVP-H | 0.320N | 0.365
| | | | | AZT/3TC-H | 0.109
Litter-adjusted correlation | −0.13
Litter-adjusted Poly-3 rate | 13.7% | 9.2% | 12.7% | 13.4% | 4.3% | 21.6%
| Vehicle Control | 0.313N | 0.456N | 0.486N | 0.117N | 0.224
| | AZT-H | 0.351 | 0.327 | 0.261N | 0.113
Litter-adjusted Poly-3 test | | | 3TC-H | 0.471 | 0.138N | 0.193
| | | | NVP-H | 0.127N | 0.216
| | | | | AZT/3TC-H | 0.028*
Sire-adjusted correlation | −0.04
Sire-adjusted Poly-3 rate | 12.8% | 9.3% | 12.1% | 13.9% | 4.6% | 22.8%
| Vehicle Control | 0.355N | 0.469N | 0.455 | 0.156N | 0.180
| | AZT-H | 0.386 | 0.319 | 0.282N | 0.109
Sire-adjusted Poly-3 test | | | 3TC-H | 0.427 | 0.177N | 0.187
| | | | NVP-H | 0.065N | 0.195
| | | | | AZT/3TC-H | 0.010**
Preputial Gland: Duct Ectasia
Overall rate | 3/25 (12.0%) | 2/24 (8.3%) | 2/25 (8.0%) | 4/25 (16.0%) | 1/24 (4.2%) | 5/23 (21.7%)
Adjusted rate | 3/22.9 (13.1%) | 2/20.2 (9.9%) | 2/23.6 (8.5%) | 4/22.4 (17.8%) | 1/21.4 (4.7%) | 5/23.0 (21.7%)
Terminal incidence | 2/20 (10.0%) | 1/18 (5.6%) | 2/23 (8.7%) | 4/22 (18.2%) | 1/21 (4.8%) | 4/22 (18.2%)
First incidence (days) | 310 | 285 | 319 (T) | 319 (T) | 318 (T) | 307
Average severity | 3.3 | 3.0 | 3.5 | 2.0 | 2.0 | 2.4
| Vehicle Control | 0.558N | 0.486N | 0.488 | 0.328N | 0.352
| | AZT-H | 0.639N | 0.383 | 0.480N | 0.263
Poly-3 test | | | 3TC-H | 0.309 | 0.535N | 0.196
| | | | NVP-H | 0.186N | 0.516
| | | | | AZT/3TC-H | 0.109
Litter-adjusted correlation | −0.16
Litter-adjusted Poly-3 rate | 13.9% | 9.0% | 8.9% | 18.0% | 4.1% | 21.6%
| Vehicle Control | 0.298N | 0.286N | 0.337 | 0.109N | 0.230
| | AZT-H | 0.496N | 0.173 | 0.260N | 0.108
Litter-adjusted Poly-3 test | | | 3TC-H | 0.160 | 0.247N | 0.097
| | | | NVP-H | 0.049N* | 0.372
| | | | | AZT/3TC-H | 0.027*
Sire-adjusted correlation | −0.05
Sire-adjusted Poly-3 rate | 12.7% | 9.2% | 8.0% | 18.2% | 4.6% | 23.1%
| Vehicle Control | 0.353N | 0.286N | 0.295 | 0.159N | 0.172
| | AZT-H | 0.446N | 0.188 | 0.287N | 0.104
Sire-adjusted Poly-3 test | | | 3TC-H | 0.134 | 0.323N | 0.090
| | | | NVP-H | 0.024N* | 0.326
| | | | | AZT/3TC-H | 0.008**
Salivary Glands: Cellular Infiltration
Overall rate | 18/25 (72.0%) | 12/23 (52.2%) | 13/25 (52.0%) | 18/25 (72.0%) | 11/24 (45.8%) | 16/23 (69.6%)
Adjusted rate | 18/23.2 (77.7%) | 12/19.9 (60.3%) | 13/23.6 (55.0%) | 18/22.4 (80.2%) | 11/21.4 (51.5%) | 16/22.8 (70.1%)
Terminal incidence | 17/20 (85.0%) | 12/18 (66.7%) | 13/23 (56.5%) | 18/22 (81.8%) | 11/21 (52.4%) | 16/22 (72.7%)
First incidence (days) | 279 | 318 (T) | 318 (T) | 319 (T) | 316 (T) | 316 (T)
Average severity | 1.2 | 1.1 | 1.2 | 1.2 | 1.2 | 1.4
| Vehicle Control | 0.174N | 0.085N | 0.565 | 0.058N | 0.399N
| | AZT-H | 0.482N | 0.131 | 0.397N | 0.364
Poly-3 test | | | 3TC-H | 0.060 | 0.523N | 0.225
| | | | NVP-H | 0.040N* | 0.329N
| | | | | AZT/3TC-H | 0.168
Litter-adjusted correlation | −0.01
Litter-adjusted Poly-3 rate | 77.6% | 60.2% | 54.9% | 80.2% | 51.4% | 70.1%
| Vehicle Control | 0.084N | 0.036N* | 0.406 | 0.027N* | 0.282N
| | AZT-H | 0.352N | 0.057 | 0.278N | 0.250
Litter-adjusted Poly-3 test | | | 3TC-H | 0.022* | 0.409N | 0.148
| | | | NVP-H | 0.017N* | 0.219N
| | | | | AZT/3TC-H | 0.113
Sire-adjusted correlation | 0.15
Sire-adjusted Poly-3 rate | 76.8% | 66.5% | 58.6% | 82.3% | 53.1% | 76.6%
| Vehicle Control | 0.199N | 0.048N* | 0.341 | 0.027N* | 0.494N
| | AZT-H | 0.265N | 0.112 | 0.174N | 0.139
Sire-adjusted Poly-3 test | | | 3TC-H | 0.033* | 0.333N | 0.074
| | | | NVP-H | 0.024N* | 0.337N
| | | | | AZT/3TC-H | 0.054
Spleen: Hyperplasia
Overall rate | 12/25 (48.0%) | 14/23 (60.9%) | 16/24 (66.7%) | 18/25 (72.0%) | 14/24 (58.3%) | 12/23 (52.2%)
Adjusted rate | 12/24.0 (49.9%) | 14/19.2 (72.8%) | 16/23.5 (68.2%) | 18/22.4 (80.2%) | 14/22.1 (63.2%) | 12/22.8 (52.6%)
Terminal incidence | 9/20 (45.0%) | 14/18 (77.8%) | 16/23 (69.6%) | 18/22 (81.8%) | 13/21 (61.9%) | 12/22 (54.5%)
First incidence (days) | 207 | 316 (T) | 318 (T) | 319 (T) | 203 | 316 (T)
Average severity | 2.4 | 2.3 | 2.1 | 2.3 | 2.5 | 2.4
| Vehicle Control | 0.109 | 0.161 | 0.027* | 0.271 | 0.544
| | AZT-H | 0.504N | 0.421 | 0.373N | 0.150N
Poly-3 test | | | 3TC-H | 0.277 | 0.483N | 0.215N
| | | | NVP-H | 0.175N | 0.044N*
| | | | | AZT/3TC-H | 0.338N
Litter-adjusted correlation | −0.03
Litter-adjusted Poly-3 rate | 49.9% | 72.9% | 68.1% | 80.4% | 63.3% | 52.8%
| Vehicle Control | 0.052 | 0.104 | 0.013* | 0.187 | 0.423
| | AZT-H | 0.358N | 0.269 | 0.241N | 0.065N
Litter-adjusted Poly-3 test | | | 3TC-H | 0.165 | 0.365N | 0.131N
| | | | NVP-H | 0.097N | 0.015N*
| | | | | AZT/3TC-H | 0.232N
Sire-adjusted correlation | 0.21
Sire-adjusted Poly-3 rate | 54.1% | 73.1% | 73.4% | 77.7% | 62.8% | 50.5%
| Vehicle Control | 0.037* | 0.069 | 0.016* | 0.194 | 0.403N
| | AZT-H | 0.488 | 0.369 | 0.121N | 0.032N*
Sire-adjusted Poly-3 test | | | 3TC-H | 0.373 | 0.160N | 0.070N
| | | | NVP-H | 0.111N | 0.038N*
| | | | | AZT/3TC-H | 0.193N
Thymus: Hyperplasia
Overall rate | 2/24 (8.3%) | 0/22 (0.0%) | 0/24 (0.0%) | 1/23 (4.3%) | 3/22 (13.6%) | 1/20 (5.0%)
Adjusted rate | 2/22.6 (8.8%) | 0/19.2 (0.0%) | 0/23.2 (0.0%) | 1/22.3 (4.5%) | 3/20.4 (14.7%) | 1/20.0 (5.0%)
Terminal incidence | 1/20 (5.0%) | 0/18 (0.0%) | 0/23 (0.0%) | 1/22 (4.5%) | 3/20 (15.0%) | 1/20 (5.0%)
First incidence (days) | 207 | — | — | 322 (T) | 319 (T) | 320 (T)
Average severity | 2.5 | — | — | 2.0 | 2.0 | 1.0
| Vehicle Control | 0.272N | 0.229N | 0.506N | 0.450 | 0.544N
| | AZT-H | — | 0.529 | 0.122 | 0.508
Poly-3 test | | | 3TC-H | 0.492 | 0.090 | 0.471
| | | | NVP-H | 0.269 | 0.736
| | | | | AZT/3TC-H | 0.307N
Litter-adjusted correlation | −0.07
Litter-adjusted Poly-3 rate | 8.9% | 0.0% | 0.0% | 4.6% | 14.7% | 4.9%
| Vehicle Control | 0.063N | 0.063N | 0.277N | 0.267 | 0.298N
| | AZT-H | — | 0.145 | 0.023* | 0.156
Litter-adjusted Poly-3 test | | | 3TC-H | 0.145 | 0.023* | 0.155
| | | | NVP-H | 0.119 | 0.483
| | | | | AZT/3TC-H | 0.132N
Sire-adjusted correlation | 0.02
Sire-adjusted Poly-3 rate | 8.8% | 0.0% | 0.0% | 4.4% | 14.6% | 5.0%
| Vehicle Control | 0.065N | 0.065N | 0.273N | 0.310 | 0.306N
| | AZT-H | — | 0.152 | 0.054 | 0.158
Sire-adjusted Poly-3 test | | | 3TC-H | 0.150 | 0.054 | 0.158
| | | | NVP-H | 0.123 | 0.462
| | | | | AZT/3TC-H | 0.175N
Urinary Bladder: Cellular Infiltration
Overall rate | 2/25 (8.0%) | 0/23 (0.0%) | 0/25 (0.0%) | 3/25 (12.0%) | 1/24 (4.2%) | 1/23 (4.3%)
Adjusted rate | 2/22.8 (8.8%) | 0/19.9 (0.0%) | 0/23.6 (0.0%) | 3/23.2 (13.0%) | 1/21.4 (4.7%) | 1/22.8 (4.4%)
Terminal incidence | 2/20 (10.0%) | 0/18 (0.0%) | 0/23 (0.0%) | 2/22 (9.1%) | 1/21 (4.8%) | 1/22 (4.5%)
First incidence (days) | 320 (T) | | | 215 | 321 (T) | 325 (T)
Average severity | 1.0 | — | — | 3.0 | 1.0 | 1.0
| Vehicle Control | 0.266N | 0.226N | 0.508 | 0.522N | 0.499N
| | AZT-H | | 0.142 | 0.514 | 0.527
Poly-3 test | | | 3TC-H | 0.110 | 0.480 | 0.493
| | | | NVP-H | 0.332N | 0.307N
| | | | | AZT/3TC-H | 0.746N
Litter-adjusted correlation | −0.06
Litter-adjusted Poly-3 rate | 8.5% | 0.0% | 0.0% | 13.0% | 4.8% | 4.6%
| Vehicle Control | 0.074N | 0.074N | 0.309 | 0.306N | 0.292N
| | AZT-H | — | 0.025* | 0.144 | 0.144
Litter-adjusted Poly-3 test | | | 3TC-H | 0.025* | 0.144 | 0.144
| | | | NVP-H | 0.154N | 0.143N
| | | | | AZT/3TC-H | 0.485N
Sire-adjusted correlation | −0.05
Sire-adjusted Poly-3 rate | 8.7% | 0.1% | 0.0% | 12.7% | 4.9% | 4.8%
| Vehicle Control | 0.061N | 0.059N | 0.328 | 0.302N | 0.290N
| | AZT-H | — | 0.028* | 0.137 | 0.130
Sire-adjusted Poly-3 test | | | 3TC-H | 0.027* | 0.133 | 0.126
| | | | NVP-H | 0.183N | 0.163N
| | | | | AZT/3TC-H | 0.496N

(T) Terminal kill

a AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b Number of lesion-bearing animals/number of animals with tissue examined microscopically

c Poly-3 estimated lesion incidence after adjustment for intercurrent mortality

d Observed incidence at terminal kill

e Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between that dosed group and the group stated to the left on the same row. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in a dose group is indicated by N.

f Not applicable; no neoplasms in animal group

g Value of statistic cannot be computed.

TABLE G10 Litter-adjusted Statistical Analysis of Selected Nonneoplastic Lesions in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Kidney: Hydronephrosis
Overall rate^b^ | 0/25 (0.0%) | 0/25 (0.0%) | 0/22 (0.0%) | 3/25 (12.0%)
Adjusted rate^c^ | 0/25.0 (0.0%) | 0/23.4 (0.0%) | 0/19.7 (0.0%) | 3/24.5 (12.2%)
Terminal rate^d^ | 0/25 (0.0%) | 0/22 (0.0%) | 0/19 (0.0%) | 1/21 (4.8%)
First incidence (days) | —^g^ | — | — | 247
Average severity | —^g^ | — | — | 3.0
Poly-3 test^e^ | 0.015* | —^h^ | — | 0.110
Litter-adjusted correlation | −0.04
Litter-adjusted Poly-3 rate | 0.0% | 0.0% | 0.0% | 12.3%
Litter-adjusted Poly-3 test | 0.026* | — | — | 0.026*
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 0.0% | 0.0% | 0.0% | 12.3%
Sire-adjusted Poly-3 test | 0.026* | — | — | 0.026*
JT/SW test^f^ | 0.010* | 0.500 | 0.583 | 0.008**
Liver: Centrilobular Degeneration
Overall rate | 0/25 (0.0%) | 0/25 (0.0%) | 0/22 (0.0%) | 3/25 (12.0%)
Adjusted rate | 0/25.0 (0.0%) | 0/23.4 (0.0%) | 0/19.7 (0.0%) | 3/23.8 (12.6%)
Terminal incidence (days) | 0/25 (0.0%) | 0/22 (0.0%) | 0/19 (0.0%) | 2/21 (9.5%)
First incidence (days) | — | — | — | 312
Average severity | — | — | — | 2.7
Poly-3 test | 0.015* | — | — | 0.105
Litter-adjusted correlation | −0.06
Litter-adjusted Poly-3 rate | 0.0% | 0.0% | 0.0% | 12.7%
Litter-adjusted Poly-3 test | 0.024* | — | — | 0.024*
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 0.0% | 0.0% | 0.0% | 12.6%
Sire-adjusted Poly-3 test | 0.024* | — | — | 0.024*
JT/SW test | 0.010* | 0.500 | 0.583 | 0.008**
Liver: Cellular Infiltration
Overall rate | 1/25 (4.0%) | 2/25 (8.0%) | 4/22 (18.2%) | 4/25 (16.0%)
Adjusted rate | 1/25.0 (4.0%) | 2/23.4 (8.6%) | 4/19.7 (20.3%) | 4/23.7 (16.9%)
Terminal incidence (days) | 1/25 (4.0%) | 2/22 (9.1%) | 4/19 (21.1%) | 4/21 (19.0%)
First incidence (days) | 318 (T) | 319 (T) | 318 (T) | 318 (T)
Average severity | 1.0 | 1.0 | 1.3 | 1.3
Poly-3 test | 0.063 | 0.476 | 0.106 | 0.157
Litter-adjusted correlation | 0.10
Litter-adjusted Poly-3 rate | 4.2% | 8.4% | 20.5% | 17.2%
Litter-adjusted Poly-3 test | 0.039* | 0.269 | 0.081 | 0.068
Sire-adjusted correlation | 0.01
Sire-adjusted Poly-3 rate | 4.0% | 8.2% | 20.5% | 16.8%
Sire-adjusted Poly-3 test | 0.015* | 0.279 | 0.076 | 0.066
JT/SW test | 0.051 | 0.278 | 0.057 | 0.089
Liver: Cytoplasmic Vacuolization
Overall rate | 14/25 (56.0%) | 17/25 (68.0%) | 13/22 (59.1%) | 15/25 (60.0%)
Adjusted rate | 14/25.0 (56.0%) | 17/23.4 (72.8%) | 13/19.7 (66.0%) | 15/23.8 (62.9%)
Terminal incidence (days) | 14/25 (56.0%) | 17/22 (77.3%) | 13/19 (68.4%) | 14/21 (66.7%)
First incidence (days) | 316 (T) | 315 (T) | 318 (T) | 312
Average severity | 1.1 | 1.2 | 1.3 | 1.7
Poly-3 test | 0.395 | 0.179 | 0.357 | 0.422
Litter-adjusted correlation | 0.17
Litter-adjusted Poly-3 rate | 56.5% | 72.9% | 66.5% | 63.6%
Litter-adjusted Poly-3 test | 0.369 | 0.138 | 0.242 | 0.305
Sire-adjusted correlation | 0.13
Sire-adjusted Poly-3 rate | 51.8% | 74.7% | 60.2% | 62.9%
Sire-adjusted Poly-3 test | 0.360 | 0.074 | 0.291 | 0.252
JT/SW test | 0.113 | 0.109 | 0.201 | 0.108
Lung: Infiltration Cellular
Overall rate | 0/25 (0.0%) | 1/25 (4.0%) | 0/22 (0.0%) | 3/25 (12.0%)
Adjusted rate | 0/25.0 (0.0%) | 1/23.4 (4.3%) | 0/19.7 (0.0%) | 3/23.7 (12.6%)
Terminal incidence (days) | 0/25 (0.0%) | 1/22 (4.5%) | 0/19 (0.0%) | 3/21 (14.3%)
First incidence (days) | — | 318 (T) | — | 320 (T)
Average severity | — | 1.0 | — | 1.7
Poly-3 test | 0.047* | 0.486 | — | 0.104
Litter-adjusted correlation | 0.23
Litter-adjusted Poly-3 rate | 0.0% | 4.1% | 0.0% | 11.6%
Litter-adjusted Poly-3 test | 0.100 | 0.147 | — | 0.071
Sire-adjusted correlation | 0.03
Sire-adjusted Poly-3 rate | 0.0% | 4.0% | 0.1% | 12.7%
Sire-adjusted Poly-3 test | 0.096 | 0.165 | — | 0.067
JT/SW test | 0.033* | 0.159 | 0.321 | 0.019*
Nose: Hyaline Droplet
Overall rate | 1/25 (4.0%) | 4/25 (16.0%) | 1/22 (4.5%) | 6/25 (24.0%)
Adjusted rate | 1/25.0 (4.0%) | 4/23.4 (17.1%) | 1/19.7 (5.1%) | 6/23.7 (25.3%)
Terminal incidence (days) | 1/25 (4.0%) | 4/22 (18.2%) | 1/19 (5.3%) | 6/21 (28.6%)
First incidence (days) | 320 (T) | 318 (T) | 318 (T) | 318 (T)
Average severity | 1.0 | 1.8 | 1.0 | 1.8
Poly-3 test | 0.046* | 0.152 | 0.705 | 0.040*
Litter-adjusted correlation | 0.31
Litter-adjusted Poly-3 rate | 4.6% | 15.9% | 6.6% | 26.1%
Litter-adjusted Poly-3 test | 0.058 | 0.120 | 0.401 | 0.027*
Sire-adjusted correlation | −0.03
Sire-adjusted Poly-3 rate | 4.1% | 17.1% | 5.0% | 25.0%
Sire-adjusted Poly-3 test | 0.074 | 0.091 | 0.443 | 0.030*
JT/SW test | 0.040* | 0.076 | 0.241 | 0.015*
Pancreas: Cellular Infiltration
Overall rate | 2/25 (8.0%) | 3/25 (12.0%) | 5/21 (23.8%) | 2/24 (8.3%)
Terminal incidence (days) | 2/25 (8.0%) | 3/22 (13.6%) | 5/19 (26.3%) | 1/21 (4.8%)
First incidence (days) | 316 (T) | 318 (T) | 318 (T) | 302
Average severity | 1.0 | 1.3 | 1.0 | 2.0
Adjusted rate | 2/25.0 (8.0%) | 3/23.4 (12.8%) | 5/19.7 (25.4%) | 2/23.5 (8.5%)
Poly-3 test | 0.393 | 0.469 | 0.119 | 0.673
Litter-adjusted correlation | −0.25
Litter-adjusted Poly-3 rate | 9.0% | 13.6% | 25.9% | 8.3%
Litter-adjusted Poly-3 test | 0.346 | 0.295 | 0.045* | 0.467N
Sire-adjusted correlation | −0.11
Sire-adjusted Poly-3 rate | 8.6% | 13.9% | 21.5% | 7.8%
Sire-adjusted Poly-3 test | 0.420 | 0.260 | 0.091 | 0.460N
JT/SW test | 0.308 | 0.307 | 0.078 | 0.262
Salivary Glands: Cellular Infiltration
Overall rate | 22/25 (88.0%) | 18/25 (72.0%) | 12/22 (54.5%) | 20/25 (80.0%)
Adjusted rate | 22/25.0 (88.0%) | 18/25.0 (72.0%) | 12/19.7 (61.0%) | 20/23.7 (84.3%)
Terminal incidence (days) | 22/25 (88.0%) | 15/22 (68.2%) | 12/19 (63.2%) | 20/21 (95.2%)
First incidence (days) | 316 (T) | 186 | 318 (T) | 317 (T)
Average severity | 1.4 | 1.5 | 1.3 | 1.4
Poly-3 test | 0.328N | 0.144N | 0.035N* | 0.516N
Litter-adjusted correlation | −0.12
Litter-adjusted Poly-3 rate | 88.3% | 72.3% | 59.9% | 84.4%
Litter-adjusted Poly-3 test | 0.225N | 0.053N | 0.004N** | 0.347N
Sire-adjusted correlation | −0.06
Sire-adjusted Poly-3 rate | 88.9% | 70.7% | 60.0% | 84.0%
Sire-adjusted Poly-3 test | 0.229N | 0.009N** | 0.002N** | 0.317N
JT/SW test | 0.175N | 0.173N | 0.012N* | 0.098N
Spleen: Hematopoietic Cell Proliferation
Overall rate | 2/25 (8.0%) | 2/25 (8.0%) | 8/22 (36.4%) | 7/25 (28.0%)
Adjusted rate | 2/25.0 (8.0%) | 2/23.9 (8.4%) | 8/22.0 (36.4%) | 7/23.8 (29.4%)
Terminal incidence (days) | 2/25 (8.0%) | 1/22 (4.5%) | 5/19 (26.3%) | 6/21 (28.6%)
First incidence (days) | 316 (T) | 249 | 101 | 312
Average severity | 2.5 | 2.5 | 2.0 | 2.6
Poly-3 test | 0.007** | 0.679 | 0.018* | 0.056
Litter-adjusted correlation | −0.18
Litter-adjusted Poly-3 rate | 8.7% | 8.7% | 37.0% | 30.4%
Litter-adjusted Poly-3 test | 0.003** | 0.499 | 0.004** | 0.023*
Sire-adjusted correlation | −0.04
Sire-adjusted Poly-3 rate | 7.9% | 9.1% | 36.3% | 29.5%
Sire-adjusted Poly-3 test | 0.003** | 0.442 | 0.004** | 0.018*
JT/SW test | 0.007** | 0.500 | 0.008** | 0.024*

(T) Terminal kill

a AZT/3TC/NVP-L = 80/50/56 mg/kg; AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg

b Number of lesion-bearing animals/number of animals examined microscopically

c Poly-3 estimated lesion incidence after adjustment for intercurrent mortality

d Observed incidence at terminal kill

e Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

f Beneath the vehicle control incidence is the P value associated with the Jonckheere/Terpstra monotonic trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group by William’s modified Shirley’s test. A negative trend or lower incidence in a dose group is indicated by N.

g Not applicable, no lesions in animal group

h Value of statistic cannot be computed.

TABLE G11 Litter-adjusted Statistical Analysis of Selected Nonneoplastic Lesions in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
Brain, Cerebrum: Mineralization
Overall rate^b^ | 2/25 (8.0%) | 0/24 (0.0%) | 0/25 (0.0%) | 3/24 (12.5%) | 0/23 (0.0%) | 0/25 (0.0%)
Adjusted rate^c^ | 2/25.0 (8.0%) | 0/23.1 (0.0%) | 0/23.2 (0.0%) | 3/22.7 (13.2%) | 0/20.7 (0.0%) | 0/23.7 (0.0%)
Terminal incidence^d^ | 2/25 (8.0%) | 0/20 (0.0%) | 0/20 (0.0%) | 3/20 (15.0%) | 0/19 (0.0%) | 0/21 (0.0%)
First incidence (days) | 318 (T) | —^f^ | — | 319 (T) | — | —
Average severity | 1.0 | —^f^ | — | 1.0 | — | —
| Vehicle Control | 0.253N | 0.252N | 0.455 | 0.279N | 0.247N
| | AZT-H | —^g^ | 0.110 | — | —
Poly-3 test^e^ | | | 3TC-H | 0.109 | — | —
| | | | NVP-H | 0.130N | 0.105N
| | | | | AZT/3TC-H | —
Litter-adjusted correlation | 0.02
Litter-adjusted Poly-3 rate | 8.1% | 0.0% | 0.0% | 13.3% | 0.0% | 0.0%
| Vehicle Control | 0.075N | 0.075N | 0.282 | 0.075N | 0.075N
| | AZT-H | — | 0.031* | — | —
Litter-adjusted Poly-3 test | | | 3TC-H | 0.031* | — | —
| | | | NVP-H | 0.031N* | 0.031N*
| | | | | AZT/3TC-H | —
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 8.0% | 0.0% | 0.0% | 13.2% | 0.0% | 0.0%
| Vehicle Control | 0.076N | 0.076N | 0.289 | 0.076N | 0.076N
| | AZT-H | — | 0.031* | — | —
Sire-adjusted Poly-3 test | | | 3TC-H | 0.031* | — | —
| | | | NVP-H | 0.031N* | 0.031N*
| | | | | AZT/3TC-H | —
Clitoral Gland: Acinus Degeneration
Overall rate | 9/24 (37.5%) | 12/24 (50.0%) | 6/23 (26.1%) | 5/21 (23.8%) | 6/21 (28.6%) | 11/22 (50.0%)
Adjusted rate | 9/24.0 (37.5%) | 12/23.4 (51.3%) | 6/21.7 (27.7%) | 5/20.6 (24.3%) | 6/19.2 (31.3%) | 11/22.0 (50.0%)
Terminal incidence | 9/24 (37.5%) | 10/20 (50.0%) | 6/20 (30.0%) | 3/18 (16.7%) | 5/17 (29.4%) | 9/20 (45.0%)
First incidence (days) | 316 (T) | 303 | 318 (T) | 257 | 264 | 275
Average severity | 2.9 | 3.2 | 3.0 | 3.4 | 3.2 | 2.7
| Vehicle Control | 0.255 | 0.349N | 0.270N | 0.460N | 0.292
| | AZT-H | 0.091N | 0.060N | 0.158N | 0.581N
Poly-3 test | | | 3TC-H | 0.541N | 0.534 | 0.112
| | | | NVP-H | 0.446 | 0.076
| | | | | AZT/3TC-H | 0.186
Litter-adjusted correlation | 0.03
Litter-adjusted Poly-3 rate | 37.7% | 51.3% | 27.6% | 24.5% | 31.2% | 50.0%
| Vehicle Control | 0.194 | 0.235N | 0.165N | 0.305N | 0.185
| | AZT-H | 0.069N | 0.043N* | 0.089N | 0.467N
Litter-adjusted Poly-3 test | | | 3TC-H | 0.411N | 0.393 | 0.055
| | | | NVP-H | 0.299 | 0.030*
| | | | | AZT/3TC-H | 0.071
Sire-adjusted correlation | 0.01
Sire-adjusted Poly-3 rate | 37.5% | 51.2% | 27.6% | 24.2% | 31.3% | 49.8%
| Vehicle Control | 0.169 | 0.265N | 0.188N | 0.322N | 0.179
| | AZT-H | 0.094N | 0.023N* | 0.052N | 0.464N
Sire-adjusted Poly-3 test | | | 3TC-H | 0.414N | 0.385 | 0.074
| | | | NVP-H | 0.259 | 0.015*
| | | | | AZT/3TC-H | 0.075
Harderian Gland: Cellular Infiltration
Overall rate | 2/25 (8.0%) | 0/24 (0.0%) | 0/25 (0.0%) | 0/25 (0.0%) | 1/23 (4.3%) | 0/24 (0.0%)
Adjusted rate | 2/25.0 (8.0%) | 0/23.1 (0.0%) | 0/23.2 (0.0%) | 0/23.2 (0.0%) | 1/20.7 (4.8%) | 0/23.3 (0.0%)
Terminal incidence | 2/25 (8.0%) | 0/20 (0.0%) | 0/20 (0.0%) | 0/20 (0.0%) | 1/19 (5.3%) | 0/21 (0.0%)
First incidence (days) | 316 (T) | — | — | — | 320 (T) | —
Average severity | 1.0 | — | — | — | 1.0 | —
| Vehicle Control | 0.253N | 0.252N | 0.253N | 0.566N | 0.251N
| | AZT-H | — | — | 0.478 | —
Poly-3 test | | | 3TC-H | — | 0.477 | —
| | | | NVP-H | 0.478 | —
| | | | | AZT/3TC-H | 0.476N
Litter-adjusted correlation | −0.03
Litter-adjusted Poly-3 rate | 8.1% | 0.0% | 0.0% | 0.0% | 4.8% | 0.0%
| Vehicle Control | 0.057N | 0.057N | 0.057N | 0.314N | 0.057N
| | AZT-H | — | — | 0.156 | —
Litter-adjusted Poly-3 test | | | 3TC-H | — | 0.156 | —
| | | | NVP-H | 0.156 | —
| | | | | AZT/3TC-H | 0.156N
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 8.1% | 0.0% | 0.0% | 0.0% | 4.8% | 0.0%
| Vehicle Control | 0.048N* | 0.048N* | 0.048N* | 0.322N | 0.048N*
| | AZT-H | — | — | 0.157 | —
Sire-adjusted Poly-3 test | | | 3TC-H | — | 0.157 | —
| | | | NVP-H | 0.156 | —
| | | | | AZT/3TC-H | 0.157N
Kidney: Protein Casts
Overall rate | 14/25 (56.0%) | 14/24 (58.3%) | 8/24 (33.3%) | 10/24 (41.7%) | 12/23 (52.2%) | 15/25 (60.0%)
Adjusted rate | 14/25.0 (56.0%) | 14/23.3 (60.0%) | 8/22.5 (35.6%) | 10/22.8 (43.9%) | 12/20.7 (58.0%) | 15/23.7 (63.2%)
Terminal incidence | 14/25 (56.0%) | 13/20 (65.0%) | 8/20 (40.0%) | 9/20 (45.0%) | 12/19 (63.2%) | 15/21 (71.4%)
First incidence (days) | 316 (T) | 297 | 318 (T) | 257 | 316 (T) | 317 (T)
Average severity | 1.1 | 1.0 | 1.0 | 1.0 | 1.0 | 1.2
| Vehicle Control | 0.504 | 0.131N | 0.294N | 0.565 | 0.413
| | AZT-H | 0.083N | 0.210N | 0.567N | 0.530
Poly-3 test | | | 3TC-H | 0.396 | 0.117 | 0.051
| | | | NVP-H | 0.266 | 0.148
| | | | | AZT/3TC-H | 0.480
Litter-adjusted correlation | −0.08
Litter-adjusted Poly-3 rate | 56.7% | 60.0% | 35.8% | 43.8% | 57.6% | 63.3%
| Vehicle Control | 0.393 | 0.077N | 0.185N | 0.473 | 0.302
| | AZT-H | 0.041N* | 0.118N | 0.425N | 0.389
Litter-adjusted Poly-3 test | | | 3TC-H | 0.308 | 0.074 | 0.029*
| | | | NVP-H | 0.175 | 0.086
| | | | | AZT/3TC-H | 0.332
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 56.1% | 59.9% | 35.4% | 44.1% | 58.3% | 63.4%
| Vehicle Control | 0.362 | 0.078N | 0.218N | 0.438 | 0.264
| | AZT-H | 0.042N* | 0.117N | 0.449N | 0.389
Sire-adjusted Poly-3 test | | | 3TC-H | 0.308 | 0.065 | 0.036*
| | | | NVP-H | 0.145 | 0.094
| | | | | AZT/3TC-H | 0.354
Kidney: Cellular Infiltration
Overall rate | 11/25 (44.0%) | 10/24 (41.7%) | 11/24 (45.8%) | 15/24 (62.5%) | 11/23 (47.8%) | 11/25 (44.0%)
Adjusted rate | 11/25.0 (44.0%) | 10/23.1 (43.3%) | 11/22.8 (48.2%) | 15/22.3 (67.3%) | 11/21.1 (52.2%) | 11/23.7 (46.4%)
Terminal incidence | 11/25 (44.0%) | 10/20 (50.0%) | 10/20 (50.0%) | 15/20 (75.0%) | 10/19 (52.6%) | 11/21 (52.4%)
First incidence (days) | 316 (T) | 316 (T) | 277 | 318 (T) | 280 | 318 (T)
Average severity | 1.4 | 1.2 | 1.0 | 1.1 | 1.3 | 1.2
| Vehicle Control | 0.594N | 0.501 | 0.090 | 0.399 | 0.548
| | AZT-H | 0.487 | 0.086 | 0.386 | 0.533
Poly-3 test | | | 3TC-H | 0.153 | 0.513 | 0.567N
| | | | NVP-H | 0.237N | 0.122N
| | | | | AZT/3TC-H | 0.463N
Litter-adjusted correlation | −0.16
Litter-adjusted Poly-3 rate | 44.6% | 41.8% | 47.7% | 66.3% | 51.3% | 45.6%
| Vehicle Control | 0.416N | 0.411 | 0.030* | 0.309 | 0.468
| | AZT-H | 0.345 | 0.025* | 0.254 | 0.392
Litter-adjusted Poly-3 test | | | 3TC-H | 0.084 | 0.406 | 0.444N
| | | | NVP-H | 0.127N | 0.051N
| | | | | AZT/3TC-H | 0.346N
Sire-adjusted correlation | 0.04
Sire-adjusted Poly-3 rate | 44.2% | 43.7% | 49.7% | 67.1% | 51.9% | 45.5%
| Vehicle Control | 0.483N | 0.354 | 0.035* | 0.308 | 0.455
| | AZT-H | 0.334 | 0.016* | 0.281 | 0.440
Sire-adjusted Poly-3 test | | | 3TC-H | 0.114 | 0.437 | 0.391N
| | | | NVP-H | 0.109N | 0.035N*
| | | | | AZT/3TC-H | 0.330N
Kidney: Hydronephrosis
Overall rate | 0/25 (0.0%) | 0/24 (0.0%) | 0/24 (0.0%) | 0/24 (0.0%) | 0/23 (0.0%) | 3/25 (12.0%)
Adjusted rate | 0/25.0 (0.0%) | 0/23.1 (0.0%) | 0/22.5 (0.0%) | 0/22.3 (0.0%) | 0/20.7 (0.0%) | 3/24.5 (12.2%)
Terminal incidence | 0/25 (0.0%) | 0/20 (0.0%) | 0/20 (0.0%) | 0/20 (0.0%) | 0/19 (0.0%) | 1/21 (4.8%)
First incidence (days) | — | — | — | — | — | 247
Average severity | — | — | — | — | — | 3.0
| Vehicle Control | — | — | — | — | 0.110
| | AZT-H | — | — | — | 0.124
Poly-3 test | | | 3TC-H | — | — | 0.130
| | | | NVP-H | — | 0.131
| | | | | AZT/3TC-H | 0.146
Litter-adjusted correlation | −0.03
Litter-adjusted Poly-3 rate | 0.0% | 0.0% | 0.0% | 0.0% | 0.0% | 12.3%
| Vehicle Control | — | — | — | — | 0.026*
| | AZT-H | — | — | — | 0.026*
Litter-adjusted Poly-3 test | | | 3TC-H | — | — | 0.026*
| | | | NVP-H | — | 0.026*
| | | | | AZT/3TC-H | 0.026*
Sire-adjusted correlation | 0.00
Sire-adjusted Poly-3 rate | 0.0% | 0.0% | 0.0% | 0.0% | 0.0% | 12.3%
| Vehicle Control | — | — | — | — | 0.026*
| | AZT-H | — | — | — | 0.026*
Sire-adjusted Poly-3 test | | | 3TC-H | — | — | 0.026*
| | | | NVP-H | — | 0.026*
| | | | | AZT/3TC-H | 0.026*
Liver: Centrilobular Degeneration
Overall rate | 0/25 (0.0%) | 0/25 (0.0%) | 0/23 (0.0%) | 1/24 (4.2%) | 0/23 (0.0%) | 3/25 (12.0%)
Adjusted rate | 0/25.0 (0.0%) | 0/23.8 (0.0%) | 0/21.7 (0.0%) | 1/22.3 (4.5%) | 0/20.7 (0.0%) | 3/23.8 (12.6%)
Terminal incidence | 0/25 (0.0%) | 0/20 (0.0%) | 0/20 (0.0%) | 1/20 (5.0%) | 0/19 (0.0%) | 2/21 (9.5%)
First incidence (days) | — | — | — | 320 (T) | — | 312
Average severity | — | — | — | 2.0 | — | 2.7
| Vehicle Control | — | — | 0.477 | — | 0.105
| | AZT-H | — | 0.487 | — | 0.114
Poly-3 test | | | 3TC-H | 0.505 | — | 0.131
| | | | NVP-H | 0.515N | 0.327
| | | | | AZT/3TC-H | 0.140
Litter-adjusted correlation | −0.06
Litter-adjusted Poly-3 rate | 0.0% | 0.0% | 0.0% | 4.6% | 0.0% | 12.8%
| Vehicle Control | — | — | 0.145 | — | 0.024*
| | AZT-H | — | 0.145 | — | 0.024*
Litter-adjusted Poly-3 test | | | 3TC-H | 0.145 | — | 0.024*
| | | | NVP-H | 0.145N | 0.146
| | | | | AZT/3TC-H | 0.024*
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 0.0% | 0.0% | 0.0% | 4.5% | 0.0% | 12.6%
| Vehicle Control | — | — | 0.145 | — | 0.025*
| | AZT-H | — | 0.145 | — | 0.025*
Sire-adjusted Poly-3 test | | | 3TC-H | 0.145 | — | 0.025*
| | | | NVP-H | 0.145N | 0.147
| | | | | AZT/3TC-H | 0.025*
Liver: Cytoplasmic Vacuolization
Overall rate | 14/25 (56.0%) | 13/25 (52.0%) | 14/23 (60.9%) | 11/24 (45.8%) | 13/23 (56.5%) | 15/25 (60.0%)
Adjusted rate | 14/25.0 (56.0%) | 13/24.1 (54.0%) | 14/22.1 (63.3%) | 11/22.7 (48.4%) | 13/21.1 (61.7%) | 15/23.8 (62.9%)
Terminal incidence | 14/25 (56.0%) | 11/20 (55.0%) | 13/20 (65.0%) | 10/20 (50.0%) | 12/19 (63.2%) | 14/21 (66.7%)
First incidence (days) | 316 (T) | 303 | 271 | 268 | 280 | 312
Average severity | 1.1 | 1.4 | 1.3 | 1.5 | 1.8 | 1.7
| Vehicle-Control | 0.559N | 0.417 | 0.409N | 0.464 | 0.422
| | AZT-H | 0.367 | 0.464N | 0.413 | 0.371
Poly-3 test | | | 3TC-H | 0.240N | 0.582N | 0.610N
| | | | NVP-H | 0.280 | 0.240
| | | | | AZT/3TC-H | 0.590
Litter-adjusted correlation | −0.13
Litter-adjusted Poly-3 rate | 55.5% | 54.0% | 63.1% | 48.2% | 60.9% | 62.4%
| Vehicle-Control | 0.458N | 0.296 | 0.296N | 0.348 | 0.310
| | AZT-H | 0.261 | 0.338N | 0.309 | 0.274
Litter-adjusted Poly-3 test | | | 3TC-H | 0.124N | 0.433N | 0.480N
| | | | NVP-H | 0.155 | 0.132
| | | | | AZT/3TC-H | 0.453
Sire-adjusted correlation | −0.05
Sire-adjusted Poly-3 rate | 54.7% | 54.5% | 62.8% | 47.3% | 58.1% | 60.2%
| Vehicle-Control | 0.493N | 0.296 | 0.305N | 0.405 | 0.369
| | AZT-H | 0.291 | 0.305N | 0.410 | 0.335
Sire-adjusted Poly-3 test | | | 3TC-H | 0.127N | 0.322N | 0.426N
| | | | NVP-H | 0.211 | 0.154
| | | | | AZT/3TC-H | 0.441
Liver: Tension Lipidosis
Overall rate | 2/25 (8.0%) | 0/25 (0.0%) | 2/23 (8.7%) | 3/24 (12.5%) | 2/23 (8.7%) | 3/25 (12.0%)
Adjusted rate | 2/25.0 (8.0%) | 0/23.8 (0.0%) | 2/21.7 (9.2%) | 3/22.3 (13.5%) | 2/20.7 (9.7%) | 3/23.8 (12.6%)
Terminal incidence | 2/25 (8.0%) | 0/20 (0.0%) | 2/20 (10.0%) | 3/20 (15.0%) | 2/19 (10.5%) | 2/21 (9.5%)
First incidence (days) | 320 (T) | — | 320 (T) | 320 (T) | 320 (T) | 312
Average severity | 1.0 | — | 1.0 | 1.7 | 1.5 | 2.0
| Vehicle Control | 0.247N | 0.643 | 0.447 | 0.625 | 0.478
| | AZT-H | 0.214 | 0.101 | 0.204 | 0.114
Poly-3 test | | | 3TC-H | 0.512 | 0.679 | 0.544
| | | | NVP-H | 0.534N | 0.634N
| | | | | AZT/3TC-H | 0.565
Litter-adjusted correlation | −0.11
Litter-adjusted Poly-3 rate | 8.0% | 0.0% | 9.4% | 13.4% | 9.6% | 12.5%
| Vehicle Control | 0.066N | 0.426 | 0.263 | 0.420 | 0.294
| | AZT-H | 0.056 | 0.024* | 0.063 | 0.028*
Litter-adjusted Poly-3 test | | | 3TC-H | 0.329 | 0.492 | 0.363
| | | | NVP-H | 0.340N | 0.462N
| | | | | AZT/3TC-H | 0.374
Sire-adjusted correlation | 0.03
Sire-adjusted Poly-3 rate | 8.0% | 0.0% | 9.5% | 13.3% | 9.6% | 12.3%
| Vehicle Control | 0.072N | 0.425 | 0.302 | 0.428 | 0.326
| | AZT-H | 0.047* | 0.025* | 0.062 | 0.031*
Sire-adjusted Poly-3 test | | | 3TC-H | 0.327 | 0.491 | 0.379
| | | | NVP-H | 0.319N | 0.453N
| | | | | AZT/3TC-H | 0.358
Lymph Node, Mandibular: Hyperplasia
Overall rate | 3/25 (12.0%) | 0/25 (0.0%) | 3/24 (12.5%) | 4/24 (16.7%) | 2/23 (8.7%) | 1/25 (4.0%)
Adjusted rate | 3/25.0 (12.0%) | 0/23.8 (0.0%) | 3/23.4 (12.8%) | 4/22.3 (18.0%) | 2/20.7 (9.7%) | 1/23.7 (4.2%)
Terminal incidence | 3/25 (12.0%) | 0/20 (0.0%) | 1/20 (5.0%) | 4/20 (20.0%) | 2/19 (10.5%) | 1/21 (4.8%)
First incidence (days) | 316 (T) | | 258 | 318 (T) | 316 (T) | 320 (T)
Average severity | 2.3 | — | 1.7 | 1.5 | 1.5 | 2.0
| Vehicle Control | 0.123N | 0.634 | 0.436 | 0.586N | 0.322N
| | AZT-H | 0.110 | 0.046* | 0.204 | 0.500
Poly-3 test | | | 3TC-H | 0.473 | 0.556N | 0.297N
| | | | NVP-H | 0.367N | 0.152N
| | | | | AZT/3TC-H | 0.452N
Litter-adjusted correlation | −0.11
Litter-adjusted Poly-3 rate | 12.2% | 0.0% | 12.7% | 17.5% | 9.6% | 4.4%
| Vehicle Control | 0.025N* | 0.476 | 0.292 | 0.386N | 0.149N
| | AZT-H | 0.026* | 0.011* | 0.063 | 0.145
Litter-adjusted Poly-3 test | | | 3TC-H | 0.315 | 0.366N | 0.142N
| | | | NVP-H | 0.211N | 0.065N
| | | | | AZT/3TC-H | 0.245N
Sire-adjusted correlation | −0.02
Sire-adjusted Poly-3 rate | 12.2% | 0.0% | 12.6% | 18.0% | 9.4% | 4.2%
| Vehicle Control | 0.026N* | 0.480 | 0.247 | 0.352N | 0.155N
| | AZT-H | 0.027* | 0.010** | 0.069 | 0.145
Sire-adjusted Poly-3 test | | | 3TC-H | 0.306 | 0.357N | 0.137N
| | | | NVP-H | 0.202N | 0.068N
| | | | | AZT/3TC-H | 0.262N
Nose: Hyaline Droplet
Overall rate | 1/25 (4.0%) | 3/25 (12.0%) | 4/25 (16.0%) | 1/24 (4.2%) | 6/24 (25.0%) | 6/25 (24.0%)
Adjusted rate | 1/25.0 (4.0%) | 3/23.8 (12.6%) | 4/23.2 (17.2%) | 1/22.3 (4.5%) | 6/20.7 (28.9%) | 6/23.7 (25.3%)
Terminal incidence | 1/25 (4.0%) | 3/20 (15.0%) | 4/20 (20.0%) | 1/20 (5.0%) | 6/19 (31.6%) | 6/21 (28.6%)
First incidence (days) | 320 (T) | 320 (T) | 320 (T) | 318 (T) | 320 (T) | 318 (T)
Average severity | 1.0 | 1.3 | 1.5 | 1.0 | 1.8 | 1.8
| Vehicle Control | 0.284 | 0.150 | 0.734 | 0.024* | 0.040*
| | AZT-H | 0.487 | 0.326N | 0.165 | 0.230
Poly-3 test | | | 3TC-H | 0.184N | 0.288 | 0.376
| | | | NVP-H | 0.035* | 0.056
| | | | | AZT/3TC-H | 0.526N
Litter-adjusted correlation | 0.17
Litter-adjusted Poly-3 rate | 4.4% | 12.9% | 17.2% | 4.3% | 27.7% | 25.8%
| Vehicle Control | 0.145 | 0.063 | 0.496N | 0.030* | 0.026*
| | AZT-H | 0.334 | 0.140N | 0.137 | 0.148
Litter-adjusted Poly-3 test | | | 3TC-H | 0.059N | 0.221 | 0.246
| | | | NVP-H | 0.029* | 0.025*
| | | | | AZT/3TC-H | 0.449N
Sire-adjusted correlation | −0.06
Sire-adjusted Poly-3 rate | 4.7% | 12.9% | 15.5% | 3.8% | 26.1% | 25.8%
| Vehicle Control | 0.143 | 0.088 | 0.440N | 0.049* | 0.030*
| | AZT-H | 0.399 | 0.127N | 0.173 | 0.144
Sire-adjusted Poly-3 test | | | 3TC-H | 0.076N | 0.230 | 0.220
| | | | NVP-H | 0.044* | 0.025*
| | | | | AZT/3TC-H | 0.491N
Ovary: Cyst
Overall rate | 1/25 (4.0%) | 3/24 (12.5%) | 1/25 (4.0%) | 2/24 (8.3%) | 3/23 (13.0%) | 0/25 (0.0%)
Adjusted rate | 1/25.0 (4.0%) | 3/23.1 (13.0%) | 1/23.2 (4.3%) | 2/22.3 (9.0%) | 3/21.7 (13.8%) | 0/23.7 (0.0%)
Terminal incidence | 1/25 (4.0%) | 3/20 (15.0%) | 1/20 (5.0%) | 2/20 (10.0%) | 2/19 (10.5%) | 0/21 (0.0%)
First incidence (days) | 321 (T) | 318 (T) | 320 (T) | 320 (T) | 102 | —
Average severity | 2.0 | 2.3 | 2.0 | 2.0 | 2.0 | —
| Vehicle Control | 0.274 | 0.744 | 0.460 | 0.252 | 0.510N
| | AZT-H | 0.300N | 0.517N | 0.636 | 0.108N
Poly-3 test | | | 3TC-H | 0.485 | 0.276 | 0.496N
| | | | NVP-H | 0.487 | 0.220N
| | | | | AZT/3TC-H | 0.097N
Litter-adjusted correlation | −0.11
Litter-adjusted Poly-3 rate | 3.8% | 13.2% | 4.4% | 8.8% | 14.3% | 0.0%
| Vehicle Control | 0.108 | 0.453 | 0.234 | 0.088 | 0.157N
| | AZT-H | 0.132N | 0.308N | 0.453 | 0.024N*
Litter-adjusted Poly-3 test | | | 3TC-H | 0.272 | 0.109 | 0.146N
| | | | NVP-H | 0.268 | 0.066N
| | | | | AZT/3TC-H | 0.018N*
Sire-adjusted correlation | —
Sire-adjusted Poly-3 rate | — | — | — | — | — | —
| Vehicle Control | — | — | — | — | —
| | AZT-H | — | — | — | —
Sire-adjusted Poly-3 test | | | 3TC-H | — | — | —
| | | | NVP-H | — | —
| | | | | AZT/3TC-H | —
Spleen: Hematopoietic Cell Proliferation
Overall rate | 2/25 (8.0%) | 8/25 (32.0%) | 7/24 (29.2%) | 6/24 (25.0%) | 6/23 (26.1%) | 7/25 (28.0%)
Adjusted rate | 2/25.0 (8.0%) | 8/24.6 (32.5%) | 7/23.5 (29.8%) | 6/22.3 (26.9%) | 6/21.1 (28.5%) | 7/23.8 (29.4%)
Terminal incidence | 2/25 (8.0%) | 4/20 (20.0%) | 4/20 (20.0%) | 6/20 (30.0%) | 5/19 (26.3%) | 6/21 (28.6%)
First incidence (days) | 316 (T) | 284 | 271 | 318 (T) | 280 | 312
Average severity | 2.5 | 2.8 | 3.1 | 2.5 | 2.5 | 2.6
| Vehicle Control | 0.032* | 0.053 | 0.087 | 0.073 | 0.056
| | AZT-H | 0.543N | 0.462N | 0.512N | 0.529N
Poly-3 test | | | 3TC-H | 0.545N | 0.591N | 0.611N
| | | | NVP-H | 0.588 | 0.557
| | | | | AZT/3TC-H | 0.603
Litter-adjusted correlation | 0.15
Litter-adjusted Poly-3 rate | 7.5% | 32.4% | 30.6% | 26.7% | 28.0% | 28.6%
| Vehicle Control | 0.012* | 0.024* | 0.041* | 0.036* | 0.021*
| | AZT-H | 0.452N | 0.344N | 0.381N | 0.391N
Litter-adjusted Poly-3 test | | | 3TC-H | 0.395N | 0.431N | 0.443N
| | | | NVP-H | 0.464 | 0.445
| | | | | AZT/3TC-H | 0.483
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 8.0% | 32.2% | 29.6% | 27.1% | 28.3% | 29.6%
| Vehicle Control | 0.023* | 0.032* | 0.048* | 0.013* | 0.017*
| | AZT-H | 0.418N | 0.368N | 0.394N | 0.433N
Sire-adjusted Poly-3 test | | | 3TC-H | 0.432N | 0.465N | 0.499
| | | | NVP-H | 0.470 | 0.424
| | | | | AZT/3TC-H | 0.465
Thymus: Hyperplasia
Overall rate | 6/25 (24.0%) | 2/21 (9.5%) | 2/22 (9.1%) | 8/22 (36.4%) | 6/24 (25.0%) | 5/24 (20.8%)
Adjusted rate | 6/25.0 (24.0%) | 2/20.4 (9.8%) | 2/21.1 (9.5%) | 8/20.7 (38.6%) | 6/20.7 (28.9%) | 5/22.8 (21.9%)
Terminal incidence | 6/25 (24.0%) | 2/19 (10.5%) | 2/20 (10.0%) | 8/19 (42.1%) | 6/19 (31.6%) | 5/21 (23.8%)
First incidence (days) | 316 (T) | 319 (T) | 321 (T) | 318 (T) | 316 (T) | 318 (T)
Average severity | 2.2 | 2.0 | 2.5 | 2.0 | 2.0 | 2.2
| Vehicle Control | 0.197N | 0.184N | 0.230 | 0.485 | 0.566N
| | AZT-H | 0.684N | 0.032* | 0.122 | 0.255
Poly-3 test | | | 3TC-H | 0.027* | 0.112 | 0.240
| | | | NVP-H | 0.371N | 0.191N
| | | | | AZT/3TC-H | 0.428N
Litter-adjusted correlation | −0.26
Litter-adjusted Poly-3 rate | 24.8% | 8.6% | 8.6% | 39.0% | 29.3% | 23.2%
| Vehicle Control | 0.046N* | 0.043N* | 0.125 | 0.341 | 0.441N
| | AZT-H | 0.499N | 0.005** | 0.022* | 0.063
Litter-adjusted Poly-3 test | | | 3TC-H | 0.004** | 0.020* | 0.060
| | | | NVP-H | 0.226N | 0.101N
| | | | | AZT/3TC-H | 0.291N
Sire-adjusted correlation | 0.03
Sire-adjusted Poly-3 rate | 24.1% | 9.6% | 10.4% | 38.7% | 29.9% | 21.6%
| Vehicle Control | 0.077N | 0.068N | 0.130 | 0.273 | 0.397N
| | AZT-H | 0.463 | 0.004** | 0.027* | 0.043*
Sire-adjusted Poly-3 test | | | 3TC-H | 0.008** | 0.031* | 0.110
| | | | NVP-H | 0.255N | 0.043N*
| | | | | AZT/3TC-H | 0.235N
Thyroid Gland: Ectopic Thymus
Overall rate | 3/23 (13.0%) | 0/24 (0.0%) | 1/25 (4.0%) | 0/23 (0.0%) | 1/22 (4.5%) | 2/25 (8.0%)
Adjusted rate | 3/23.0 (13.0%) | 0/22.8 (0.0%) | 1/23.2 (4.3%) | 0/21.8 (0.0%) | 1/20.7 (4.8%) | 2/24.1 (8.3%)
Terminal incidence | 3/23 (13.0%) | 0/19 (0.0%) | 1/20 (5.0%) | 0/20 (0.0%) | 1/19 (5.3%) | 1/21 (4.8%)
First incidence (days) | 316 (T) | — | 320 (T) | — | 320 (T) | 275
| Vehicle Control | 0.115N | 0.298N | 0.123N | 0.342N | 0.478N
| | AZT-H | 0.504 | — | 0.481 | 0.248
Poly-3 test | | | 3TC-H | 0.513N | 0.735 | 0.513
| | | | NVP-H | 0.489 | 0.258
| | | | | AZT/3TC-H | 0.554
Litter-adjusted correlation | −0.11
Litter-adjusted Poly-3 rate | 13.7% | 0.0% | 4.4% | 0.0% | 4.5% | 8.7%
| Vehicle Control | 0.017N* | 0.116N | 0.017N* | 0.123N | 0.277N
| | AZT-H | 0.146 | — | 0.157 | 0.056
Litter-adjusted Poly-3 test | | | 3TC-H | 0.146N | 0.494 | 0.269
| | | | NVP-H | 0.157 | 0.056
| | | | | AZT/3TC-H | 0.279
Sire-adjusted correlation | 0.01
Sire-adjusted Poly-3 rate | 13.1% | 0.0% | 4.3% | 0.0% | 4.8% | 8.3%
| Vehicle Control | 0.020N* | 0.129N | 0.020N* | 0.151N | 0.293N
| | AZT-H | 0.146 | — | 0.160 | 0.057
Sire-adjusted Poly-3 test | | | 3TC-H | 0.146N | 0.471 | 0.153
| | | | NVP-H | 0.160 | 0.056
| | | | | AZT/3TC-H | 0.314
Urinary Bladder: Cellular Infiltration
Overall rate | 8/25 (32.0%) | 4/24 (16.7%) | 8/24 (33.3%) | 4/23 (17.4%) | 8/23 (34.8%) | 3/25 (12.0%)
Adjusted rate | 8/25.0 (32.0%) | 4/23.1 (17.3%) | 8/23.0 (34.8%) | 4/21.8 (18.3%) | 8/21.1 (38.0%) | 3/23.7 (12.6%)
Terminal incidence | 8/25 (32.0%) | 4/20 (20.0%) | 7/20 (35.0%) | 4/20 (20.0%) | 7/19 (36.8%) | 3/21 (14.3%)
First incidence (days) | 316 (T) | 318 (T) | 258 | 320 (T) | 280 | 318 (T)
Average severity | 1.1 | 1.3 | 1.1 | 1.0 | 1.0 | 1.0
| Vehicle Control | 0.201N | 0.538 | 0.234N | 0.455 | 0.100N
| | AZT-H | 0.153 | 0.616 | 0.113 | 0.485N
Poly-3 test | | | 3TC-H | 0.181N | 0.538 | 0.071N
| | | | NVP-H | 0.136 | 0.453N
| | | | | AZT/3TC-H | 0.049N*
Litter-adjusted correlation | 0.07
Litter-adjusted Poly-3 rate | 32.1% | 17.7% | 35.2% | 18.2% | 38.1% | 12.9%
| Vehicle Control | 0.108N | 0.418 | 0.107N | 0.333 | 0.038N*
| | AZT-H | 0.114 | 0.480 | 0.068 | 0.327N
Litter-adjusted Poly-3 test | | | 3TC-H | 0.116N | 0.429 | 0.055N
| | | | NVP-H | 0.068 | 0.299N
| | | | | AZT/3TC-H | 0.027N*
Sire-adjusted correlation | 0.07
Sire-adjusted Poly-3 rate | 33.7% | 18.1% | 36.0% | 18.6% | 40.3% | 12.9%
| Vehicle Control | 0.072N | 0.430 | 0.064N | 0.305 | 0.025N*
| | AZT-H | 0.093 | 0.480 | 0.048* | 0.240N
Sire-adjusted Poly-3 test | | | 3TC-H | 0.118N | 0.401 | 0.036N*
| | | | NVP-H | 0.069 | 0.288N
| | | | | AZT/3TC-H | 0.012N*
Uterus: Endometrium Hyperplasia
Overall rate | 22/25 (88.0%) | 19/25 (76.0%) | 19/25 (76.0%) | 19/23 (82.6%) | 17/23 (73.9%) | 17/25 (68.0%)
Adjusted rate | 22/25.0 (88.0%) | 19/24.3 (78.2%) | 19/23.7 (80.3%) | 19/22.1 (86.1%) | 17/21.5 (79.0%) | 17/24.1 (70.5%)
Terminal incidence | 22/25 (88.0%) | 16/20 (80.0%) | 18/20 (90.0%) | 18/20 (90.0%) | 15/19 (78.9%) | 16/21 (76.2%)
First incidence (days) | 316 (T) | 297 | 271 | 297 | 264 | 275
Average severity | 1.8 | 1.4 | 1.8 | 2.1 | 1.4 | 1.9
| Vehicle Control | 0.293N | 0.362N | 0.599N | 0.332N | 0.116N
| | AZT-H | 0.572 | 0.371 | 0.618 | 0.385N
Poly-3 test | | | 3TC-H | 0.445 | 0.605N | 0.319N
| | | | NVP-H | 0.409N | 0.167N
| | | | | AZT/3TC-H | 0.374N
Litter-adjusted correlation | −0.05
Litter-adjusted Poly-3 rate | 88.1% | 78.4% | 80.8% | 85.9% | 79.3% | 70.5%
| Vehicle Control | 0.167N | 0.234N | 0.397N | 0.205N | 0.054N
| | AZT-H | 0.411 | 0.223 | 0.469 | 0.254N
Litter-adjusted Poly-3 test | | | 3TC-H | 0.304 | 0.446N | 0.191N
| | | | NVP-H | 0.265N | 0.076N
| | | | | AZT/3TC-H | 0.240N
Sire-adjusted correlation | 0.01
Sire-adjusted Poly-3 rate | 87.7% | 77.9% | 80.1% | 85.6% | 78.6% | 70.4%
| Vehicle Control | 0.149N | 0.246N | 0.404N | 0.214N | 0.050N*
| | AZT-H | 0.405 | 0.215 | 0.471 | 0.266N
Sire-adjusted Poly-3 test | | | 3TC-H | 0.282 | 0.451N | 0.224N
| | | | NVP-H | 0.255N | 0.078N
| | | | | AZT/3TC-H | 0.225N

(T) Terminal kill

a AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b Number of lesion-bearing animals/number of animals with tissue examined microscopically

c Poly-3 estimated lesion incidence after adjustment for intercurrent mortality

d Observed incidence at terminal kill

e Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between that dosed group and the group stated to the left on the same row. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in a dose group is indicated by N.

f Not applicable; no neoplasms in animal group

g Value of statistic cannot be computed.