# APPENDIX F CHEMICAL CHARACTERIZATION AND DOSE FORMULATION STUDIES

## Procurement and Characterization

AZT, 3TC, and NVP were obtained from Cipla Ltd., Mumbai Central (Mumbai, India) in single lots F60731, B10250, and FX1009, respectively. Identity and purity analyses were conducted by the study laboratory at the National Center for Toxicological Research (NCTR; Jefferson, AR) and Galbraith Laboratories, Inc. (Knoxville, TN). To ensure stability, the bulk chemicals were stored in sealed amber jars at room temperature. Reports on analyses performed in support of the AZT, 3TC, and NVP in utero/postnatal gavage study are on file at the NCTR.

### AZT

Lot F60731 of the chemical, a white-to-beige crystalline solid, was identified as AZT by the study laboratory using proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy, direct exposure probe/electron ionization (DEP/EI) mass spectrometry (MS), and liquid chromatography combined with mass spectrometry (LC-MS). All spectra were consistent with the structure of AZT, reference spectra, and spectra of AZT samples obtained from Sigma-Aldrich^®^ Corporation (St. Louis, MO) or spectra of a previously characterized lot (Cipla lot FX4159) used in preceding studies (NTP, 2013a,b). A representative proton NMR spectrum is presented in Figure F1.

The study laboratory assessed the purity of the bulk chemical by proton and carbon-13 NMR spectroscopy and high-performance liquid chromatography (HPLC). HPLC was conducted with a Waters Millennium^32^ system using photodiode array (PDA) detection at 254 nm (Waters Corporation, Milford, MA). The analytical column was a Nova-Pak^®^ (3.9 mm × 150 mm, 4 µm particle size, and 60 Å pore size) C18 column (Waters Corporation). The mobile phase (1 mL/minute) was held at 5% acetonitrile:95% water for 5 minutes and then linearly changed to 95% acetonitrile:5% water over 20 minutes, followed by a final 5-minute hold.

No impurity resonances were detected by either proton or carbon-13 NMR analyses other than those associated with the solvent. HPLC-PDA detected no impurities with an overall purity of approximately 100%. The overall purity of lot F60731 was determined to be at least 99.9%.

### 3TC

Lot B10250 of the chemical, a white-to-off-white crystalline solid, was identified as 3TC by the study laboratory using proton NMR spectroscopy, DEP/EI-MS, and LC-MS. All spectra were consistent with the structure of 3TC and/or the spectra of a 3TC sample obtained from GlaxoWellcome (Research Triangle Park, NC). A representative proton NMR spectrum is presented in Figure F2.

The study laboratory assessed the purity of the bulk chemical by proton NMR spectroscopy and the same HPLC-PDA system used to estimate the purity of lot F60731 of AZT.

Total impurity was estimated at 0.5% by proton NMR spectroscopy. HPLC-PDA detected one impurity with a peak area of 1.1% of the total peak area and estimated a purity of approximately 98.9%. The overall purity of lot B10250 was estimated to be approximately 99%.

### NVP

Lot FX1009 of the chemical, a white-to-off-white crystalline powder, was identified as NVP by the study laboratory using proton NMR spectroscopy, DEP/EI-MS, gas chromatography/electron ionization MS, and LC-MS. All spectra were consistent with the structure of NVP, literature spectra, and/or the spectra of an NVP sample obtained from Boehringer/Ingelheim (Ridgefield, CT). A representative proton NMR spectrum is presented in Figure F3.

Karl Fischer titration and elemental analyses of lot FX1009 were performed by Galbraith Laboratories, Inc., and the study laboratory assessed the purity of the bulk chemical by proton NMR spectroscopy and the same HPLC-PDA system used to estimate the purity of lot F60731 of AZT.

For lot FX1009, Karl Fischer titration indicated less than 0.14% water. Elemental analyses for carbon, hydrogen, and nitrogen were in agreement with the theoretical values for NVP. Total impurity was estimated at 0.2% by proton NMR. HPLC-PDA detected a single peak, indicating that the test article was 100.0% pure. The overall purity of lot FX1009 was estimated to be at least 99.5%.

### Dosing Vehicle

The vehicle used for dose formulations in this study was a 0.2% methylcellulose/0.1% Tween^®^ 80 aqueous solution. This vehicle was selected based upon preliminary experiments to find a vehicle that gave homogeneous formulations of the individual test articles and the test article combinations. Methylcellulose was obtained from Sigma-Aldrich Corporation (St. Louis, MO) in two lots (084K0065 and 125K0055) and Tween^®^ 80 was obtained from the same source in three lots (073K00643, 064K00631 and 125K01921). Proton and carbon-13 NMR analyses of methylcellulose lot 084K0065 were performed by the study laboratory, and spectra were consistent with those obtained previously for a methylcellulose standard obtained from Fischer Scientific (Fair Lawn, NJ).

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared by admixing the test chemicals with an aqueous solution of 0.2% methylcellulose/0.1% Tween^®^ 80 to give the required concentrations (Table F1). AZT and 3TC formed true solutions at the concentrations used, whereas NVP was insoluble and formed stable suspensions. The dose formulations were stored (with constant stirring) in sealed amber glass bottles at room temperature for up to 21 days.

Homogeneity and stability studies of 0.05 and 0.20 mg/mL formulations of AZT in the methylcellulose/Tween^®^ 80 vehicle and of high- and low-concentration mixtures of the three test chemicals in the dosing vehicle were conducted by the study laboratory using HPLC. For these analyses, the same Waters HPLC-PDA system was used as for the bulk chemical purity determinations except that the solvent program was a 3-minute linear gradient from 100% mobile phase A (methanol:water, 5:95; 0.005 M sodium phosphate monobasic, 0.003 M sodium pentanesulfonic acid; pH 2.5) to 100% mobile phase B (methanol:water, 90:10; 0.005 M sodium phosphate monobasic, 0.003 M sodium pentanesulfonic acid; pH 2.5) followed by a 10.5-minute hold. The high-concentration mixture was composed of AZT (20 mg/mL), 3TC (10 mg/mL), and NVP (13.3 mg/mL), and the low-concentration mixture was composed of AZT (6.66 mg/mL), 3TC (3.33 mg/mL), and NVP (4.4 mg/mL). Homogeneity was confirmed, and stability was confirmed for up to 29 days for the AZT formulations and for up to 21 days for the three-component formulations stored at room temperature in clear glass vials sealed with Teflon^®^ lined silicone rubber septa, that were stirred constantly.

At fifteen time points, analyses of the dose formulations of the antiretroviral drugs were conducted by the study laboratory using HPLC-PDA by the system described above for the homogeneity and stability studies. Of the 161 measured concentrations of test chemical, 139 were within 10% of the target concentration; all preparations that were accepted for use were within 15% of their target concentrations (Table F2).

FIGURE F1 Proton Nuclear Magnetic Resonance Spectrum of AZT

Proton Nuclear Magnetic Resonance Spectrum of AZT

FIGURE F2 Proton Nuclear Magnetic Resonance Spectrum of 3TC

Proton Nuclear Magnetic Resonance Spectrum of 3TC

FIGURE F3 Proton Nuclear Magnetic Resonance Spectrum of NVP

Proton Nuclear Magnetic Resonance Spectrum of NVP

TABLE F1 Preparation and Storage of Dose Formulations in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP

Preparation
Weighed amounts of the test chemicals were homogenized into an even suspension in 80% of the required volume of an aqueous solution of 0.2% methylcellulose and 0.1% Tween® 80 that was then completely transferred into a volumetric flask and adjusted to the required final volume. The dose formulations were prepared every 2 weeks or as required.
Chemical Lot Numbers
AZT, F60731
3TC, B10250
NVP, FX1009
Maximum Storage Time
21 days
Storage Conditions
Stored (with constant stirring) in sealed amber glass bottles at room temperature
Study Laboratory
National Center for Toxicological Research (Jefferson, AR)

TABLE F2 Results of Analyses of Dose Formulations Administered to Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP

Dose Formulation | Date Prepared | | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
AZT
| December 27, 2006 | | 12 | 11.6 ± 0.1 | −3
| January 4, 2007 | | 20 | 18.7 ± 0.3 | −7
| May 3, 2007 | | 12 | 11.0 ± 0.3 | −8
| | | 20 | 18.2 ± 0.1 | −9
| July 12, 2007 | | 12 | 12.5 ± 0.3 | +4
3TC
| December 27, 2006 | | 7.5 | 7.05 ± 0.04 | −6
| January 4, 2007 | | 12.5 | 11.4 ± 0.1 | −9
| May 3, 2007 | | 7.5 | 6.86 ± 0.03 | −9
| May 4, 2007 | | 12.5 | 11.7 ± 0.0 | −6
| July 12, 2007 | | 7.5 | 7.44 ± 0.24 | −1
| July 13, 2007 | | 12.5 | 12.5 ± 0.6 | 0
NVP
| December 19, 2006 | | 8.4 | 7.62 ± 0.12 | −9
| January 4, 2007 | | 3.5 | 3.70 ± 0.35 | +6
| | | 14 | 14.9 ± 0.1 | +6
| May 10, 2007 | | 8.4 | 7.63 ± 0.17 | −9
| | | 3.5 | 3.47 ± 0.03 | −1
| | | 14 | 12.7 ± 0.2 | −9
| July 12, 2007 | | 8.4 | 8.37 ± 0.38 | 0
| July 13, 2007 | | 3.5 | 3.86 ± 0.01 | +10
| | | 14 | 14.4 ± 0.3 | +3
| October 29, 2007 | | 8.4 | 8.47 ± 0.36 | +1
| | | 14 | 14.2 ± 0.7 | +1
AZT and 3TC
| December 27, 2006
| | AZT | 12 | 11.7 ± 0.1 | −3
| | 3TC | 7.5 | 7.09 ± 0.05 | −5
| January 4, 2007
| | AZT | 20 | 18.8 ± 0.1 | −6
| | 3TC | 12.5 | 11.4 ± 0.1 | −9
| May 3, 2007
| | AZT | 12 | 11.3 ± 0.0 | −6
| | 3TC | 7.5 | 6.77 ± 0.05 | −10
| May 4, 2007
| | AZT | 20 | 18.4 ± 0.1 | −8
| | 3TC | 12.5 | 11.2 ± 0.0 | −10
| July 12, 2007
| | AZT | 12 | 12.0 ± 0.9 | 0
| | 3TC | 7.5 | 7.40 ± 0.55 | −1
| July 13, 2007
| | AZT | 20 | 21.1 ± 1.0 | +6
| | 3TC | 12.5 | 13.4 ± 0.7 | +7
AZT, 3TC, and NVP
| December 19, 2006
| | AZT | 4 | 4.03 ± 0.04 | +1
| | 3TC | 2.5 | 2.52 ± 0.01 | +1
| | NVP | 2.8 | 2.67 ± 0.02 | −5
| December 19, 2006
| | AZT | 8 | 7.90 ± 0.15 | −1
| | 3TC | 5 | 4.63 ± 0.08 | −7
| | NVP | 5.6 | 5.18 ± 0.10 | −8
| December 19, 2006
| | AZT | 12 | 11.1 ± 0.1 | −8
| | 3TC | 7.5 | 6.79 ± 0.04 | −9
| | NVP | 8.4 | 8.04 ± 0.02 | −4
| January 4, 2007
| | AZT | 6.67 | 6.62 ± 0.13 | −1
| | 3TC | 4.17 | 3.94 ± 0.06 | −6
| | NVP | 1.17 | 1.09 ± 0.32^b^ | −7
| January 4, 2007
| | AZT | 6.67 | 6.74 ± 0.10 | +1
| | 3TC | 4.17 | 3.95 ± 0.05 | −5
| | NVP | 4.67 | 4.72 ± 1.58^b^ | +1
| January 4, 2007
| | AZT | 13.33 | 12.5 ± 0.1 | −6
| | 3TC | 8.33 | 7.94 ± 0.12 | −5
| | NVP | 2.33 | 2.28 ± 0.36 | −2
| January 4, 2007
| | AZT | 13.33 | 12.7 ± 0.1 | −5
| | 3TC | 8.33 | 7.97 ± 0.10 | −4
| | NVP | 9.33 | 8.96 ± 0.34 | −4
| January 4, 2007
| | AZT | 20 | 18.6 ± 0.1 | −7
| | 3TC | 12.5 | 11.4 ± 0.1 | −9
| | NVP | 3.5 | 3.31 ± 0.17 | −5
| January 4, 2007
| | AZT | 20 | 18.7 ± 0.4 | −7
| | 3TC | 12.5 | 11.6 ± 0.2 | −7
| | NVP | 14 | 11.8 ± 0.3^c^ | −16
| January 10, 2007
| | AZT | 20 | 19.0 ± 0.1 | −5
| | 3TC | 12.5 | 11.7 ± 0.3 | −6
| | NVP | 14 | 13.9 ± 0.2 | −1
| May 10, 2007
| | AZT | 4 | 4.03 ± 0.02 | +1
| | 3TC | 2.5 | 2.41 ± 0.03 | −4
| | NVP | 2.8 | 2.69 ± 0.02 | −4
| May 10, 2007
| | AZT | 8 | 7.74 ± 0.10 | −3
| | 3TC | 5 | 4.57 ± 0.06 | −9
| | NVP | 5.6 | 5.53 ± 0.03 | −1
| May 10, 2007
| | AZT | 12 | 10.7 ± 0.0 | −11
| | 3TC | 7.5 | 6.87 ± 0.05 | −8
| | NVP | 8.4 | 7.93 ± 0.09 | −6
| May 10, 2007
| | AZT | 6.67 | 6.66 ± 0.12 | 0
| | 3TC | 4.17 | 3.79 ± 0.04 | −9
| | NVP | 1.17 | 1.20 ± 0.01 | +3
| May 10, 2007
| | AZT | 6.67 | 6.54 ± 0.04 | −2
| | 3TC | 4.17 | 3.88 ± 0.04 | −7
| | NVP | 4.67 | 4.32 ± 0.04 | −7
| May 10, 2007
| | AZT | 13.33 | 12.5 ± 0.1 | −6
| | 3TC | 8.33 | 7.69 ± 0.05 | −8
| | NVP | 2.33 | 2.38 ± 0.01 | +2
| May 10, 2007
| | AZT | 13.33 | 12.7 ± 0.5 | −5
| | 3TC | 8.33 | 7.74 ± 0.30 | −7
| | NVP | 9.33 | 8.36 ± 1.1 | −10
| May 10, 2007
| | AZT | 20 | 18.4 ± 0.4 | −8
| | 3TC | 12.5 | 11.3 ± 0.2 | −10
| | NVP | 3.5 | 3.49 ± 0.07 | 0
| May 10, 2007
| | AZT | 20 | 19.1 ± 0.1 | −5
| | 3TC | 12.5 | 11.0 ± 0.0 | −12
| | NVP | 14 | 13.0 ± 0.1 | −7
| June 21, 2007
| | AZT | 4 | 3.93 ± 0.09 | −2
| | 3TC | 2.5 | 2.42 ± 0.05 | −3
| | NVP | 2.8 | 2.59 ± 0.06 | −8
| June 21, 2007
| | AZT | 12 | 10.5 ± 0.7 | −13
| | 3TC | 7.5 | 6.34 ± 0.43 | −15
| | NVP | 8.4 | 7.14 ± 0.03 | −15
| June 21, 2007
| | AZT | 6.67 | 5.98 ± 0.03 | −10
| | 3TC | 4.17 | 3.72 ± 0.03 | −11
| | NVP | 1.17 | 1.07 ± 0.0 | −9
| June 21, 2007
| | AZT | 20 | 17.5 ± 0.9 | −13
| | 3TC | 12.5 | 10.5 ± 0.6^c^ | −16
| | NVP | 14 | 8.47 ± 0.15^c^ | −40
| June 28, 2007
| | AZT | 6.67 | 6.44 ± 0.04 | −3
| | 3TC | 4.17 | 3.73 ± 0.02 | −11
| | NVP | 1.17 | 1.03 ± 0.02 | −12
| June 28, 2007
| | AZT | 12 | 11.0 ± 0.0 | −8
| | 3TC | 7.5 | 6.73 ± 0.01 | −10
| | NVP | 8.4 | 7.00 ± 0.01^c^ | −17
| June 28, 2007
| | AZT | 20 | 18.0 ± 0.4 | −10
| | 3TC | 12.5 | 10.7 ± 0.2 | −14
| | NVP | 14 | 12.1 ± 1.8 | −14
| July 5, 2007
| | AZT | 6.67 | 6.26 ± 0.15 | −6
| | 3TC | 4.17 | 3.72 ± 0.11 | −11
| | NVP | 1.17 | 0.77 ± 0.05^c^ | −34
| July 5, 2007
| | AZT | 12 | 10.9 ± 0.0 | −9
| | 3TC | 7.5 | 6.65 ± 0.03 | −11
| | NVP | 8.4 | 8.12 ± 0.12 | −3
| July 5, 2007
| | AZT | 20 | 18.8 ± 0.2 | −6
| | 3TC | 12.5 | 11.3 ± 0.2 | −10
| | NVP | 14 | 12.3 ± 0.3 | −12
| July 12, 2007
| | AZT | 4 | 4.31 ± 0.22 | +8
| | 3TC | 2.5 | 2.57 ± 0.12 | +3
| | NVP | 2.8 | 2.71 ± 0.05 | −3
| July 12, 2007
| | AZT | 8 | 8.14 ± 0.23 | +2
| | 3TC | 5 | 5.01 ± 0.20 | 0
| | NVP | 5.6 | 5.44 ± 0.13 | −3
| July 12, 2007
| | AZT | 12 | 12.2 ± 0.3 | +2
| | 3TC | 7.5 | 7.56 ± 0.24 | +1
| | NVP | 8.4 | 8.32 ± 0.09 | −1
| July 13, 2007
| | AZT | 6.67 | 7.33 ± 0.05 | +10
| | 3TC | 4.17 | 4.59 ± 0.04 | +10
| | NVP | 1.17 | 1.33 ± 0.06 | +14
| July 13, 2007
| | AZT | 6.67 | 7.25 ± 0.12 | +9
| | 3TC | 4.17 | 4.60 ± 0.10 | +10
| | NVP | 4.67 | 4.79 ± 0.31 | +3
| July 13, 2007
| | AZT | 13.33 | 14.4 ± 0.1 | +8
| | 3TC | 8.33 | 8.96 ± 0.05 | +8
| | NVP | 2.33 | 2.74 ± 0.13^c^ | +18
| July 13, 2007
| | AZT | 13.33 | 14.6 ± 0.1 | +10
| | 3TC | 8.33 | 9.00 ± 0.02 | +8
| | NVP | 9.33 | 9.87 ± 0.27 | +6
| July 13, 2007
| | AZT | 20 | 21.0 ± 0.1 | +5
| | 3TC | 12.5 | 13.1 ± 0.2 | +5
| | NVP | 3.5 | 4.06 ± 0.18 | +16
| July 13, 2007
| | AZT | 20 | 20.8 ± 0.2 | +4
| | 3TC | 12.5 | 13.0 ± 0.1 | +4
| | NVP | 14 | 14.9 ± 0.4 | +6
| September 27, 2007
| | AZT | 4 | 4.40 ± 0.15^d^ | +10
| | 3TC | 2.5 | 2.73 ± 0.00^d^ | +9
| | NVP | 2.8 | 2.95 ± 0.19^d^ | +5
| September 27, 2007
| | AZT | 6.67 | 7.09 ± 0.27 | +6
| | 3TC | 4.17 | 4.27 ± 0.14 | +2
| | NVP | 1.17 | 1.18 ± 0.04 | +1
| September 27, 2007
| | AZT | 12 | 12.7 ± 0.6 | +6
| | 3TC | 7.5 | 7.54 ± 0.22 | +1
| | NVP | 8.4 | 8.95 ± 0.24 | +7
| September 27, 2007
| | AZT | 20 | 21.0 ± 0.8 | +5
| | 3TC | 12.5 | 12.8 ± 0.3 | +2
| | NVP | 14 | 15.2 ± 0.4 | +9
| November 20, 2007
| | AZT | 12 | 11.9 ± 0.4 | −1
| | 3TC | 7.5 | 7.40 ± 0.09 | −1
| | NVP | 8.4 | 8.71 ± 0.20 | +4

a Results of triplicate analyses (mean ± standard deviation). For dams (gestational days 12 to 18) and pups [postnatal days (PNDs) 11 to 28], dosing volume=10 mL/kg twice daily; 2.5 mg/mL=50 mg/kg, 2.8 mg/mL=56 mg/kg, 4 mg/mL=80 mg/kg, 5 mg/mL=100 mg/kg, 5.6 mg/mL=112 mg/kg, 7.5 mg/mL=150 mg/kg, 8 mg/mL=160 mg/kg, 8.4 mg/mL=168 mg/kg, 12 mg/mL=240 mg/kg. For pups (PNDs 1 to 10), dosing volume=3 mL/kg twice daily; 1.17 mg/mL=7 mg/kg, 2.33 mg/mL=14 mg/kg, 3.5 mg/mL=21 mg/kg, 4.17 mg/mL=25 mg/kg, 4.67 mg/mL=28 mg/kg, 6.67 mg/mL=40 mg/kg, 8.33 mg/mL=50 mg/kg, 9.33 mg/mL=56 mg/kg, 12.5 mg/mL=75 mg/kg, 13.33 mg/mL=80 mg/kg, 14 mg/mL=84 mg/kg, 20 mg/mL=120 mg/kg.

b n=6

c Dose preparation was out of specification and not used for study

d n=2