# APPENDIX E ORGAN WEIGHTS AND ORGAN-WEIGHT-TO-BODY-WEIGHT RATIOS

TABLE E1 Organ Weights of Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| R^b^ | Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Male
n | | 20 | 24 | 22 | 22
Necropsy body wt | | 46.0 ± 1.0 | 44.6 ± 0.7 | 41.4 ± 1.4 | 44.0 ± 1.2
Brain
Absolute | 0.38 | 515.3 ± 4.1^**^ | 502.3 ± 3.7 | 487.0 ± 6.2^**^ | 465.3 ± 5.7^**^
Relative | 0.06 | 11.3 ± 0.3 | 11.3 ± 0.2 | 12.2 ± 0.6 | 10.8 ± 0.4
Heart
Absolute | −0.19 | 234.9 ± 6.9 | 231.0 ± 4.3 | 216.2 ± 7.9 | 231.7 ± 5.7
Relative | −0.24 | 5.1 ± 0.1 | 5.2 ± 0.1 | 5.3 ± 0.2 | 5.3 ± 0.1
Kidney
Absolute | 0.15 | 672.0 ± 14.4^*^ | 631.1 ± 12.9 | 583.0 ± 22.9^**^ | 619.7 ± 21.7^c^
Relative | 0.15 | 14.6 ± 0.2 | 14.2 ± 0.3 | 14.1 ± 0.3 | 14.2 ± 0.3^c^
Liver
Absolute | 0.16 | 2,039.5 ± 81.1 | 2,082.2 ± 66.1 | 2,124.2 ± 169.9 | 2,338.4 ± 135.7
Relative | 0.06 | 44.0 ± 1.1^*^ | 46.9 ± 1.7 | 51.5 ± 4.7 | 52.8 ± 2.3
Lung
Absolute | 0.44 | 253.8 ± 8.6 | 262.0 ± 7.3 | 252.6 ± 7.3 | 237.7 ± 7.7
Relative | 0.18 | 5.6 ± 0.2 | 5.9 ± 0.2 | 6.3 ± 0.3 | 5.5 ± 0.2
Female
n | | 25 | 22 | 19 | 21
Necropsy body wt | | 41.3 ± 1.4 | 40.7 ± 1.0 | 41.2 ± 1.4 | 40.3 ± 1.6
Brain
Absolute | 0.29 | 534.6 ± 7.3^**^ | 512.6 ± 4.1^*^ | 494.3 ± 6.3^**^ | 472.4 ± 3.3^**^
Relative | 0.57 | 13.4 ± 0.5^*^ | 12.8 ± 0.3 | 12.2 ± 0.4 | 12.1 ± 0.5
Heart
Absolute | 0.29 | 170.0 ± 4.6^**^ | 171.7 ± 3.4 | 174.0 ± 4.2 | 188.1 ± 4.5^*^
Relative | 0.50 | 4.2 ± 0.1^*^ | 4.3 ± 0.1 | 4.3 ± 0.1 | 4.8 ± 0.2
Kidney
Absolute | 0.39 | 448.5 ± 9.5 | 429.1 ± 8.7 | 410.9 ± 9.1 | 436.5 ± 13.5
Relative | −0.08 | 11.1 ± 0.3 | 10.6 ± 0.2 | 10.1 ± 0.2^*^ | 11.0 ± 0.3
Liver
Absolute | 0.32 | 1,462.3 ± 51.3^d^ | 1,507.1 ± 46.8 | 1,447.7 ± 49.2 | 1,494.2 ± 71.3
Relative | −0.22 | 35.5 ± 0.9^d^ | 37.1 ± 0.9 | 35.3 ± 0.6 | 37.1 ± 0.9
Lung
Absolute | −0.11 | 239.8 ± 8.2^d^ | 246.7 ± 8.6 | 223.5 ± 7.0 | 235.6 ± 6.5^e^
Relative | 0.39 | 5.9 ± 0.2^d^ | 6.1 ± 0.2 | 5.6 ± 0.3 | 6.1 ± 0.3^e^

* Significant trend (P≤0.05, vehicle control column) or significantly different (P≤0.05, dosed group columns) from the vehicle control group by Dunnett’s test

** P≤0.01

a Body weights are given in grams; organ weights (absolute weights) are given in milligrams; organ-weight-to-body-weight ratios (relative weights) are given as the organ weight/body weight; AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg

b R = Correlation within littermates

c n=21

d n=24

e n=20

TABLE E2 Organ Weights of Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| R^b^ | Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
Male
n | | 20 | 18 | 23 | 22 | 21 | 22
Necropsy body wt | | 46.0 ± 1.0 | 45.8 ± 0.6 | 47.9 ± 0.6 | 46.0 ± 0.7 | 45.8 ± 0.7 | 44.0 ± 1.2
Brain
Absolute | 0.32 | 515.3 ± 4.1^††^ | 493.0 ± 3.8^*^,^††^ | 531.0 ± 4.8^††^ | 509.5 ± 4.8^††^ | 498.1 ± 4.1^††^,^c^ | 465.3 ± 5.7^**^
Relative | 0.36 | 11.3 ± 0.3 | 10.8 ± 0.1 | 11.1 ± 0.2 | 11.1 ± 0.2 | 11.0 ± 0.2^c^ | 10.8 ± 0.4
Heart
Absolute | 0.15 | 234.9 ± 6.9 | 232.3 ± 6.5 | 250.1 ± 6.4 | 223.0 ± 6.3 | 232.1 ± 5.8^c^ | 231.7 ± 5.7
Relative | 0.12 | 5.1 ± 0.1 | 5.1 ± 0.1 | 5.2 ± 0.2 | 4.8 ± 0.1 | 5.1 ± 0.1^c^ | 5.3 ± 0.1
Kidney
Absolute | 0.23 | 672.0 ± 14.4 | 653.0 ± 18.2 | 721.1 ± 18.0^††^ | 630.9 ± 20.0 | 666.8 ± 13.5 | 619.7 ± 21.7^d^
Relative | 0.04 | 14.6 ± 0.2 | 14.2 ± 0.3 | 15.0 ± 0.3 | 13.7 ± 0.3 | 14.6 ± 0.2 | 14.2 ± 0.3^d^
Liver
Absolute | 0.35 | 2,039.5 ± 81.1 | 2,290.2 ± 98.4 | 2,164.6 ± 83.7 | 2,005.3 ± 81.7 | 2,276.6 ± 99.9 | 2,338.4 ± 135.7
Relative | 0.18 | 44.0 ± 1.1^††^ | 49.8 ± 1.7 | 44.9 ± 1.3^††^ | 43.3 ± 1.3^††^ | 49.3 ± 1.5 | 52.8 ± 2.3^**^
Lung
Absolute | −0.02 | 253.8 ± 8.6 | 241.9 ± 9.4^e^ | 288.7 ± 9.5^*^,^††^ | 255.5 ± 8.5 | 244.5 ± 9.1 | 237.7 ± 7.7
Relative | 0.01 | 5.6 ± 0.2 | 5.3 ± 0.2^e^ | 6.0 ± 0.2 | 5.6 ± 0.2 | 5.3 ± 0.2 | 5.5 ± 0.2
Female
n | | 25 | 20 | 20 | 20 | 19 | 21
Necropsy body wt | | 41.3 ± 1.4 | 40.4 ± 2.1 | 40.7 ± 1.5 | 42.3 ± 1.8 | 44.9 ± 1.3 | 40.3 ± 1.6
Brain
Absolute | 0.37 | 534.6 ± 7.3^††^ | 491.6 ± 4.2^**^ | 542.8 ± 5.0^††^ | 542.0 ± 5.9^††^ | 513.1 ± 6.0^††^ | 472.4 ± 3.3^**^
Relative | 0.43 | 13.4 ± 0.5 | 12.8 ± 0.7 | 13.8 ± 0.6 | 13.2 ± 0.5 | 11.6 ± 0.4 | 12.1 ± 0.5
Heart
Absolute | 0.11 | 170.0 ± 4.6 | 171.0 ± 4.1 | 176.4 ± 4.8 | 169.5 ± 7.1 | 190.6 ± 4.9^*^ | 188.1 ± 4.5
Relative | 0.18 | 4.2 ± 0.1 | 4.4 ± 0.2 | 4.5 ± 0.2 | 4.0 ± 0.1^†^ | 4.3 ± 0.1 | 4.8 ± 0.2
Kidney
Absolute | 0.27 | 448.5 ± 9.5 | 415.2 ± 10.6 | 455.7 ± 5.8 | 433.3 ± 14.0 | 451.9 ± 9.6 | 436.5 ± 13.5
Relative | 0.07 | 11.1 ± 0.3 | 10.6 ± 0.4 | 11.5 ± 0.5 | 10.4 ± 0.3 | 10.2 ± 0.2 | 11.0 ± 0.3
Liver
Absolute | 0.18 | 1,462.3 ± 51.3^f^ | 1,435.9 ± 50.9 | 1,450.8 ± 31.0 | 1,564.5 ± 90.0 | 1,681.7 ± 79.7 | 1,494.2 ± 71.3
Relative | −0.14 | 35.5 ± 0.9^f^ | 36.3 ± 1.1 | 36.3 ± 1.0 | 37.3 ± 1.7 | 37.4 ± 1.3 | 37.1 ± 0.9
Lung
Absolute | 0.12 | 239.8 ± 8.2^f^ | 216.1 ± 4.7 | 242.9 ± 10.2 | 219.2 ± 7.3 | 250.7 ± 9.9 | 235.6 ± 6.5^c^
Relative | 0.34 | 5.9 ± 0.2^f^ | 5.6 ± 0.3 | 6.1 ± 0.3 | 5.3 ± 0.2 | 5.7 ± 0.3 | 6.1 ± 0.3^c^

* Significantly different (P≤0.05) from the vehicle control group by Dunnett’s test

** P≤0.01

† Significantly different (P≤0.05) from the AZT/3TC/NVP=H group by Dunnett’s test

†† P≤0.01

a Body weights are given in grams; organ weights (absolute weights) are given in milligrams; organ-weight-to-body-weight ratios (relative weights) are given as the organ weight/body weight; AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b R = Correlation within littermates

c n=20

d n=21

e n=17

f n=24