# APPENDIX D BODY WEIGHT ANALYSES

TABLE D1 Body Weights of Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | | AZT/3TC/NVP-L | | AZT/3TC/NVP-M | | AZT/3TC/NVP-H
Week | Pups/Litters | Weight | Pups/Litters | Weight | Pups/Litters | Weight | Pups/Litters | Weight
2 | 25/18 | 8.0 ± 1.1 | 25/16 | 7.7 ± 0.8 | 23/14 | 7.6 ± 1.6 | 24/18 | 7.3 ± 1.1
3 | 25/18 | 10.8 ± 1.4 | 25/16 | 10.4 ± 1.0 | 23/14 | 10.2 ± 2.1 | 24/18 | 9.8 ± 1.7
4 | 25/18 | 15.8 ± 1.8^**^,^b^ | 25/16 | 15.5 ± 1.4 | 23/14 | 14.5 ± 2.6 | 24/18 | 14.1 ± 2.2^*^
5 | 25/18 | 20.1 ± 1.4^***^ | 25/16 | 19.5 ± 1.2 | 23/14 | 18.3 ± 2.4^*^ | 24/18 | 18.2 ± 2.1^**^
6 | 25/18 | 23.1 ± 1.4^***^ | 25/16 | 22.2 ± 1.2 | 23/14 | 20.9 ± 2.4^**^ | 24/18 | 20.6 ± 2.0^***^
7 | 25/18 | 25.5 ± 1.4^***^ | 25/16 | 24.4 ± 1.2 | 23/14 | 23.2 ± 2.4^***^ | 24/18 | 22.7 ± 2.0^***^
8 | 25/18 | 27.1 ± 1.5^***^ | 25/16 | 25.9 ± 1.3 | 23/14 | 24.7 ± 2.5^**^ | 24/18 | 24.1 ± 2.1^***^
9 | 25/18 | 28.6 ± 1.7^***^ | 25/16 | 27.3 ± 1.5 | 23/14 | 26.2 ± 2.7^**^ | 24/18 | 25.6 ± 2.2^***^
10 | 25/18 | 29.9 ± 1.9^***^ | 25/16 | 28.6 ± 1.7 | 23/14 | 27.5 ± 2.9^**^ | 24/18 | 26.8 ± 2.4^***^
11 | 25/18 | 31.1 ± 2.1^***^ | 25/16 | 29.8 ± 1.9 | 23/14 | 28.8 ± 3.2^*^ | 23/18 | 28.0 ± 2.6^***^
12 | 25/18 | 32.4 ± 2.3^***^ | 25/16 | 30.9 ± 2.1 | 23/14 | 30.0 ± 3.5^*^ | 23/18 | 29.1 ± 2.8^**^
13 | 25/18 | 33.5 ± 2.5^***^ | 25/16 | 32.0 ± 2.4 | 23/14 | 31.2 ± 3.8^*^ | 23/18 | 30.2 ± 2.9^**^
14 | 25/18 | 34.7 ± 2.7^***^ | 25/16 | 33.0 ± 2.6 | 23/14 | 32.4 ± 4.1^*^ | 23/18 | 31.2 ± 3.1^**^
15 | 25/18 | 35.8 ± 2.9^***^ | 25/16 | 34.1 ± 2.8 | 23/14 | 33.5 ± 4.3 | 23/18 | 32.3 ± 3.2^**^
16 | 25/18 | 36.9 ± 3.2^**^ | 25/16 | 35.2 ± 2.9 | 23/14 | 34.5 ± 4.6 | 23/18 | 33.3 ± 3.4^**^
17 | 25/18 | 37.9 ± 3.4^**^ | 25/16 | 36.2 ± 3.0 | 23/14 | 35.5 ± 4.8 | 23/18 | 34.3 ± 3.6^**^
18 | 25/18 | 38.8 ± 3.7^**^ | 25/16 | 37.2 ± 3.1 | 23/14 | 36.4 ± 5.0 | 23/18 | 35.3 ± 3.7^*^
19 | 25/18 | 39.6 ± 4.0^**^ | 25/16 | 38.2 ± 3.2 | 23/14 | 37.3 ± 5.1 | 23/18 | 36.3 ± 3.9^*^
20 | 25/18 | 40.4 ± 4.3^*^ | 25/16 | 39.1 ± 3.3 | 23/14 | 38.2 ± 5.2 | 23/18 | 37.3 ± 4.1^*^
21 | 25/18 | 41.2 ± 4.7^*^ | 25/16 | 39.9 ± 3.5 | 23/14 | 39.0 ± 5.3 | 23/18 | 38.3 ± 4.3
22 | 25/18 | 41.9 ± 5.1^*^ | 25/16 | 40.8 ± 3.6 | 23/14 | 39.8 ± 5.4 | 23/18 | 39.2 ± 4.5
23 | 25/18 | 42.6 ± 5.4^*^ | 25/16 | 41.5 ± 3.6 | 23/14 | 40.6 ± 5.3 | 23/18 | 40.1 ± 4.6
24 | 24/18 | 44.0 ± 4.5^*^ | 25/16 | 42.3 ± 3.7 | 23/14 | 41.4 ± 5.3 | 23/18 | 41.0 ± 4.8
25 | 24/18 | 44.7 ± 4.5^*^ | 25/16 | 42.9 ± 3.8 | 23/14 | 42.0 ± 5.3 | 23/18 | 41.8 ± 4.9
26 | 24/18 | 45.3 ± 4.5^*^ | 25/16 | 43.5 ± 3.8 | 23/14 | 42.7 ± 5.2 | 23/18 | 42.5 ± 5.0
27 | 24/18 | 45.8 ± 4.4 | 25/16 | 44.1 ± 3.8 | 23/14 | 43.2 ± 5.2 | 23/18 | 43.3 ± 5.0
28 | 24/18 | 46.3 ± 4.4 | 25/16 | 44.6 ± 3.8 | 23/14 | 43.7 ± 5.2 | 23/18 | 43.9 ± 5.1
29 | 23/18 | 46.7 ± 4.4 | 25/16 | 44.9 ± 3.8 | 23/14 | 44.2 ± 5.2 | 23/18 | 44.5 ± 5.1
30 | 23/18 | 47.1 ± 4.3 | 25/16 | 45.3 ± 3.7 | 23/14 | 44.6 ± 5.2 | 23/18 | 45.1 ± 5.1
31 | 23/18 | 47.4 ± 4.3 | 25/16 | 45.6 ± 3.7 | 23/14 | 44.9 ± 5.2 | 23/18 | 45.5 ± 5.2
32 | 23/18 | 47.8 ± 4.3 | 25/16 | 45.8 ± 3.6 | 23/14 | 45.2 ± 5.1 | 23/18 | 45.9 ± 5.2
33 | 23/18 | 48.1 ± 4.3 | 25/16 | 46.0 ± 3.6 | 23/14 | 45.5 ± 5.1 | 23/18 | 46.3 ± 5.3
34 | 23/18 | 48.5 ± 4.4 | 25/16 | 46.2 ± 3.6 | 23/14 | 45.7 ± 5.0 | 23/18 | 46.6 ± 5.3
35 | 23/18 | 48.8 ± 4.4 | 25/16 | 46.4 ± 3.6 | 23/14 | 45.9 ± 5.0 | 23/18 | 46.9 ± 5.4
36 | 23/18 | 49.1 ± 4.4 | 25/16 | 46.7 ± 3.7 | 23/14 | 46.1 ± 4.9 | 23/18 | 47.1 ± 5.4
37 | 23/18 | 49.4 ± 4.4 | 25/16 | 46.9 ± 3.7 | 23/14 | 46.3 ± 4.9 | 23/18 | 47.3 ± 5.4
38 | 23/18 | 49.7 ± 4.4 | 25/16 | 47.1 ± 3.7 | 23/14 | 46.5 ± 4.8 | 23/18 | 47.4 ± 5.5
39 | 23/18 | 49.8 ± 4.4 | 25/16 | 47.4 ± 3.7 | 23/14 | 46.6 ± 4.8 | 23/18 | 47.5 ± 5.4
40 | 22/18 | 49.9 ± 4.4 | 25/16 | 47.6 ± 3.6 | 23/14 | 46.7 ± 4.7 | 23/18 | 47.6 ± 5.4
41 | 22/18 | 49.9 ± 4.4 | 24/16 | 47.8 ± 3.7 | 23/14 | 46.6 ± 4.9^*^ | 23/18 | 47.6 ± 5.4
42 | 22/18 | 50.0 ± 4.4 | 24/16 | 48.1 ± 3.8 | 23/14 | 46.6 ± 5.2^*^ | 23/18 | 47.6 ± 5.5
43 | 21/18 | 49.8 ± 4.5 | 24/16 | 48.3 ± 3.8 | 23/14 | 46.5 ± 5.6 | 23/18 | 47.6 ± 5.6
44 | 20/18 | 49.8 ± 4.8 | 22/15 | 48.3 ± 3.8 | 22/14 | 46.4 ± 6.2 | 22/17 | 48.0 ± 5.6

a Unadjusted weights are given as mean ± standard error in grams. AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg.

b Asterisks represent significance of comparisons of body weights adjusted for litter correlation by Dunnett’s test;

* P<0.05

** P<0.01

*** P<0.001. Asterisks appearing in the vehicle control column represent the trend. Asterisks in the dosed group columns represent pairwise comparisons with the vehicle control group.

TABLE D2 Body Weights of Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | | AZT-H | | 3TC-H | | NVP-H | | AZT/3TC-H | | AZT/3TC/NVP-H
Week | Pups/Litters | Weight | Pups/Litters | Weight | Pups/Litters | Weight | Pups/Litters | Weight | Pups/Litters | Weight | Pups/Litters | Weight
2 | 25/18 | 8.0 ± 1.1 | 24/18 | 7.4 ± 1.0 | 25/16 | 8.3 ± 1.0 | 26/17 | 7.9 ± 1.0 | 25/17 | 7.5 ± 0.7 | 24/18 | 7.3 ± 1.1
3 | 25/18 | 10.8 ± 1.4 | 24/18 | 10.0 ± 1.4 | 25/16 | 11.1 ± 1.2 | 26/17 | 10.7 ± 1.2 | 25/17 | 10.0 ± 0.8 | 24/18 | 9.8 ± 1.7
4 | 25/18 | 15.8 ± 1.8 | 24/18 | 14.6 ± 2.0 | 25/16 | 16.5 ± 1.6 | 26/17 | 15.6 ± 1.9 | 25/17 | 14.7 ± 1.2 | 24/18 | 14.1 ± 2.2
5 | 25/18 | 20.1 ± 1.4 | 23/17 | 18.8 ± 1.8 | 25/16 | 21.0 ± 1.4^*^,^b^ | 25/16 | 19.9 ± 1.4 | 25/17 | 19.1 ± 1.4 | 24/18 | 18.2 ± 2.1^**^
6 | 25/18 | 23.1 ± 1.4 | 23/17 | 21.6 ± 1.8^*^ | 25/16 | 23.7 ± 1.5 | 25/16 | 22.5 ± 1.6 | 25/17 | 22.0 ± 1.5 | 24/18 | 20.6 ± 2.0^***^
7 | 25/18 | 25.5 ± 1.4 | 23/17 | 23.7 ± 2.1^**^ | 25/16 | 26.2 ± 1.6 | 25/16 | 24.7 ± 1.7 | 25/17 | 24.4 ± 1.7 | 24/18 | 22.7 ± 2.0^***^
8 | 25/18 | 27.1 ± 1.5 | 23/17 | 25.3 ± 2.4^**^ | 25/16 | 27.9 ± 1.7 | 25/16 | 26.2 ± 1.9 | 25/17 | 26.1 ± 1.9 | 24/18 | 24.1 ± 2.1^***^
9 | 25/18 | 28.6 ± 1.7 | 23/17 | 26.7 ± 2.5^**^ | 25/16 | 29.5 ± 1.9 | 25/16 | 27.6 ± 2.0 | 25/17 | 27.5 ± 2.2 | 24/18 | 25.6 ± 2.2^***^
10 | 25/18 | 29.9 ± 1.9 | 23/17 | 28.0 ± 2.6^**^ | 25/16 | 30.9 ± 2.1 | 25/16 | 28.8 ± 2.2 | 25/17 | 28.8 ± 2.5 | 24/18 | 26.8 ± 2.4^***^
11 | 25/18 | 31.1 ± 2.1 | 23/17 | 29.2 ± 2.7^*^ | 25/16 | 32.2 ± 2.3 | 25/16 | 30.0 ± 2.4 | 25/17 | 30.1 ± 2.9 | 23/18 | 28.0 ± 2.6^***^
12 | 25/18 | 32.4 ± 2.3 | 23/17 | 30.4 ± 3.0^*^ | 25/16 | 33.5 ± 2.5 | 25/16 | 31.2 ± 2.6 | 25/17 | 31.4 ± 3.2 | 23/18 | 29.1 ± 2.8^***^
13 | 25/18 | 33.5 ± 2.5 | 23/17 | 31.5 ± 3.3^*^ | 25/16 | 34.7 ± 2.7 | 25/16 | 32.3 ± 2.8 | 25/17 | 32.6 ± 3.6 | 23/18 | 30.2 ± 2.9^***^
14 | 25/18 | 34.7 ± 2.7 | 23/17 | 32.6 ± 3.6 | 25/16 | 35.9 ± 3.0 | 25/16 | 33.3 ± 3.1 | 24/16 | 34.1 ± 3.6 | 23/18 | 31.2 ± 3.1^***^
15 | 25/18 | 35.8 ± 2.9 | 23/17 | 33.7 ± 3.9 | 25/16 | 37.0 ± 3.2 | 25/16 | 34.4 ± 3.3 | 24/16 | 35.3 ± 3.8 | 23/18 | 32.3 ± 3.2^***^
16 | 25/18 | 36.9 ± 3.2 | 23/17 | 34.7 ± 4.1 | 25/16 | 38.1 ± 3.4 | 25/16 | 35.4 ± 3.5 | 24/16 | 36.5 ± 3.9 | 23/18 | 33.3 ± 3.4^***^
17 | 25/18 | 37.9 ± 3.4 | 23/17 | 35.7 ± 4.4 | 25/16 | 39.0 ± 3.5 | 25/16 | 36.4 ± 3.7 | 24/16 | 37.6 ± 3.9 | 23/18 | 34.3 ± 3.6^**^
18 | 25/18 | 38.8 ± 3.7 | 23/17 | 36.7 ± 4.5 | 25/16 | 39.9 ± 3.7 | 25/16 | 37.3 ± 3.9 | 24/16 | 38.6 ± 3.9 | 23/18 | 35.3 ± 3.7^**^
19 | 25/18 | 39.6 ± 4.0 | 23/17 | 37.6 ± 4.6 | 25/16 | 40.7 ± 3.9 | 25/16 | 38.2 ± 4.1 | 24/16 | 39.5 ± 3.8 | 23/18 | 36.3 ± 3.9^*^
20 | 25/18 | 40.4 ± 4.3 | 23/17 | 38.4 ± 4.8 | 25/16 | 41.6 ± 4.0 | 25/16 | 39.0 ± 4.3 | 24/16 | 40.4 ± 3.8 | 23/18 | 37.3 ± 4.1^*^
21 | 25/18 | 41.2 ± 4.7 | 23/17 | 39.2 ± 4.9 | 25/16 | 42.3 ± 4.1 | 25/16 | 39.8 ± 4.5 | 24/16 | 41.3 ± 3.7 | 23/18 | 38.3 ± 4.3
22 | 25/18 | 41.9 ± 5.1 | 23/17 | 39.9 ± 5.1 | 25/16 | 43.1 ± 4.1 | 25/16 | 40.6 ± 4.6 | 23/16 | 42.3 ± 3.5 | 23/18 | 39.2 ± 4.5
23 | 25/18 | 42.6 ± 5.4 | 22/16 | 41.2 ± 4.8 | 25/16 | 43.8 ± 4.2 | 25/16 | 41.4 ± 4.7 | 23/16 | 43.0 ± 3.4 | 23/18 | 40.1 ± 4.6
24 | 24/18 | 44.0 ± 4.5 | 22/16 | 41.9 ± 4.7 | 25/16 | 44.5 ± 4.2 | 24/15 | 41.9 ± 4.8 | 23/16 | 43.8 ± 3.3 | 23/18 | 41.0 ± 4.8
25 | 24/18 | 44.7 ± 4.5 | 21/16 | 43.0 ± 4.1 | 25/16 | 45.2 ± 4.1 | 24/15 | 42.5 ± 4.8 | 23/16 | 44.4 ± 3.1 | 23/18 | 41.8 ± 4.9
26 | 24/18 | 45.3 ± 4.5 | 21/16 | 43.6 ± 3.9 | 24/16 | 46.2 ± 4.0 | 24/15 | 43.1 ± 4.9 | 23/16 | 44.9 ± 3.0 | 23/18 | 42.5 ± 5.0
27 | 24/18 | 45.8 ± 4.4 | 21/16 | 44.1 ± 3.8 | 24/16 | 46.8 ± 3.9 | 24/15 | 43.6 ± 4.8 | 23/16 | 45.4 ± 2.9 | 23/18 | 43.3 ± 5.0
28 | 24/18 | 46.3 ± 4.4 | 21/16 | 44.5 ± 3.7 | 24/16 | 47.4 ± 3.9 | 24/15 | 44.0 ± 4.8 | 22/15 | 45.9 ± 2.9 | 23/18 | 43.9 ± 5.1
29 | 23/18 | 46.7 ± 4.4 | 21/16 | 44.9 ± 3.6 | 24/16 | 47.9 ± 3.8 | 24/15 | 44.5 ± 4.7 | 22/15 | 46.3 ± 2.9 | 23/18 | 44.5 ± 5.1
30 | 23/18 | 47.1 ± 4.3 | 21/16 | 45.3 ± 3.6 | 24/16 | 48.3 ± 3.8 | 24/15 | 44.9 ± 4.7 | 22/15 | 46.7 ± 2.8 | 23/18 | 45.1 ± 5.1
31 | 23/18 | 47.4 ± 4.3 | 21/16 | 45.7 ± 3.5 | 24/16 | 48.7 ± 3.7 | 23/15 | 45.7 ± 4.4 | 22/15 | 47.1 ± 2.8 | 23/18 | 45.5 ± 5.2
32 | 23/18 | 47.8 ± 4.3 | 21/16 | 46.0 ± 3.4 | 24/16 | 49.1 ± 3.7 | 23/15 | 46.0 ± 4.5 | 22/15 | 47.4 ± 2.8 | 23/18 | 45.9 ± 5.2
33 | 23/18 | 48.1 ± 4.3 | 21/16 | 46.3 ± 3.4 | 24/16 | 49.4 ± 3.6 | 23/15 | 46.4 ± 4.5 | 22/15 | 47.7 ± 2.8 | 23/18 | 46.3 ± 5.3
34 | 23/18 | 48.5 ± 4.4 | 20/15 | 46.7 ± 3.4 | 24/16 | 49.6 ± 3.7 | 22/15 | 46.9 ± 4.6 | 22/15 | 48.0 ± 2.8 | 23/18 | 46.6 ± 5.3
35 | 23/18 | 48.8 ± 4.4 | 20/15 | 46.8 ± 3.7 | 23/16 | 50.3 ± 3.2 | 22/15 | 47.3 ± 4.7 | 22/15 | 48.3 ± 2.8 | 23/18 | 46.9 ± 5.4
36 | 23/18 | 49.1 ± 4.4 | 20/15 | 47.0 ± 4.0 | 23/16 | 50.5 ± 3.3 | 22/15 | 47.7 ± 4.7 | 22/15 | 48.6 ± 2.9 | 23/18 | 47.1 ± 5.4
37 | 23/18 | 49.4 ± 4.4 | 19/14 | 47.8 ± 3.3 | 23/16 | 50.7 ± 3.4 | 22/15 | 48.0 ± 4.7 | 22/15 | 48.9 ± 2.9 | 23/18 | 47.3 ± 5.4
38 | 23/18 | 49.7 ± 4.4 | 19/14 | 48.0 ± 3.7 | 23/16 | 50.9 ± 3.5 | 22/15 | 48.4 ± 4.6 | 22/15 | 49.2 ± 3.0 | 23/18 | 47.4 ± 5.5
39 | 23/18 | 49.8 ± 4.4 | 19/14 | 48.1 ± 4.2 | 23/16 | 51.1 ± 3.6 | 22/15 | 48.7 ± 4.5 | 22/15 | 49.5 ± 3.0 | 23/18 | 47.5 ± 5.4
40 | 22/18 | 49.9 ± 4.4 | 18/13 | 49.2 ± 2.6 | 23/16 | 51.3 ± 3.6 | 22/15 | 48.9 ± 4.5 | 22/15 | 49.7 ± 3.0 | 23/18 | 47.6 ± 5.4
41 | 22/18 | 49.9 ± 4.4 | 18/13 | 49.5 ± 2.5 | 23/16 | 51.6 ± 3.6 | 22/15 | 49.2 ± 4.4 | 22/15 | 49.9 ± 3.0 | 23/18 | 47.6 ± 5.4
42 | 22/18 | 50.0 ± 4.4 | 18/13 | 49.7 ± 2.5 | 23/16 | 51.8 ± 3.5 | 22/15 | 49.4 ± 4.3 | 22/15 | 50.0 ± 3.0 | 23/18 | 47.6 ± 5.5
43 | 21/18 | 49.8 ± 4.5 | 18/13 | 49.9 ± 2.5 | 23/16 | 52.0 ± 3.5 | 22/15 | 49.6 ± 4.2 | 21/14 | 50.0 ± 3.0 | 23/18 | 47.6 ± 5.6
44 | 20/18 | 49.8 ± 4.8 | 18/13 | 50.2 ± 2.5 | 23/16 | 52.3 ± 3.4 | 22/15 | 49.9 ± 4.1 | 19/13 | 50.3 ± 3.2 | 22/17 | 48.0 ± 5.6

a Unadjusted weights are given as mean ± standard error in grams. AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b Asterisks represent significance of pairwise comparisons with the vehicle control group for body weights adjusted for litter correlation by Dunnett’s test

* P<0.05

** P<0.01

*** P<0.001.

TABLE D3 Body Weights of Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | | AZT/3TC/NVP-L | | AZT/3TC/NVP-M | | AZT/3TC/NVP-H
Week | Pups/Litters | Weight | Pups/Litters | Weight | Pups/Litters | Weight | Pups/Litters | Weight
2 | 25/18 | 7.9 ± 0.9^**^,^b^ | 25/15 | 7.7 ± 0.9 | 23/12 | 7.5 ± 1.1 | 25/17 | 7.1 ± 0.9^**^
3 | 25/18 | 10.5 ± 0.9^**^ | 25/15 | 10.0 ± 0.9 | 23/12 | 9.8 ± 1.3 | 25/17 | 9.5 ± 1.0^**^
4 | 25/18 | 13.8 ± 1.2^***^ | 25/15 | 13.6 ± 1.2 | 23/12 | 13.3 ± 1.4 | 25/17 | 12.5 ± 1.3^**^
5 | 25/18 | 17.2 ± 1.2^***^ | 25/15 | 16.6 ± 1.4 | 23/12 | 16.3 ± 1.5 | 25/17 | 15.3 ± 1.2^***^
6 | 25/18 | 19.3 ± 1.2^***^ | 25/15 | 18.6 ± 1.5 | 23/12 | 18.1 ± 1.6 | 25/17^*^ | 17.2 ± 1.3^***^
7 | 25/18 | 21.1 ± 1.2^***^ | 25/15 | 20.3 ± 1.6 | 23/12 | 19.6 ± 1.7 | 25/17^**^ | 18.8 ± 1.3^***^
8 | 25/18 | 22.2 ± 1.4^***^ | 25/15 | 21.4 ± 1.6 | 23/12 | 20.9 ± 1.8 | 25/17^*^ | 20.0 ± 1.5^***^
9 | 25/18 | 23.2 ± 1.5^***^ | 25/15 | 22.4 ± 1.7 | 23/12 | 22.0 ± 1.8 | 25/17 | 21.2 ± 1.7^**^
10 | 25/18 | 24.0 ± 1.7^**^ | 25/15 | 23.3 ± 1.8 | 23/12 | 23.1 ± 2.0 | 25/17 | 22.3 ± 1.9^**^
11 | 25/18 | 24.9 ± 1.9^*^ | 25/15 | 24.1 ± 1.9 | 23/12 | 24.1 ± 2.2 | 25/17 | 23.3 ± 2.2^*^
12 | 25/18 | 25.7 ± 2.1 | 25/15 | 24.9 ± 2.0 | 23/12 | 25.0 ± 2.4 | 25/17 | 24.4 ± 2.5
13 | 25/18 | 26.5 ± 2.3 | 25/15 | 25.7 ± 2.2 | 23/12 | 26.0 ± 2.6 | 25/17 | 25.4 ± 2.8
14 | 25/18 | 27.3 ± 2.5 | 25/15 | 26.5 ± 2.4 | 22/12 | 26.9 ± 2.9 | 25/17 | 26.4 ± 3.2
15 | 25/18 | 28.1 ± 2.7 | 25/15 | 27.3 ± 2.7 | 22/12 | 27.8 ± 3.2 | 25/17 | 27.8 ± 3.6
16 | 25/18 | 28.9 ± 2.9 | 25/15 | 28.1 ± 2.9 | 22/12 | 28.7 ± 3.5 | 25/17 | 28.2 ± 4.1
17 | 25/18 | 29.7 ± 3.2 | 25/15 | 28.9 ± 3.1 | 22/12 | 29.5 ± 3.8 | 25/17 | 29.0 ± 4.5
18 | 25/18 | 30.5 ± 3.5 | 25/15 | 29.6 ± 3.4 | 22/12 | 30.3 ± 4.1 | 25/17 | 29.8 ± 4.9
19 | 25/18 | 31.2 ± 3.8 | 25/15 | 30.4 ± 3.6 | 21/12 | 30.9 ± 4.3 | 25/17 | 30.6 ± 5.3
20 | 25/18 | 31.9 ± 4.1 | 25/15 | 31.1 ± 3.8 | 21/12 | 31.5 ± 4.6 | 25/17 | 31.4 ± 5.7
21 | 25/18 | 32.5 ± 4.3 | 25/15 | 31.7 ± 3.9 | 21/12 | 32.1 ± 4.8 | 25/17 | 32.1 ± 6.0
22 | 25/18 | 33.2 ± 4.6 | 25/15 | 32.3 ± 4.1 | 21/12 | 32.7 ± 4.9 | 25/17 | 32.9 ± 6.3
23 | 25/18 | 33.9 ± 4.8 | 25/15 | 32.8 ± 4.2 | 21/12 | 33.3 ± 5.1 | 25/17 | 33.6 ± 6.5
24 | 25/18 | 34.5 ± 5.1 | 25/15 | 33.3 ± 4.4 | 21/12 | 33.9 ± 5.2 | 25/17 | 34.3 ± 6.8
25 | 25/18 | 35.2 ± 5.3 | 25/15 | 33.8 ± 4.7 | 21/12 | 34.5 ± 5.3 | 25/17 | 34.9 ± 6.9
26 | 25/18 | 35.9 ± 5.5 | 24/15 | 34.7 ± 4.6 | 21/12 | 35.0 ± 5.4 | 25/17 | 35.6 ± 7.0
27 | 25/18 | 36.6 ± 5.7 | 24/15 | 35.4 ± 4.7 | 21/12 | 35.6 ± 5.5 | 25/17 | 36.1 ± 7.0
28 | 25/18 | 37.3 ± 5.9 | 24/15 | 36.0 ± 4.8 | 21/12 | 36.2 ± 5.5 | 25/17 | 36.7 ± 7.1
29 | 25/18 | 37.8 ± 6.0 | 24/15 | 36.6 ± 4.8 | 21/12 | 36.8 ± 5.6 | 25/17 | 37.2 ± 7.1
30 | 25/18 | 38.4 ± 6.1 | 24/15 | 37.2 ± 4.9 | 21/12 | 37.3 ± 5.7 | 25/17 | 37.7 ± 7.1
31 | 25/18 | 38.9 ± 6.1 | 24/15 | 37.7 ± 4.8 | 21/12 | 37.8 ± 5.8 | 25/17 | 38.1 ± 7.2
32 | 25/18 | 39.4 ± 6.2 | 24/15 | 38.2 ± 4.8 | 21/12 | 38.3 ± 5.9 | 25/17 | 38.5 ± 7.2
33 | 25/18 | 39.8 ± 6.2 | 24/15 | 38.7 ± 4.8 | 21/12 | 38.7 ± 6.0 | 25/17 | 39.0 ± 7.3
34 | 25/18 | 40.2 ± 6.3 | 23/15 | 39.1 ± 4.9 | 21/12 | 39.1 ± 6.1 | 25/17 | 39.3 ± 7.4
35 | 25/18 | 40.6 ± 6.5 | 23/15 | 39.6 ± 5.0 | 21/12 | 39.4 ± 6.2 | 24/17 | 39.9 ± 7.7
36 | 25/18 | 41.0 ± 6.6 | 23/15 | 39.9 ± 5.0 | 21/12 | 39.8 ± 6.3 | 24/17 | 40.4 ± 7.8
37 | 25/18 | 41.4 ± 6.7 | 23/15 | 40.3 ± 5.1 | 20/12 | 40.8 ± 5.7 | 24/17 | 40.9 ± 7.8
38 | 25/18 | 41.8 ± 6.9 | 23/15 | 40.7 ± 5.1 | 20/12 | 41.2 ± 5.7 | 23/17 | 41.9 ± 7.6
39 | 25/18 | 42.2 ± 6.9 | 23/15 | 41.0 ± 5.0 | 20/12 | 41.6 ± 5.7 | 23/17 | 42.1 ± 7.6
40 | 25/18 | 42.6 ± 7.0 | 23/15 | 41.4 ± 5.0 | 20/12 | 42.0 ± 5.6 | 23/17 | 42.4 ± 7.7
41 | 25/18 | 43.0 ± 7.0 | 22/15 | 42.1 ± 4.7 | 20/12 | 42.5 ± 5.6 | 23/17 | 42.5 ± 7.8
42 | 25/18 | 43.4 ± 7.0 | 22/15 | 42.5 ± 4.6 | 20/12 | 42.9 ± 5.7 | 23/17 | 42.5 ± 8.0
43 | 25/18 | 43.8 ± 7.0 | 22/15 | 42.9 ± 4.5 | 20/12 | 43.3 ± 5.7 | 22/16 | 43.3 ± 7.7
44 | 25/18 | 44.3 ± 7.0 | 21/14 | 43.3 ± 4.6 | 19/11 | 43.3 ± 5.6 | 21/15 | 43.9 ± 7.7

a Unadjusted weights are given as mean ± standard error in grams. AZT/3TC/NVP-L = 80/50/56 mg/kg; AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg.

b Asterisks represent significance of comparisons of body weights adjusted for litter correlation by Dunnett’s test;

* P<0.05

** P<0.01

*** P<0.001. Asterisks appearing in the vehicle control column represent the trend. Asterisks in the dosed group columns represent pairwise comparisons with the vehicle control group.

TABLE D4 Body Weights of Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | | AZT-H | | 3TC-H | | NVP-H | | AZT/3TC-H | | AZT/3TC/NVP-H
Week | Pups/Litters | Weight | Pups/Litters | Weight | Pups/Litters | Weight | Pups/Litters | Weight | Pups/Litters | Weight | Pups/Litters | Weight
2 | 25/18 | 7.9 ± 0.9 | 25/19 | 7.1 ± 1.1^*^,^b^ | 25/16 | 8.1 ± 0.8 | 25/16 | 8.1 ± 1.0 | 24/16 | 7.5 ± 0.7 | 25/17 | 7.1 ± 0.9^**^
3 | 25/18 | 10.5 ± 0.9 | 25/19 | 9.5 ± 1.4^*^ | 25/16 | 10.6 ± 1.0 | 25/16 | 10.6 ± 1.2 | 24/16 | 9.9 ± 1.0 | 25/17 | 9.5 ± 1.0^***^
4 | 25/18 | 13.8 ± 1.2 | 25/19 | 13.0 ± 1.5 | 25/16 | 14.3 ± 1.0 | 25/16 | 14.3 ± 1.5 | 24/16 | 13.5 ± 0.8 | 25/17 | 12.5 ± 1.3^***^
5 | 25/18 | 17.2 ± 1.2 | 25/19 | 16.1 ± 1.6^*^ | 25/16 | 17.6 ± 1.0 | 25/16 | 17.4 ± 1.5 | 24/16 | 16.7 ± 0.9 | 25/17 | 15.3 ± 1.2^***^
6 | 25/18 | 19.3 ± 1.2 | 25/19 | 18.1 ± 1.6^**^ | 25/16 | 19.6 ± 1.1 | 25/16 | 19.4 ± 1.7 | 24/16 | 18.8 ± 0.9 | 25/17 | 17.2 ± 1.3^***^
7 | 25/18 | 21.1 ± 1.2 | 25/19 | 19.7 ± 1.6^**^ | 25/16 | 21.3 ± 1.2 | 25/16 | 21.1 ± 1.9 | 24/16 | 20.5 ± 1.0 | 25/17 | 18.8 ± 1.3^***^
8 | 25/18 | 22.2 ± 1.4 | 25/19 | 20.9 ± 1.7^*^ | 25/16 | 22.4 ± 1.3 | 25/16 | 22.2 ± 2.1 | 24/16 | 21.7 ± 1.1 | 25/17 | 20.0 ± 1.5^***^
9 | 25/18 | 23.2 ± 1.5 | 25/19 | 22.0 ± 1.8^*^ | 25/16 | 23.5 ± 1.5 | 25/16 | 23.2 ± 2.4 | 24/16 | 22.9 ± 1.2 | 25/17 | 21.2 ± 1.7^***^
10 | 25/18 | 24.0 ± 1.7 | 25/19 | 23.0 ± 1.9 | 25/16 | 24.4 ± 1.6 | 25/16 | 24.2 ± 2.7 | 24/16 | 23.9 ± 1.4 | 25/17 | 22.3 ± 1.9^**^
11 | 25/18 | 24.9 ± 1.9 | 25/19 | 23.9 ± 2.0 | 25/16 | 25.3 ± 1.8 | 25/16 | 25.2 ± 3.1 | 24/16 | 24.9 ± 1.6 | 25/17 | 23.3 ± 2.2
12 | 25/18 | 25.7 ± 2.1 | 25/19 | 24.7 ± 2.1 | 25/16 | 26.1 ± 2.1 | 25/16 | 26.1 ± 3.4 | 24/16 | 25.9 ± 1.8 | 25/17 | 24.4 ± 2.5
13 | 25/18 | 26.5 ± 2.3 | 25/19 | 25.5 ± 2.3 | 25/16 | 27.0 ± 2.3 | 25/16 | 27.0 ± 3.8 | 24/16 | 26.6 ± 2.3 | 25/17 | 25.4 ± 2.8
14 | 25/18 | 27.3 ± 2.5 | 25/19 | 26.3 ± 2.5 | 25/16 | 27.7 ± 2.5 | 25/16 | 27.9 ± 4.1 | 23/16 | 27.7 ± 2.6 | 25/17 | 26.4 ± 3.2
15 | 25/18 | 28.1 ± 2.7 | 25/19 | 27.1 ± 2.8 | 25/16 | 28.5 ± 2.7 | 25/16 | 28.8 ± 4.4 | 23/16 | 28.5 ± 3.1 | 25/17 | 27.3 ± 3.6
16 | 25/18 | 28.9 ± 2.9 | 25/19 | 28.0 ± 3.0 | 25/16 | 29.2 ± 2.9 | 25/16 | 29.6 ± 4.7 | 22/16 | 29.7 ± 2.7 | 25/17 | 28.2 ± 4.1
17 | 25/18 | 29.7 ± 3.2 | 25/19 | 28.9 ± 3.3 | 25/16 | 29.8 ± 3.1 | 25/16 | 30.4 ± 4.9 | 22/16 | 30.6 ± 2.8 | 25/17 | 29.0 ± 4.5
18 | 25/18 | 30.5 ± 3.5 | 25/19 | 29.8 ± 3.6 | 25/16 | 30.5 ± 3.3 | 25/16 | 31.2 ± 5.1 | 22/16 | 31.4 ± 3.0 | 25/17 | 29.8 ± 4.9
19 | 25/18 | 31.2 ± 3.8 | 25/19 | 30.6 ± 3.8 | 25/16 | 31.1 ± 3.4 | 25/16 | 31.9 ± 5.2 | 22/16 | 32.1 ± 3.1 | 25/17 | 30.6 ± 5.3
20 | 25/18 | 31.9 ± 4.1 | 25/19 | 31.5 ± 4.1 | 25/16 | 31.8 ± 3.6 | 25/16 | 32.6 ± 5.3 | 22/16 | 32.9 ± 3.2 | 25/17 | 31.4 ± 5.7
21 | 25/18 | 32.5 ± 4.3 | 25/19 | 32.3 ± 4.3 | 25/16 | 32.4 ± 3.7 | 25/16 | 33.3 ± 5.4 | 22/16 | 33.6 ± 3.3 | 25/17 | 32.1 ± 6.0
22 | 25/18 | 33.2 ± 4.6 | 25/19 | 33.0 ± 4.5 | 25/16 | 33.1 ± 3.8 | 25/16 | 34.0 ± 5.6 | 22/16 | 34.4 ± 3.4 | 25/17 | 32.9 ± 6.3
23 | 25/18 | 33.9 ± 4.8 | 25/19 | 33.7 ± 4.7 | 25/16 | 33.8 ± 3.8 | 25/16 | 34.6 ± 5.6 | 22/16 | 35.1 ± 3.6 | 25/17 | 33.6 ± 6.5
24 | 25/18 | 34.5 ± 5.1 | 25/19 | 34.4 ± 4.9 | 25/16 | 34.5 ± 4.0 | 25/16 | 35.3 ± 5.7 | 22/16 | 35.9 ± 3.7 | 25/17 | 34.3 ± 6.8
25 | 25/18 | 35.2 ± 5.3 | 25/19 | 34.9 ± 5.1 | 25/16 | 35.2 ± 4.1 | 25/16 | 35.9 ± 5.8 | 22/16 | 36.6 ± 3.9 | 25/17 | 34.9 ± 6.9
26 | 25/18 | 35.9 ± 5.5 | 25/19 | 35.4 ± 5.3 | 25/16 | 35.9 ± 4.2 | 25/16 | 36.4 ± 5.9 | 22/16 | 37.3 ± 4.1 | 25/17 | 35.6 ± 7.0
27 | 25/18 | 36.6 ± 5.7 | 25/19 | 35.8 ± 5.5 | 25/16 | 36.6 ± 4.3 | 25/16 | 37.0 ± 5.9 | 22/16 | 38.0 ± 4.3 | 25/17 | 36.1 ± 7.0
28 | 25/18 | 37.3 ± 5.9 | 25/19 | 36.3 ± 5.7 | 25/16 | 37.3 ± 4.4 | 25/16 | 37.5 ± 5.9 | 22/16 | 38.6 ± 4.5 | 25/17 | 36.7 ± 7.1
29 | 25/18 | 37.8 ± 6.0 | 25/19 | 36.7 ± 5.8 | 25/16 | 38.0 ± 4.5 | 25/16 | 38.1 ± 5.9 | 22/16 | 39.1 ± 4.6 | 25/17 | 37.2 ± 7.1
30 | 25/18 | 38.4 ± 6.1 | 25/19 | 37.2 ± 6.0 | 25/16 | 38.6 ± 4.6 | 25/16 | 38.7 ± 6.0 | 22/16 | 39.6 ± 4.7 | 25/17 | 37.7 ± 7.1
31 | 25/18 | 38.9 ± 6.1 | 25/19 | 37.7 ± 6.1 | 25/16 | 39.2 ± 4.6 | 25/16 | 39.2 ± 6.0 | 22/16 | 40.1 ± 4.7 | 25/17 | 38.1 ± 7.2
32 | 25/18 | 39.4 ± 6.2 | 25/19 | 38.2 ± 6.3 | 25/16 | 39.6 ± 4.6 | 25/16 | 39.7 ± 6.1 | 22/16 | 40.5 ± 4.7 | 25/17 | 38.5 ± 7.2
33 | 25/18 | 39.8 ± 6.2 | 25/19 | 38.7 ± 6.4 | 25/16 | 40.0 ± 4.6 | 25/16 | 40.2 ± 6.2 | 22/16 | 40.8 ± 4.8 | 25/17 | 39.0 ± 7.3
34 | 25/18 | 40.2 ± 6.3 | 25/19 | 39.1 ± 6.6 | 25/16 | 40.4 ± 4.6 | 25/16 | 40.6 ± 6.4 | 22/16 | 41.1 ± 5.0 | 25/17 | 39.3 ± 7.4
35 | 25/18 | 40.6 ± 6.5 | 25/19 | 39.4 ± 6.8 | 25/16 | 40.8 ± 4.7 | 24/16 | 41.3 ± 6.5 | 22/16 | 41.3 ± 5.3 | 24/17 | 39.9 ± 7.7
36 | 25/18 | 41.0 ± 6.6 | 25/19 | 39.7 ± 7.1 | 24/15 | 41.3 ± 4.9 | 24/16 | 41.6 ± 6.7 | 21/16 | 41.9 ± 5.7 | 24/17 | 40.4 ± 7.8
37 | 25/18 | 41.4 ± 6.7 | 25/19 | 40.0 ± 7.3 | 24/15 | 41.6 ± 5.1 | 22/16 | 42.3 ± 6.9 | 20/15 | 43.1 ± 4.9 | 24/17 | 40.9 ± 7.8
38 | 25/18 | 41.8 ± 6.9 | 25/19 | 40.3 ± 7.6 | 24/15 | 41.8 ± 5.5 | 22/16 | 42.5 ± 7.2 | 20/15 | 43.6 ± 5.0 | 23/17 | 41.9 ± 7.6
39 | 25/18 | 42.2 ± 6.9 | 24/19 | 41.1 ± 7.6 | 22/14 | 41.7 ± 5.3 | 22/16 | 42.6 ± 7.5 | 20/15 | 44.2 ± 5.2 | 23/17 | 42.1 ± 7.6
40 | 25/18 | 42.6 ± 7.0 | 23/18 | 41.2 ± 8.0 | 22/14 | 41.7 ± 5.7 | 22/16 | 42.7 ± 7.9 | 19/14 | 45.2 ± 5.1 | 23/17 | 42.4 ± 7.7
41 | 25/18 | 43.0 ± 7.0 | 23/18 | 41.6 ± 8.2 | 21/13 | 42.7 ± 4.7 | 22/16 | 42.8 ± 8.4 | 19/14 | 45.8 ± 5.3 | 23/17 | 42.5 ± 7.8
42 | 25/18 | 43.4 ± 7.0 | 21/17 | 42.1 ± 8.5 | 20/12 | 42.9 ± 5.1 | 21/15 | 43.9 ± 8.0 | 19/14 | 46.4 ± 5.5 | 23/17 | 42.5 ± 8.0
43 | 25/18 | 43.8 ± 7.0 | 21/17 | 42.5 ± 8.7 | 20/12 | 43.2 ± 5.5 | 20/14 | 44.7 ± 8.1 | 19/14 | 47.0 ± 5.7 | 22/16 | 43.3 ± 7.7
44 | 25/18 | 44.3 ± 7.0 | 21/17 | 42.9 ± 8.8 | 20/12 | 43.4 ± 5.9 | 20/14 | 45.1 ± 8.3 | 18/13 | 48.1 ± 5.6 | 21/15 | 43.9 ± 7.7

a Unadjusted weights are given as mean ± standard error in grams. AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b Asterisks represent significance of pairwise comparisons with the vehicle control group for body weights adjusted for litter correlation by Dunnett’s test;

* P<0.05

** P<0.01

*** P<0.001.