# APPENDIX C CLINICAL PATHOLOGY RESULTS

TABLE C1 Hematology and Clinical Chemistry Data for Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Male
n | 20 | 24 | 21 | 22
Hematology
Hematocrit (%) | 45.7 ± 1.5 | 46.0 ± 1.9 | 47.5 ± 1.6 | 48.8 ± 1.2
Erythrocytes (10^6^/mm^3^) | 9.4 ± 0.3 | 9.5 ± 0.4 | 9.8 ± 0.3 | 10.1 ± 0.2
Mean cell volume (μm^3^) | 48.7 ± 0.3 | 48.4 ± 0.3 | 48.5 ± 0.2 | 48.4 ± 0.3
Mean cell hemoglobin (pg) | 16.0 ± 0.1 | 15.8 ± 0.1 | 15.8 ± 0.1 | 15.7 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 32.8 ± 0.1 | 32.7 ± 0.1 | 32.6 ± 0.2 | 32.4 ± 0.1
Platelets (10^3^/mm^3^) | 780.4 ± 30.5 | 785.9 ± 37.8 | 861.2 ± 38.0 | 842.0 ± 43.5
Leukocytes (10^3^/mm^3^) | 3.5 ± 0.7 | 3.3 ± 0.4 | 3.9 ± 0.4 | 3.8 ± 0.4
Neutrophils (%) | 5.4 ± 0.9 | 4.4 ± 0.6 | 3.4 ± 0.4 | 4.4 ± 0.8
Lymphocytes (%) | 85.8 ± 1.4 | 85.0 ± 1.3 | 89.5 ± 0.9 | 87.8 ± 1.2
Monocytes (%) | 5.0 ± 0.3 | 6.3 ± 0.6 | 4.7 ± 0.5 | 4.8 ± 0.4
Basophils (%) | 2.2 ± 0.3 | 2.6 ± 0.4 | 1.5 ± 0.2 | 2.0 ± 0.3
Eosinophils (%) | 1.5 ± 0.3 | 1.8 ± 0.5 | 0.8 ± 0.1 | 1.0 ± 0.2
Clinical Chemistry
Glucose (mg/dL) | 196.9 ± 11.4 | 197.4 ± 7.2 | 191.8 ± 8.5 | 196.9 ± 11.5
Total protein (g/dL) | 6.8 ± 0.1 | 7.1 ± 0.1 | 7.0 ± 0.1 | 7.1 ± 0.2
Alanine aminotransferase (U/L) | 38.7 ± 3.1^*^ | 38.9 ± 2.6 | 48.7 ± 5.3 | 55.6 ± 6.3^**^
Alkaline phosphatase (U/L) | 104.4 ± 22.1 | 77.5 ± 5.1 | 97.0 ± 6.7 | 81.5 ± 5.1
Female
n | 25 | 22 | 19 | 20
Hematology
Hematocrit (%) | 47.1 ± 0.7 | 46.8 ± 1.1 | 47.2 ± 1.2 | 45.4 ± 1.0
Erythrocytes (10^6^/mm^3^) | 9.7 ± 0.1 | 9.6 ± 0.2 | 9.7 ± 0.2 | 9.4 ± 0.2
Mean cell volume (μm^3^) | 48.6 ± 0.2 | 48.5 ± 0.2 | 49.0 ± 0.2 | 48.4 ± 0.2
Mean cell hemoglobin (pg) | 16.0 ± 0.1 | 15.9 ± 0.1 | 16.0 ± 0.1 | 15.8 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 44.7 ± 11.8 | 32.9 ± 0.1 | 32.7 ± 0.1 | 32.8 ± 0.1
Platelets (10^3^/mm^3^) | 724.7 ± 26.7 | 711.7 ± 34.2 | 700.1 ± 46.7 | 751.0 ± 31.5
Leukocytes (10^3^/mm^3^) | 4.3 ± 0.6 | 3.2 ± 0.2 | 4.5 ± 0.4 | 3.9 ± 0.4
Neutrophils (%) | 4.9 ± 0.6 | 4.2 ± 0.5 | 4.7 ± 0.8 | 4.0 ± 0.5
Lymphocytes (%) | 84.9 ± 1.2 | 85.4 ± 1.5 | 86.6 ± 1.6 | 86.5 ± 1.2
Monocytes (%) | 5.9 ± 0.6 | 6.0 ± 0.8 | 5.2 ± 0.5 | 6.2 ± 0.5
Basophils (%) | 2.6 ± 0.4 | 2.8 ± 0.5 | 2.2 ± 0.4 | 1.9 ± 0.3
Eosinophils (%) | 1.7 ± 0.3 | 1.6 ± 0.4 | 1.3 ± 0.3 | 1.4 ± 0.3
n | 25 | 22 | 19 | 20
Clinical Chemistry
Glucose (mg/dL) | 156.8 ± 8.3 | 163.7 ± 6.2 | 175.0 ± 9.0 | 170.7 ± 6.8
Total protein (g/dL) | 6.7 ± 0.1 | 6.8 ± 0.1 | 7.0 ± 0.1 | 6.5 ± 0.1
Alanine aminotransferase (U/L) | 30.7 ± 6.7 | 23.8 ± 1.2 | 22.7 ± 1.4 | 29.9 ± 3.8
Alkaline phosphatase (U/L) | 138.7 ± 22.8 | 116.1 ± 7.1 | 113.4 ± 7.3 | 128.4 ± 7.3

* Significant (P≤0.05) dose trend

** Significantly different (P≤0.01) from the vehicle control group by Dunnett’s test

a Data are presented as mean ± standard error. AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg.

TABLE C2 Hematology and Clinical Chemistry Data for Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
Male
n | 20 | 17 | 24 | 22 | 21 | 22
Hematology
Hematocrit (%) | 45.7 ± 1.5 | 50.1 ± 1.0 | 45.6 ± 1.4 | 48.3 ± 1.2 | 50.1 ± 1.4 | 48.8 ± 1.2
Erythrocytes (10^6^/mm^3^) | 9.4 ± 0.3 | 10.3 ± 0.2 | 9.4 ± 0.3 | 9.8 ± 0.2 | 10.2 ± 0.3 | 10.1 ± 0.2
Mean cell volume (μm^3^) | 48.7 ± 0.3 | 48.9 ± 0.3 | 48.7 ± 0.2 | 49.2 ± 0.2 | 49.0 ± 0.2 | 48.4 ± 0.3
Mean cell hemoglobin (pg) | 16.0 ± 0.1 | 15.9 ± 0.1 | 15.9 ± 0.1 | 16.0 ± 0.1 | 15.9 ± 0.1 | 15.7 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 32.8 ± 0.1 | 32.5 ± 0.1 | 32.7 ± 0.1 | 32.4 ± 0.1 | 32.5 ± 0.1 | 32.4 ± 0.1
Platelets (10^3^/mm^3^) | 780.4 ± 30.5 | 881.5 ± 26.1 | 854.2 ± 38.2 | 853.2 ± 32.7 | 913.1 ± 27.9 | 842.0 ± 43.5
Leukocytes (10^3^/mm^3^) | 3.5 ± 0.7 | 3.0 ± 0.4 | 3.7 ± 0.6 | 3.1 ± 0.4 | 3.8 ± 0.4 | 3.8 ± 0.4
Neutrophils (%) | 5.4 ± 0.9 | 3.6 ± 0.4 | 5.4 ± 1.0 | 3.7 ± 0.4 | 4.3 ± 1.3 | 4.4 ± 0.8
Lymphocytes (%) | 85.8 ± 1.4 | 87.8 ± 0.9 | 85.4 ± 1.5 | 87.2 ± 1.0 | 87.1 ± 2.2 | 87.8 ± 1.2
Monocytes (%) | 5.0 ± 0.3 | 5.2 ± 0.3 | 5.6 ± 0.4 | 6.3 ± 0.6 | 6.1 ± 0.8 | 4.8 ± 0.4
Basophils (%) | 2.2 ± 0.3 | 2.1 ± 0.4 | 2.2 ± 0.4 | 1.7 ± 0.2 | 1.6 ± 0.3 | 2.0 ± 0.3
Eosinophils (%) | 1.5 ± 0.3 | 1.3 ± 0.3 | 1.4 ± 0.3 | 1.1 ± 0.3 | 0.9 ± 0.2 | 1.0 ± 0.2
Clinical Chemistry
Glucose (mg/dL) | 196.9 ± 11.4 | 209.5 ± 13.0 | 205.9 ± 10.8 | 172.1 ± 9.7 | 184.4 ± 10.9 | 196.9 ± 11.5
Total protein (g/dL) | 6.8 ± 0.1 | 6.9 ± 0.2 | 6.8 ± 0.2 | 6.9 ± 0.1 | 7.0 ± 0.2 | 7.1 ± 0.2
Alanine aminotransferase (U/L) | 38.7 ± 3.1 | 43.8 ± 3.3 | 59.3 ± 26.1 | 35.9 ± 2.7 | 44.0 ± 3.1 | 55.6 ± 6.3^*^
Alkaline phosphatase (U/L) | 104.4 ± 22.1 | 98.1 ± 5.9 | 105.7 ± 12.3 | 91.2 ± 9.2 | 90.4 ± 4.1 | 81.5 ± 5.1
Female
n | 25 | 20 | 19 | 20 | 19 | 20
Hematology
Hematocrit (%) | 47.1 ± 0.7 | 45.9 ± 1.1 | 45.0 ± 0.9 | 46.1 ± 1.8 | 46.8 ± 1.5 | 45.4 ± 1.0
Erythrocytes (10^6^/mm^3^) | 9.7 ± 0.1 | 9.5 ± 0.2 | 9.2 ± 0.2 | 9.4 ± 0.4 | 9.6 ± 0.3 | 9.4 ± 0.2
Mean cell volume (μm^3^) | 48.6 ± 0.2 | 48.6 ± 0.2 | 48.6 ± 0.2 | 48.8 ± 0.3 | 48.6 ± 0.3 | 48.4 ± 0.2
Mean cell hemoglobin (pg) | 16.0 ± 0.1 | 16.0 ± 0.1 | 15.9 ± 0.1 | 16.0 ± 0.1 | 15.9 ± 0.1 | 15.8 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 44.7 ± 11.8 | 33.0 ± 0.1 | 32.7 ± 0.1 | 32.8 ± 0.1 | 32.7 ± 0.1 | 32.8 ± 0.1
Platelets (10^3^/mm^3^) | 724.7 ± 26.7 | 689.9 ± 24.2 | 699.6 ± 27.3 | 757.0 ± 33.5 | 756.9 ± 40.2 | 751.0 ± 31.5
Leukocytes (10^3^/mm^3^) | 4.3 ± 0.6 | 3.6 ± 0.3 | 3.5 ± 0.3 | 3.8 ± 0.4 | 4.8 ± 0.6 | 3.9 ± 0.4
Neutrophils (%) | 4.9 ± 0.6 | 4.6 ± 0.7 | 4.4 ± 0.5 | 4.5 ± 0.8 | 4.0 ± 1.0 | 4.0 ± 0.5
Lymphocytes (%) | 84.9 ± 1.2 | 84.4 ± 1.6 | 84.5 ± 1.2 | 87.0 ± 1.3 | 87.6 ± 1.5 | 86.5 ± 1.2
Monocytes (%) | 5.9 ± 0.6 | 6.9 ± 0.9 | 6.5 ± 0.6 | 6.0 ± 0.5 | 5.4 ± 0.4 | 6.2 ± 0.5
Basophils (%) | 2.6 ± 0.4 | 2.6 ± 0.3 | 2.9 ± 0.4 | 1.8 ± 0.2 | 1.8 ± 0.3 | 1.9 ± 0.3
Eosinophils (%) | 1.7 ± 0.3 | 1.5 ± 0.2 | 1.7 ± 0.3 | 1.2 ± 0.2 | 1.2 ± 0.2 | 1.4 ± 0.3
n | 25 | 20 | 19 | 20 | 19 | 20
Clinical Chemistry
Glucose (mg/dL) | 156.8 ± 8.3 | 154.4 ± 7.5 | 168.5 ± 7.8 | 158.5 ± 6.6 | 169.8 ± 7.5 | 170.7 ± 6.8
Total Protein (g/dL) | 6.7 ± 0.1 | 6.6 ± 0.1 | 6.5 ± 0.1 | 6.6 ± 0.1 | 6.5 ± 0.1 | 6.5 ± 0.1
Alanine aminotransferase (U/L) | 30.7 ± 6.7 | 26.9 ± 1.0 | 23.7 ± 1.6 | 27.4 ± 3.4 | 28.6 ± 2.2 | 29.9 ± 3.8
Alkaline phosphatase (U/L) | 138.7 ± 22.8 | 120.7 ± 6.9 | 184.6 ± 62.0 | 130.1 ± 24.1 | 126.7 ± 11.5 | 128.4 ± 7.3

* Significantly different (P≤0.05) from the vehicle control group by Tukey’s test

a Data are presented as mean ± standard error. AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP