# APPENDIX B GENETIC TOXICOLOGY

TABLE B1 Frequency of Micronuclei in Peripheral Blood Erythrocytes and Reticulocytes in 1-Day-Old Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP^a^

| %RET | % Micronucleated NCE | % Micronucleated RET
Male
Vehicle Control^b^ | 5 | 5 | 5
Mean ± standard error | 20.0 ± 1.4 | 0.2 ± 0.0 | 0.5 ± 0.1
Tukey test^c^ | A | A | A
AZT-H | 8 | 8 | 8
Mean ± standard error | 8.7 ± 1.2 | 3.9 ± 0.9 | 6.2 ± 1.2
Tukey test | B | B | B
Dunnett’s Test P value^d^ | P<0.001 | P<0.001 | P=0.008
3TC-H | 5 | 5 | 5
Mean ± standard error | 20.8 ± 2.2 | 0.2 ± 0.0 | 0.5 ± 0.1
Tukey test | A | A | A
Dunnett’s Test P value | NS | NS | NS
NVP-H | 5 | 5 | 5
Mean ± standard error | 18.9 ± 0.1 | 0.2 ± 0.0 | 0.4 ± 0.0
Tukey test | A | A | A
Dunnett’s Test P value | NS | NS | NS
AZT/3TC-H | 6 | 6 | 6
Mean ± standard error | 5.8 ± 0.7 | 4.3 ± 0.4 | 7.3 ± 1.0
Tukey test | B | B | B
Dunnett’s Test P value | P<0.001 | P<0.001 | P=0.003
AZT/3TC/NVP-M | 3 | 3 | 3
Mean ± standard error | 5.8 ± 0.7 | 3.5 ± 0.5 | 9.6 ± 4.7
Tukey test | B | B | B
Dunnett’s Test P value | P<0.001 | P=0.045 | P=0.001
AZT/3TC/NVP-H | 6 | 6 | 6
Mean ± standard error | 6.2 ± 0.7 | 6.7 ± 0.4 | 7.9 ± 1.4
Tukey test | B | C | B
Dunnett’s Test P value | P<0.001 | P<0.001 | P=0.001
Female
Vehicle Control | 5 | 5 | 5
Mean ± standard error | 19.6 ± 2.4 | 0.2 ± 0.0 | 0.5 ± 0.1
Tukey test | A | A | A
AZT-H | 5 | 5 | 5
Mean ± standard error | 5.6 ± 0.6 | 3.7 ± 0.6 | 9.4 ± 3.6
Tukey test | B | B | AB
Dunnett’s Test P value | P<0.001 | P<0.001 | P=0.014
3TC-H | 3 | 3 | 3
Mean ± standard error | 17.2 ± 1.2 | 0.2 ± 0.1 | 0.5 ± 0.0
Tukey test | A | A | AB
Dunnett’s Test P value | NS | NS | NS
NVP-H | 3 | 5 | 5
Mean ± standard error | 17.4 ± 0.4 | 0.2 ± 0.0 | 0.4 ± 0.0
Tukey test | A | A | A
Dunnett’s Test P value | NS | NS | NS
AZT/3TC-H | 5 | 5 | 5
Mean ± standard error | 6.3 ± 0.8 | 3.1 ± 0.3 | 6.5 ± 1.5
Tukey test | B | B | A
Dunnett’s Test P value | P<0.001 | P<0.001 | NS
AZT/3TC/NVP-M | 4 | 4 | 4
Mean ± standard error | 5.6 ± 0.5 | 3.8 ± 0.4 | 8.3 ± 2.2
Tukey test | B | B | AB
Dunnett’s Test P value | P<0.001 | P<0.001 | P=0.043
AZT/3TC/NVP-H | 5 | 5 | 5
Mean ± standard error | 6.2 ± 0.9 | 6.4 ± 0.6 | 10.3 ± 3.0
Tukey test | B | C | B
Dunnett’s Test P value | P<0.001 | P<0.001 | P=0.007

a NCE = normochromatic erythrocytes; RET = reticulocytes. Dams were dosed from gestational day (GD) 12 through GD 18 with the listed doses; AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-M = 160/100/112 mg/kg AZT/3TC/NVP; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b Number examined

c Letters associated with an exposure group represent significance of Tukey test evaluation. Groups with different letters are significantly different from each other (P<0.05).

d Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that exposed group. Two-tailed Dunnett’s tests were used for the % RET values and one-tailed Dunnett’s tests were used for the % micronucleated NCE and % micronucleated RET values. NS = Not significant

TABLE B2 Frequency of Micronuclei in Peripheral Blood Erythrocytes and Reticulocytes in 28-Day-Old Heterozygous F1 p53^+/−^ Male Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP^a^

| % RET | % Micronucleated NCE | % Micronucleated RET
Vehicle Control^b^ | 8 | 8 | 8
Mean ± standard error | 6.80 ± 0.2 | 0.23 ± 0.01 | 0.27 ± 0.02
Tukey test^c^ | A | A | A
AZT-H | 7 | 7 | 7
Mean ± standard error | 6.19 ± 0.3 | 5.02 ± 0.5 | 2.47 ± 0.40
Tukey test | A | B | B
3TC-H | 8 | 8 | 8
Mean ± standard error | 7.03 ± 0.2 | 0.27 ± 0.01 | 0.29 ± 0.01
Tukey test | A | A | A
AZT/3TC-H | 7 | 7 | 7
Mean ± standard error | 7.290 ± 0.7 | 6.50 ± 0.35 | 4.11 ± 0.46
Tukey test | A | C | C

a NCE = normochromatic erythrocytes; RET = reticulocytes; AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; AZT/3TC-H = 240/150 mg/kg AZT/3TC

b Number examined

c Letters associated with a dose group represent significance of Tukey test evaluation. Groups with different letters are significantly different from each other (P<0.05).