# APPENDIX A SUMMARY OF LESIONS IN HETEROZYGOUS F1 p53^+/−^ MICE IN THE IN UTERO/POSTNATAL GAVAGE STUDY OF AZT, 3TC, AND NVP

TABLE A1 Summary of the Incidence of Neoplasms in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Disposition Summary
Animals initially in study | 25 | 25 | 25 | 25
Early deaths
Moribund | 2
Natural deaths | 1 | 1 | | 1
Survivors
Died/moribund after day 320 | 2 | | 1 | 1
Terminal kill | 20 | 24 | 22 | 22
Removals | | | 2 | 1
Animals examined microscopically | 25 | 25 | 23 | 24
Alimentary System
Esophagus | (25) | (25) | (23) | (24)
Gallbladder | (22) | (24) | (23) | (23)
Intestine large, cecum | (22) | (24) | (23) | (23)
Intestine large, colon | (22) | (24) | (23) | (23)
Intestine large, rectum | (22) | (24) | (23) | (23)
Intestine small, duodenum | (23) | (24) | (23) | (23)
Leiomyosarcoma | 1 (4%)
Intestine small, ileum | (22) | (24) | (23) | (23)
Intestine small, jejunum | (23) | (24) | (23) | (23)
Adenocarcinoma | 1 (4%)
Liver | (25) | (25) | (23) | (23)
Hepatocellular adenoma | 1 (4%) | 4 (16%) | 5 (22%) | 7 (30%)
Hepatocellular adenoma, multiple | | 3 (12%) | 2 (9%) | 2 (9%)
Hepatocellular carcinoma | | 2 (8%) | 2 (9%)
Hepatocellular carcinoma, multiple | | | | 1 (4%)
Mesentery | (3) | (1) | (2) | (0)
Hemangiosarcoma | | 1 (100%)
Leiomyosarcoma, metastatic, intestine small, duodenum | 1 (33%)
Sarcoma | 1 (33%)
Pancreas | (24) | (25) | (23) | (23)
Leiomyosarcoma, metastatic, intestine small, duodenum | 1 (4%)
Sarcoma, metastatic, tissue NOS | 1 (4%)
Salivary glands | (25) | (25) | (23) | (23)
Stomach, forestomach | (25) | (25) | (23) | (23)
Stomach, glandular | (23) | (24) | (23) | (23)
Cardiovascular System
Blood vessel | (25) | (25) | (23) | (24)
Heart | (25) | (25) | (23) | (24)
Endocrine System
Adrenal cortex | (25) | (25) | (23) | (23)
Adrenal medulla | (25) | (25) | (23) | (22)
Pheochromocytoma benign | | | 1 (4%)
Islets, pancreatic | (24) | (25) | (23) | (23)
Parathyroid gland | (23) | (23) | (23) | (23)
Pituitary gland | (24) | (25) | (23) | (23)
Thyroid gland | (25) | (25) | (23) | (23)
General Body System
Tissue NOS | (1) | (0) | (0) | (0)
Abdominal, sarcoma | 1 (100%)
Genital System
Epididymis | (25) | (25) | (23) | (23)
Preputial gland | (25) | (25) | (23) | (23)
Squamous cell carcinoma | | | 1 (4%)
Squamous cell papilloma | | | | 1 (4%)
Prostate | (25) | (25) | (23) | (23)
Seminal vesicle | (25) | (25) | (23) | (23)
Testes | (25) | (25) | (23) | (23)
Hematopoietic System
Bone marrow | (23) | (25) | (23) | (23)
Lymph node | (2) | (3) | (1) | (1)
Mediastinal, sarcoma, metastatic, tissue NOS | 1 (50%)
Lymph node, mandibular | (25) | (25) | (23) | (23)
Lymph node, mesenteric | (24) | (25) | (23) | (23)
Sarcoma, metastatic, tissue NOS | 1 (4%)
Spleen | (25) | (25) | (23) | (23)
Thymus | (24) | (25) | (20) | (20)
Integumentary System
Mammary gland | (1) | (1) | (0) | (0)
Skin | (25) | (25) | (23) | (24)
Osteosarcoma, metastatic, bone | | | | 1 (4%)
Squamous cell papilloma | | | 1 (4%)
Musculoskeletal System
Bone | (3) | (0) | (1) | (1)
Osteosarcoma | 1 (33%)
Cranium, neuroblastoma, metastatic, nose | | | 1 (100%)
Humerus, osteosarcoma | 1 (33%)
Rib, osteosarcoma | | | | 1 (100%)
Tibia, osteosarcoma | 1 (33%)
Bone, femur | (25) | (25) | (23) | (24)
Skeletal muscle | (3) | (0) | (0) | (0)
Leiomyosarcoma, metastatic, intestine small, duodenum | 1 (33%)
Diaphragm, sarcoma, metastatic, tissue NOS | 1 (33%)
Nervous System
Brain, brain stem | (25) | (24) | (23) | (23)
Brain, cerebellum | (25) | (24) | (23) | (23)
Brain, cerebrum | (25) | (25) | (23) | (23)
Olfactory lobe, neuroblastoma, metastatic, nose | | | 1 (4%)
Peripheral nerve | (1) | (0) | (0) | (0)
Spinal cord, cervical | (1) | (0) | (0) | (0)
Spinal cord, lumbar | (1) | (0) | (0) | (0)
Spinal cord, thoracic | (1) | (0) | (0) | (0)
Respiratory System
Lung | (25) | (25) | (23) | (23)
Alveolar/bronchiolar adenoma | | | 2 (9%)
Osteosarcoma, metastatic, bone | 1 (4%)
Nose | (25) | (25) | (23) | (24)
Neuroblastoma | | | 1 (4%)
Trachea | (25) | (25) | (23) | (23)
Special Senses System
Eye | (22) | (24) | (23) | (23)
Harderian gland | (25) | (25) | (23) | (23)
Adenoma | | 1 (4%)
Neuroblastoma, metastatic, nose | | | 1 (4%)
Urinary System
Kidney | (25) | (25) | (23) | (23)
Urinary bladder | (25) | (25) | (23) | (23)
Systemic Lesions
Multiple organs^b^ | (25) | (25) | (23) | (24)
Leukemia granulocytic | | 1 (4%)
Lymphoma malignant | 1 (4%) | | 1 (4%) | 2 (8%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 7 | 11 | 13 | 14
Total primary neoplasms | 9 | 12 | 16 | 14
Total animals with benign neoplasms | 1 | 7 | 11 | 10
Total benign neoplasms | 1 | 8 | 11 | 10
Total animals with malignant neoplasms | 7 | 4 | 5 | 4
Total malignant neoplasms | 8 | 4 | 5 | 4
Total animals with metastatic neoplasms | 3 | | 1 | 1
Total metastatic neoplasms | 8 | | 3 | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm. AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A2 Statistical Analysis of Primary Neoplasms in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Bone: Osteosarcoma
Overall rate^b^ | 3/25 (12.0%) | 0/25 (0.0%) | 0/23 (0.0%) | 1/24 (4.2%)
Adjusted rate^c^ | 3/23.9 (12.6%) | 0/24.8 (0.0%) | 0/22.9 (0.0%) | 1/22.9 (4.4%)
Terminal rate^d^ | 1/20 (5.0%) | 0/24 (0.0%) | 0/22 (0.0%) | 1/22 (4.5%)
First incidence (days) | 207 | —^f^ | — | 326 (T)
Poly-3 test^e^ | P=0.137N | P=0.107N | P=0.121N | P=0.319N
Liver: Hepalocellular Adenoma
Overall rate | 1/25 (4.0%) | 7/25 (28.0%) | 7/23 (30.4%) | 9/23 (39.1%)
Adjusted rate | 1/22.9 (4.4%) | 7/24.8 (28.3%) | 7/22.9 (30.5%) | 9/22.8 (39.4%)
Terminal rate | 0/20 (0.0%) | 7/24 (29.2%) | 7/22 (31.8%) | 9/22 (40.9%)
First incidence (days) | 313 | 315 (T) | 318 (T) | 316 (T)
Poly-3 test | P=0.006 | P=0.030 | P=0.021 | P=0.003
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 1/25 (4.0%) | 9/25 (36.0%) | 8/23 (34.8%) | 10/23 (43.5%)
Adjusted rate | 1/22.9 (4.4%) | 9/24.8 (36.4%) | 8/22.9 (34.9%) | 10/22.8 (43.8%)
Terminal rate | 0/20 (0.0%) | 9/24 (37.5%) | 8/22 (36.4%) | 10/22 (45.5%)
First incidence (days) | 313 | 315 (T) | 318 (T) | 316 (T)
Poly-3 test | P=0.004 | P=0.006 | P=0.009 | P=0.001
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 0/25 (0.0%) | 0/25 (0.0%) | 2/23 (8.7%) | 0/23 (0.0%)
Adjusted rate | 0/22.8 (0.0%) | 0/24.8 (0.0%) | 2/22.9 (8.7%) | 0/22.8 (0.0%)
Terminal rate | 0/20 (0.0%) | 0/24 (0.0%) | 2/22 (9.1%) | 0/22 (0.0%)
First incidence (days) | — | — | 318 (T) | —
Poly-3 test | P=0.379 | —^g^ | P=0.236 | —
All Organs: Malignant Lymphoma
Overall rate | 1/25 (4.0%) | 0/25 (0.0%) | 1/23 (4.3%) | 2/24 (8.3%)
Adjusted rate | 1/23.6 (4.2%) | 0/24.8 (0.0%) | 1/22.9 (4.4%) | 2/23.0 (8.7%)
Terminal rate | 0/20 (0.0%) | 0/24 (0.0%) | 1/22 (4.5%) | 1/22 (4.5%)
First incidence (days) | 176 | — | 325 (T) | 307
Poly-3 test | P=0.238 | P=0.491N | P=0.754 | P=0.491
All Organs: Osteosarcoma
Overall rate | 3/25 (12.0%) | 0/25 (0.0%) | 0/23 (0.0%) | 1/24 (4.2%)
Adjusted rate | 3/23.9 (12.6%) | 0/24.8 (0.0%) | 0/22.9 (0.0%) | 1/22.9 (4.4%)
Terminal rate | 1/20 (5.0%) | 0/24 (0.0%) | 0/22 (0.0%) | 1/22 (4.5%)
First incidence (days) | 207 | — | — | 326 (T)
Poly-3 test | P=0.137N | P=0.107N | P=0.121N | P=0.319N
All Organs: Malignant Neoplasms
Overall rate | 7/25 (28.0%) | 4/25 (16.0%) | 5/23 (21.7%) | 4/24 (16.7%)
Adjusted rate | 7/25.0 (28.0%) | 4/25.0 (16.0%) | 5/23.0 (21.7%) | 4/23.0 (17.4%)
Terminal rate | 2/20 (10.0%) | 3/24 (12.5%) | 4/22 (18.2%) | 3/22 (13.6%)
First incidence (days) | 176 | 297 | 318 (T) | 307
Poly-3 test | P=0.278N | P=0.249N | P=0.435N | P=0.300N
All Organs: Benign Neoplasms
Overall rate | 1/25 (4.0%) | 7/25 (28.0%) | 11/23 (47.8%) | 10/24 (41.7%)
Adjusted rate | 1/22.9 (4.4%) | 7/24.8 (28.3%) | 11/23.0 (47.8%) | 10/22.9 (43.8%)
Terminal rate | 0/20 (0.0%) | 7/24 (29.2%) | 10/22 (45.5%) | 10/22 (45.5%)
First incidence (days) | 313 | 315 (T) | 318 (T) | 316 (T)
Poly-3 test | P<0.001 | P=0.030 | P<0.001 | P=0.001
All Organs: Benign or Malignant Neoplasms
Overall rate | 7/25 (28.0%) | 11/25 (44.0%) | 13/23 (56.5%) | 14/24 (58.3%)
Adjusted rate | 7/25.0 (28.0%) | 11/25.0 (44.0%) | 13/23.0 (56.5%) | 14/23.0 (60.8%)
Terminal rate | 2/20 (10.0%) | 10/24 (41.7%) | 12/22 (54.5%) | 13/22 (59.1%)
First incidence (days) | 176 | 297 | 318 (T) | 307
Poly-3 test | P=0.009 | P=0.190 | P=0.040 | P=0.019

(T) Terminal kill

a AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg

b Number of neoplasm-bearing animals/number of animals with tissue examined microscopically

c Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

d Observed incidence at terminal kill

e Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

f Not applicable; no neoplasms in animal group

g Value of statistic cannot be computed.

TABLE A3 Summary of the Incidence of Nonneoplastic Lesions in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Disposition Summary
Animals initially in study | 25 | 25 | 25 | 25
Early deaths
Moribund | 2
Natural deaths | 1 | 1 | | 1
Survivors
Died/moribund after day 320 | 2 | | 1 | 1
Terminal kill | 20 | 24 | 22 | 22
Removals | | | 2 | 1
Animals examined microscopically | 25 | 25 | 23 | 24
Alimentary System
Esophagus | (25) | (25) | (23) | (24)
Gallbladder | (22) | (24) | (23) | (23)
Intestine large, cecum | (22) | (24) | (23) | (23)
Intestine large, colon | (22) | (24) | (23) | (23)
Intestine large, rectum | (22) | (24) | (23) | (23)
Intestine small, duodenum | (23) | (24) | (23) | (23)
Ectopic pancreas | | | | 1 (4%)
Intestine small, ileum | (22) | (24) | (23) | (23)
Intestine small, jejunum | (23) | (24) | (23) | (23)
Liver | (25) | (25) | (23) | (23)
Basophilic focus | | | 2 (9%) | 2 (9%)
Hematopoietic cell proliferation | 1 (4%) | 1 (4%)
Infiltration cellular, lymphocyte | | 1 (4%) | 1 (4%)
Inflammation, suppurative | | | 1 (4%)
Inflammation, chronic active | | 1 (4%) | 1 (4%) | 1 (4%)
Necrosis | 1 (4%) | 1 (4%) | 1 (4%) | 2 (9%)
Tension lipidosis | | 2 (8%) | 2 (9%) | 1 (4%)
Vacuolization cytoplasmic | 19 (76%) | 21 (84%) | 19 (83%) | 20 (87%)
Centrilobular, degeneration | 15 (60%) | 20 (80%) | 18 (78%) | 17 (74%)
Mesentery | (3) | (1) | (2) | (0)
Fat, necrosis | 1 (33%) | | 2 (100%)
Pancreas | (24) | (25) | (23) | (23)
Cyst | 1 (4%)
Infiltration cellular, lymphocyte | | 2 (8%)
Acinus, degeneration | | | 1 (4%)
Salivary glands | (25) | (25) | (23) | (23)
Infiltration cellular, lymphocyte | 18 (72%) | 14 (56%) | 16 (70%) | 16 (70%)
Stomach, forestomach | (25) | (25) | (23) | (23)
Hyperkeratosis | | | 1 (4%)
Epithelium, hyperplasia | 1 (4%)
Stomach, glandular | (23) | (24) | (23) | (23)
Cardiovascular System
Blood vessel | (25) | (25) | (23) | (24)
Heart | (25) | (25) | (23) | (24)
Mineralization | | 1 (4%)
Endocrine System
Adrenal cortex | (25) | (25) | (23) | (23)
Accessory adrenal cortical nodule | 1 (4%) | | | 1 (4%)
Hypertrophy | | | 1 (4%) | 2 (9%)
Subcapsular, hyperplasia | 13 (52%) | 14 (56%) | 11 (48%) | 12 (52%)
Adrenal medulla | (25) | (25) | (23) | (22)
Islets, pancreatic | (24) | (25) | (23) | (23)
Hyperplasia | 13 (54%) | 9 (36%) | 13 (57%) | 6 (26%)
Parathyroid gland | (23) | (23) | (23) | (23)
Pituitary gland | (24) | (25) | (23) | (23)
Thyroid gland | (25) | (25) | (23) | (23)
Ectopic thymus | 2 (8%)
Follicle, degeneration | | | | 1 (4%)
General Body System
Tissue NOS | (1) | (0) | (0) | (0)
Genital System
Epididymis | (25) | (25) | (23) | (23)
Exfoliated germ cell | | | | 1 (4%)
Hypospermia | | | | 1 (4%)
Inflammation, chronic active | | | 1 (4%)
Preputial gland | (25) | (25) | (23) | (23)
Cyst | | 1 (4%)
Infiltration cellular, lymphocyte | | 1 (4%)
Inflammation, suppurative | | | 1 (4%)
Inflammation, chronic active | 1 (4%) | | 1 (4%)
Keratin cyst | | 1 (4%)
Acinus, degeneration | 3 (12%) | 4 (16%) | 7 (30%) | 5 (22%)
Duct, ectasia | 3 (12%) | 3 (12%) | 5 (22%) | 5 (22%)
Prostate | (25) | (25) | (23) | (23)
Inflammation, suppurative | | | 1 (4%)
Seminal vesicle | (25) | (25) | (23) | (23)
Testes | (25) | (25) | (23) | (23)
Seminiferous tubule, degeneration | | | 1 (4%) | 1 (4%)
Hematopoietic System
Bone marrow | (23) | (25) | (23) | (23)
Hyperplasia | 3 (13%) | 2 (8%) | 4 (17%)
Lymph node | (2) | (3) | (1) | (1)
Axillary, hyperplasia, lymphoid | | 1 (33%)
Lumbar, hyperplasia, lymphoid | | 1 (33%)
Mediastinal, hyperplasia, lymphoid | 1 (50%) | 2 (67%)
Mediastinal, infiltration cellular, plasma cell | | 1 (33%)
Renal, hyperplasia, lymphoid | | 1 (33%)
Lymph node, mandibular | (25) | (25) | (23) | (23)
Hyperplasia, lymphoid | 2 (8%) | 2 (8%) | 4 (17%) | 5 (22%)
Infiltration cellular, plasma cell | | | 1 (4%)
Lymph node, mesenteric | (24) | (25) | (23) | (23)
Hyperplasia, lymphoid | 9 (38%) | 10 (40%) | 5 (22%) | 9 (39%)
Infiltration cellular, plasma cell | | 1 (4%) | 1 (4%)
Infiltration cellular, polymorphonuclear | | | 1 (4%)
Spleen | (25) | (25) | (23) | (23)
Hematopoietic cell proliferation | 7 (28%) | 9 (36%) | 6 (26%) | 6 (26%)
Hyperplasia, lymphoid | 12 (48%) | 15 (60%) | 13 (57%) | 12 (52%)
Thymus | (24) | (25) | (20) | (20)
Atrophy | 2 (8%) | 1 (4%) | | 1 (5%)
Hyperplasia, lymphoid | 2 (8%) | 3 (12%) | 1 (5%) | 1 (5%)
Integumentary System
Mammary gland | (1) | (1) | (0) | (0)
Skin | (25) | (25) | (23) | (24)
Inflammation, suppurative | | | | 1 (4%)
Epithelium, hyperplasia | | | | 1 (4%)
Musculoskeletal System
Bone | (3) | (0) | (1) | (1)
Bone, femur | (25) | (25) | (23) | (24)
Fibro-osseous lesion | 1 (4%) | | 1 (4%)
Skeletal muscle | (3) | (0) | (0) | (0)
Nervous System
Brain, brain stem | (25) | (24) | (23) | (23)
Brain, cerebellum | (25) | (24) | (23) | (23)
Brain, cerebrum | (25) | (25) | (23) | (23)
Mineralization | 2 (8%) | 1 (4%) | 3 (13%) | 1 (4%)
Peripheral nerve | (1) | (0) | (0) | (0)
Spinal cord, cervical | (1) | (0) | (0) | (0)
Spinal cord, lumbar | (1) | (0) | (0) | (0)
Spinal cord, thoracic | (1) | (0) | (0) | (0)
Compression | 1 (100%)
Respiratory System
Lung | (25) | (25) | (23) | (23)
Hemorrhage | | 1 (4%)
Alveolar epithelium, hyperplasia | | 1 (4%) | | 1 (4%)
Nose | (25) | (25) | (23) | (24)
Hyaline droplet | | 3 (12%) | 2 (9%)
Trachea | (25) | (25) | (23) | (23)
Special Senses System
Eye | (22) | (24) | (23) | (23)
Harderian gland | (25) | (25) | (23) | (23)
Infiltration cellular, lymphocyte | 1 (4%) | 1 (4%) | 1 (4%)
Urinary System
Kidney | (25) | (25) | (23) | (23)
Casts protein | 3 (12%) | 7 (28%) | 7 (30%) | 10 (43%)
Cyst | | | 1 (4%)
Hydronephrosis | 1 (4%) | 13 (52%) | 5 (22%) | 12 (52%)
Infarct | | | 1 (4%)
Infiltration cellular, lymphocyte | 8 (32%) | 9 (36%) | 9 (39%) | 7 (30%)
Nephropathy | 1 (4%) | | | 1 (4%)
Urinary bladder | (25) | (25) | (23) | (23)
Infiltration cellular, lymphocyte | 2 (8%) | 1 (4%) | 1 (4%) | 1 (4%)
Lumen, dilatation | 1 (4%)

a Number of animals examined microscopically at the site and the number of animals with lesion. AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg.

TABLE A4 Summary of the Incidence of Neoplasms in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
Disposition Summary
Animals initially in study | 25 | 25 | 25 | 26 | 25 | 25
Early deaths
Moribund | 2 | 4 | | | 3
Natural deaths | 1 | 2 | 2 | 4 | | 1
Survivors
Died/moribund after day 320 | 2 | | | | 1 | 1
Terminal kill | 20 | 18 | 23 | 22 | 21 | 22
Removals | | 1 | | | | 1
Animals examined microscopically | 25 | 24 | 25 | 26 | 25 | 24
Alimentary System
Esophagus | (25) | (23) | (25) | (25) | (24) | (24)
Gallbladder | (22) | (21) | (25) | (22) | (24) | (23)
Intestine large, cecum | (22) | (22) | (24) | (22) | (24) | (23)
Adenoma | | | | 1 (5%)
Intestine large, colon | (22) | (22) | (25) | (23) | (24) | (23)
Intestine large, rectum | (22) | (22) | (23) | (22) | (24) | (23)
Intestine small, duodenum | (23) | (22) | (23) | (22) | (24) | (23)
Leiomyosarcoma | 1 (4%)
Intestine small, ileum | (22) | (22) | (24) | (22) | (24) | (23)
Intestine small, jejunum | (23) | (22) | (23) | (22) | (24) | (23)
Adenocarcinoma | 1 (4%)
Liver | (25) | (23) | (25) | (25) | (25) | (23)
Hemangiosarcoma | | | | | 1 (4%)
Hepatocellular adenoma | 1 (4%) | 4 (17%) | 2 (8%) | 2 (8%) | 7 (28%) | 7 (30%)
Hepatocellular adenoma, multiple | | 4 (17%) | 1 (4%) | | 2 (8%) | 2 (9%)
Hepatocellular carcinoma, multiple | | | | | 1 (4%) | 1 (4%)
Sarcoma, metastatic, uncertain primary site | | | 1 (4%)
Capsule, alveolar/bronchiolar carcinoma, metastatic, lung | | | 1 (4%)
Mesentery | (3) | (0) | (0) | (1) | (2) | (0)
Fibrosarcoma | | | | | 1 (50%)
Leiomyosarcoma, metastatic, intestine small, duodenum | 1 (33%)
Sarcoma | 1 (33%) | | | 1 (100%)
Pancreas | (24) | (23) | (25) | (25) | (24) | (23)
Alveolar/bronchiolar carcinoma, metastatic, lung | | | 1 (4%)
Leiomyosarcoma, metastatic, intestine small, duodenum | 1 (4%)
Sarcoma, metastatic, tissue NOS | 1 (4%)
Sarcoma, metastatic, uncertain primary site | | | 1 (4%)
Salivary glands | (25) | (23) | (25) | (25) | (24) | (23)
Stomach, forestomach | (25) | (23) | (25) | (23) | (24) | (23)
Stomach, glandular | (23) | (22) | (24) | (22) | (24) | (23)
Cardiovascular System
Blood vessel | (25) | (23) | (25) | (25) | (24) | (24)
Alveolar/bronchiolar carcinoma, metastatic, lung | | | 1 (4%)
Heart | (25) | (24) | (25) | (25) | (24) | (24)
Alveolar/bronchiolar carcinoma, metastatic, lung | | | 1 (4%)
Endocrine System
Adrenal cortex | (25) | (23) | (25) | (25) | (23) | (23)
Adrenal medulla | (25) | (23) | (25) | (23) | (21) | (22)
Islets, pancreatic | (24) | (23) | (25) | (25) | (24) | (23)
Parathyroid gland | (23) | (20) | (24) | (18) | (19) | (23)
Pituitary gland | (24) | (21) | (25) | (25) | (24) | (23)
Thyroid gland | (25) | (23) | (25) | (23) | (23) | (23)
General Body System
Tissue NOS | (1) | (0) | (1) | (3) | (0) | (0)
Abdominal, sarcoma | 1 (100%) | | 1 (100%) | 1 (33%)
Genital System
Epididymis | (25) | (23) | (25) | (25) | (24) | (23)
Sarcoma, metastatic, uncertain primary site | | | 1 (4%)
Preputial gland | (25) | (24) | (25) | (25) | (24) | (23)
Squamous cell papilloma | | | | | | 1 (4%)
Prostate | (25) | (23) | (25) | (25) | (24) | (23)
Seminal vesicle | (25) | (23) | (24) | (25) | (24) | (23)
Sarcoma, metastatic, uncertain primary site | | | 1 (4%)
Testes | (25) | (24) | (24) | (25) | (24) | (23)
Hematopoietic System
Bone marrow | (23) | (24) | (24) | (25) | (24) | (23)
Lymph node | (2) | (2) | (1) | (1) | (2) | (1)
Sarcoma, metastatic, uncertain primary site | | | 1 (100%)
Mediastinal, sarcoma, metastatic, tissue NOS | 1 (50%)
Mediastinal, sarcoma, metastatic, uncertain primary site | | | 1 (100%)
Lymph node, mandibular | (25) | (23) | (25) | (25) | (24) | (23)
Lymph node, mesenteric | (24) | (23) | (25) | (25) | (24) | (23)
Sarcoma, metastatic, tissue NOS | 1 (4%)
Sarcoma, metastatic, uncertain primary site | | | 1 (4%)
Spleen | (25) | (23) | (24) | (25) | (24) | (23)
Hemangiosarcoma | | | | | 1 (4%)
Thymus | (24) | (22) | (24) | (23) | (22) | (20)
Sarcoma, metastatic, uncertain primary site | | | 1 (4%)
Integumentary System
Mammary gland | (1) | (0) | (0) | (1) | (1) | (0)
Skin | (25) | (24) | (25) | (25) | (24) | (24)
Osteosarcoma, metastatic, bone | | | | | | 1 (4%)
Musculoskeletal System
Bone | (3) | (0) | (1) | (1) | (0) | (1)
Osteosarcoma | 1 (33%)
Cranium, osteosarcoma | | | 1 (100%)
Humerus, osteosarcoma | 1 (33%)
Pelvis, osteosarcoma | | | | 1 (100%)
Rib, osteosarcoma | | | | | | 1 (100%)
Tibia, osteosarcoma | 1 (33%)
Bone, femur | (25) | (24) | (25) | (25) | (25) | (24)
Osteosarcoma | | | 1 (4%)
Skeletal muscle | (3) | (2) | (1) | (0) | (0) | (0)
Leiomyosarcoma, metastatic, intestine small, duodenum | 1 (33%)
Rhabdomyosarcoma | | 1 (50%)
Diaphragm, sarcoma, metastatic, tissue NOS | 1 (33%)
Diaphragm, sarcoma, metastatic, uncertain primary site | | | 1 (100%)
Nervous System
Brain, brain stem | (25) | (23) | (25) | (25) | (24) | (23)
Brain, cerebellum | (25) | (23) | (25) | (25) | (24) | (23)
Brain, cerebrum | (25) | (23) | (25) | (25) | (24) | (23)
Peripheral nerve | (1) | (0) | (0) | (0) | (0) | (0)
Spinal cord, cervical | (1) | (0) | (0) | (0) | (0) | (0)
Spinal cord, lumbar | (1) | (0) | (0) | (0) | (0) | (0)
Spinal cord, thoracic | (1) | (0) | (0) | (0) | (0) | (0)
Respiratory System
Lung | (25) | (24) | (25) | (25) | (24) | (23)
Alveolar/bronchiolar adenoma | | | 1 (4%) | 1 (4%)
Alveolar/bronchiolar carcinoma | | 1 (4%) | 1 (4%)
Osteosarcoma, metastatic, bone | 1 (4%)
Nose | (25) | (24) | (25) | (25) | (25) | (24)
Osteosarcoma | | 1 (4%)
Trachea | (25) | (23) | (25) | (25) | (24) | (23)
Special Senses System
Eye | (22) | (22) | (23) | (23) | (24) | (23)
Harderian gland | (25) | (22) | (25) | (25) | (24) | (23)
Adenoma | | | 1 (4%) | 1 (4%)
Carcinoma | | | 1 (4%)
Urinary System
Kidney | (25) | (23) | (25) | (25) | (24) | (23)
Capsule, alveolar/bronchiolar carcinoma, metastatic, lung | | | 1 (4%)
Urinary bladder | (25) | (23) | (25) | (25) | (24) | (23)
Sarcoma | | | | 1 (4%)
Systemic Lesions
Multiple organs^b^ | (25) | (24) | (25) | (26) | (25) | (24)
Histiocytic sarcoma | | | | 1 (4%) | 1 (4%)
Lymphoma malignant | 1 (4%) | 3 (13%) | | | 3 (12%) | 2 (8%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 7 | 12 | 9 | 9 | 17 | 14
Total primary neoplasms | 9 | 14 | 10 | 10 | 17 | 14
Total animals with benign neoplasms | 1 | 8 | 5 | 5 | 9 | 10
Total benign neoplasms | 1 | 8 | 5 | 5 | 9 | 10
Total animals with malignant neoplasms | 7 | 6 | 5 | 5 | 8 | 4
Total malignant neoplasms | 8 | 6 | 5 | 5 | 8 | 4
Total animals with metastatic neoplasms | 3 | | 2 | | | 1
Total metastatic neoplasms | 8 | | 14 | | | 1
Total animals with malignant neoplasms, uncertain primary site | | | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm. AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A5 Statistical Analysis of Primary Neoplasms in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
Bone: Osteosarcoma
Overall rate^b^ | 3/25 (12.0%) | 0/24 (0.0%) | 1/25 (4.0%) | 1/26 (3.8%) | 0/25 (0.0%) | 1/24 (4.2%)
Adjusted rate^c^ | 3/23.9 (12.6%) | 0/19.9 (0.0%) | 1/23.6 (4.2%) | 1/22.9 (4.4%) | 0/22.2 (0.0%) | 1/22.9 (4.4%)
Terminal rate^d^ | 1/20 (5.0%) | 0/18 (0.0%) | 1/23 (4.3%) | 1/22 (4.5%) | 0/21 (0.0%) | 1/22 (4.5%)
First incidence (days) | 207 | —^f^ | 318 (T) | 322 (T) | — | 326 (T)
| Vehicle Control | P=0.150N | P=0.307N | P=0.319N | P=0.127N | P=0.319N
| | AZT-H | P=0.534 | P=0.528 | —^g^ | P=0.528
Poly-3 test^e^ | | | 3TC-H | P=0.753 | P=0.512N | P=0.753
| | | | NVP-H | P=0.506N | P=0.761
| | | | | AZT/3TC-H | P=0.506
Liver: Hepalocellular Adenoma
Overall rate | 1/25 (4.0%) | 8/23 (34.8%) | 3/25 (12.0%) | 2/25 (8.0%) | 9/25 (36.0%) | 9/23 (39.1%)
Adjusted rate | 1/22.9 (4.4%) | 8/19.9 (40.2%) | 3/23.6 (12.7%) | 2/22.4 (8.9%) | 9/22.2 (40.5%) | 9/22.8 (39.4%)
Terminal rate | 0/20 (0.0%) | 8/18 (44.4%) | 3/23 (13.0%) | 2/22 (9.1%) | 9/21 (42.9%) | 9/22 (40.9%)
First incidence (days) | 313 | 316 (T) | 318 (T) | 322 (T) | 316 (T) | 316 (T)
| Vehicle Control | P=0.004 | P=0.313 | P=0.493 | P=0.003 | P=0.003
| | AZT-H | P=0.038N | P=0.017N | P=0.615 | P=0.601N
Poly-3 test | | | 3TC-H | P=0.524N | P=0.031 | P=0.036
| | | | NVP-H | P=0.014 | P=0.016
| | | | | AZT/3TC-H | P=0.589N
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 1/25 (4.0%) | 8/23 (34.8%) | 3/25 (12.0%) | 2/25 (8.0%) | 10/25 (40.0%) | 10/23 (43.5%)
Adjusted rate | 1/22.9 (4.4%) | 8/19.9 (40.2%) | 3/23.6 (12.7%) | 2/22.4 (8.9%) | 10/22.2 (45.0%) | 10/22.8 (43.8%)
Terminal rate | 0/20 (0.0%) | 8/18 (44.4%) | 3/23 (13.0%) | 2/22 (9.1%) | 10/21 (47.6%) | 10/22 (45.5%)
First incidence (days) | 313 | 316 (T) | 318 (T) | 322 (T) | 316 (T) | 316 (T)
| Vehicle Control | P=0.004 | P=0.313 | P=0.493 | P<0.001 | P=0.001
| | AZT-H | P=0.038N | P=0.017N | P=0.499 | P=0.529
Poly-3 test | | | 3TC-H | P=0.524N | P=0.014 | P=0.017
| | | | NVP-H | P=0.006 | P=0.007
| | | | | AZT/3TC-H | 0.585N
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 0/25 (0.0%) | 1/24 (4.2%) | 2/25 (8.0%) | 1/25 (4.0%) | 0/24 (0.0%) | 0/23 (0.0%)
Adjusted rate | 0/22.8 (0.0%) | 1/19.9 (5.0%) | 2/24.2 (8.3%) | 1/22.4 (4.5%) | 0/21.4 (0.0%) | 0/22.8 (0.0%)
Terminal rate | 0/20 (0.0%) | 1/18 (5.6%) | 1/23 (4.3%) | 1/22 (4.5%) | 0/21 (0.0%) | 0/22 (0.0%)
First incidence (days) | — | 319 (T) | 250 | 320 (T) | — | —
| Vehicle Control | P=0.473 | P=0.248 | P=0.497 | — | —
| | AZT-H | P=0.568 | P=0.734N | P=0.486N | P=0.473N
Poly-3 test | | | 3TC-H | P=0.526N | P=0.263N | P=0.248N
| | | | NVP-H | P=0.510N | P=0.497N
| | | | | AZT/3TC-H | —
All Organs: Malignant Lymphoma
Overall rate | 1/25 (4.0%) | 3/24 (12.5%) | 0/25 (0.0%) | 0/26 (0.0%) | 3/25 (12.0%) | 2/24 (8.3%)
Adjusted rate | 1/23.6 (4.2%) | 3/22.1 (13.6%) | 0/23.6 (0.0%) | 0/22.9 (0.0%) | 3/24.8 (12.1%) | 2/23.0 (8.7%)
Terminal rate | 0/20 (0.0%) | 0/18 (0.0%) | 0/23 (0.0%) | 0/22 (0.0%) | 0/21 (0.0%) | 1/22 (4.5%)
First incidence (days) | 176 | 168 | — | — | 99 | 307
| Vehicle Control | P=0.277 | P=0.500N | P=0.507N | P=0.321 | P=0.491
| | AZT-H | P=0.101N | P=0.106N | P=0.609N | P=0.480N
Poly-3 test | | | 3TC-H | — | P=0.123 | P=0.229
| | | | NVP-H | P=0.130 | P=0.236
| | | | | AZT/3TC-H | P=0.535N
All Organs: Osteosarcoma
Overall rate | 3/25 (12.0%) | 1/24 (4.2%) | 2/25 (8.0%) | 1/26 (3.8%) | 0/25 (0.0%) | 1/24 (4.2%)
Adjusted rate | 3/23.9 (12.6%) | 1/19.9 (5.0%) | 2/23.6 (8.5%) | 1/22.9 (4.4%) | 0/22.2 (0.0%) | 1/22.9 (4.4%)
Terminal rate | 1/20 (5.0%) | 1/18 (5.6%) | 2/23 (8.7%) | 1/22 (4.5%) | 0/21 (0.0%) | 1/22 (4.5%)
First incidence (days) | 207 | 318 (T) | 318 (T) | 322 (T) | — | 326 (T)
| Vehicle Control | P=0.371N | P=0.505N | P=0.319N | P=0.127N | P=0.319N
| | AZT-H | P=0.560 | P=0.730N | P=0.478N | P=0.729N
Poly-3 test | | | 3TC-H | P=0.512N | P=0.249N | P=0.512N
| | | | NVP-H | P=0.506N | P=0.761
| | | | | AZT/3TC-H | P=0.506
All Organs: Benign Neoplasms
Overall rate | 1/25 (4.0%) | 8/24 (33.3%) | 5/25 (20.0%) | 5/26 (19.2%) | 9/25 (36.0%) | 10/24 (41.7%)
Adjusted rate | 1/22.9 (4.4%) | 8/19.9 (40.2%) | 5/23.6 (21.2%) | 5/22.9 (21.9%) | 9/22.2 (40.5%) | 10/22.9 (43.8%)
Terminal rate | 0/20 (0.0%) | 8/18 (44.4%) | 5/23 (21.7%) | 5/22 (22.7%) | 9/21 (42.9%) | 10/22 (45.5%)
First incidence (days) | 313 | 316 (T) | 318 (T) | 320 (T) | 316 (T) | 316 (T)
| Vehicle Control | P=0.004 | P=0.099 | P=0.091 | P=0.003 | P=0.001
| | AZT-H | P=0.150N | P=0.166N | P=0.615 | P=0.530
Poly-3 test | | | 3TC-H | P=0.615 | P=0.135 | P=0.089
| | | | NVP-H | P=0.150 | P=0.102
| | | | | AZT/3TC-H | P=0.532
All Organs: Malignant Neoplasms
Overall rate | 7/25 (28.0%) | 6/24 (25.0%) | 5/25 (20.0%) | 5/26 (19.2%) | 8/25 (32.0%) | 4/24 (16.7%)
Adjusted rate | 7/25.0 (28.0%) | 6/22.4 (26.8%) | 5/24.2 (20.7%) | 5/25.0 (20.0%) | 8/25.0 (32.0%) | 4/23.0 (17.4%)
Terminal rate | 2/20 (10.0%) | 2/18 (11.1%) | 4/23 (17.4%) | 2/22 (9.1%) | 4/21 (19.0%) | 3/22 (13.6%)
First incidence (days) | 176 | 168 | 250 | 177 | 99 | 307
| Vehicle Control | P=0.590N | P=0.397N | P=0.372N | P=0.500 | P=0.300N
| | AZT-H | p=0.444N | P=0.419N | P=0.471 | P=0.344N
Poly-3 test | | | 3TC-H | P=0.614N | P=0.285 | P=0.532N
| | | | NVP-H | P=0.262 | P=0.554N
| | | | | AZT/3TC-H | P=0.203N
All Organs: Benign or Malignant Neoplasms
Overall rate | 7/25 (28.0%) | 12/24 (50.0%) | 9/25 (36.0%) | 9/26 (34.6%) | 17/25 (68.0%) | 14/24 (58.3%)
Adjusted rate | 7/25.0 (28.0%) | 12/22.4 (53.6%) | 9/24.2 (37.2%) | 9/25.0 (36.0%) | 17/25.0 (68.0%) | 14/23.0 (60.8%)
Terminal rate | 2/20 (10.0%) | 8/18 (44.4%) | 8/23 (34.8%) | 6/22 (27.3%) | 13/21 (61.9%) | 13/22 (59.1%)
First incidence (days) | 176 | 168 | 250 | 177 | 99 | 307
| Vehicle Control | P=0.065 | P=0.352 | P=0.383 | P=0.003 | P=0.019
| | AZT-H | P=0.206N | P=0.179N | P=0.238 | P=0.424
Poly-3 test | | | 3TC-H | P=0.580N | P=0.027 | P=0.090
| | | | NVP-H | P=0.020 | P=0.074
| | | | | AZT/3TC-H | P=0.415N

(T) Terminal kill

a AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b Number of neoplasm-bearing animals/number of animals with tissue examined microscopically

c Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

d Observed incidence at terminal kill

e Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between that dosed group and the group stated to the left on the same row. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence is indicated by N. Significant P values are bolded.

f Not applicable; no neoplasms in animal group

g Value of statistic cannot be computed.

TABLE A6 Summary of the Incidence of Nonneoplastic Lesions in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
Disposition Summary
Animals initially in study | 25 | 25 | 25 | 26 | 25 | 25
Early deaths
Moribund | 2 | 4 | | | 3
Natural deaths | 1 | 2 | 2 | 4 | | 1
Survivors
Died/moribund after day 320 | 2 | | | | 1 | 1
Terminal kill | 20 | 18 | 23 | 22 | 21 | 22
Removals | | 1 | | | | 1
Animals examined microscopically | 25 | 24 | 25 | 26 | 25 | 24
Alimentary System
Esophagus | (25) | (23) | (25) | (25) | (24) | (24)
Gallbladder | (22) | (21) | (25) | (22) | (24) | (23)
Intestine large, cecum | (22) | (22) | (24) | (22) | (24) | (23)
Intestine large, colon | (22) | (22) | (25) | (23) | (24) | (23)
Intestine large, rectum | (22) | (22) | (23) | (22) | (24) | (23)
Intestine small, duodenum | (23) | (22) | (23) | (22) | (24) | (23)
Ectopic pancreas | | | | | | 1 (4%)
Intestine small, ileum | (22) | (22) | (24) | (22) | (24) | (23)
Intestine small, jejunum | (23) | (22) | (23) | (22) | (24) | (23)
Liver | (25) | (23) | (25) | (25) | (25) | (23)
Basophilic focus | | | 1 (4%) | 1 (4%) | 1 (4%) | 2 (9%)
Hematopoietic cell proliferation | 1 (4%)
Infiltration cellular, lymphocyte | | | | 1 (4%)
Inflammation, chronic active | | | 1 (4%) | | 1 (4%) | 1 (4%)
Mixed cell focus | | | 1 (4%) | | 1 (4%)
Necrosis | 1 (4%) | | 1 (4%) | | | 2 (9%)
Tension lipidosis | | 1 (4%) | | 1 (4%) | 1 (4%) | 1 (4%)
Vacuolization cytoplasmic | 19 (76%) | 18 (78%) | 20 (80%) | 20 (80%) | 21 (84%) | 20 (87%)
Centrilobular, degeneration | 15 (60%) | 16 (70%) | 18 (72%) | 17 (68%) | 17 (68%) | 17 (74%)
Mesentery | (3) | (0) | (0) | (1) | (2) | (0)
Inflammation, chronic active | | | | | 1 (50%)
Fat, necrosis | 1 (33%) | | | | 1 (50%)
Pancreas | (24) | (23) | (25) | (25) | (24) | (23)
Cyst | 1 (4%) | 1 (4%)
Hemorrhage | | | | | 1 (4%)
Infiltration cellular, lymphocyte | | | | | 1 (4%)
Acinus, degeneration | | 1 (4%) | 1 (4%)
Salivary glands | (25) | (23) | (25) | (25) | (24) | (23)
Infiltration cellular, lymphocyte | 18 (72%) | 12 (52%) | 13 (52%) | 18 (72%) | 11 (46%) | 16 (70%)
Stomach, forestomach | (25) | (23) | (25) | (23) | (24) | (23)
Hyperkeratosis | | 1 (4%)
Ulcer | | | | | 1 (4%)
Epithelium, hyperplasia | 1 (4%) | | | | 1 (4%)
Stomach, glandular | (23) | (22) | (24) | (22) | (24) | (23)
Cardiovascular System
Blood vessel | (25) | (23) | (25) | (25) | (24) | (24)
Heart | (25) | (24) | (25) | (25) | (24) | (24)
Endocrine System
Adrenal cortex | (25) | (23) | (25) | (25) | (23) | (23)
Accessory adrenal cortical nodule | 1 (4%) | | | | | 1 (4%)
Cyst | | | | | 1 (4%)
Hypertrophy | | 1 (4%) | | | | 2 (9%)
Subcapsular, hyperplasia | 13 (52%) | 11 (48%) | 13 (52%) | 7 (28%) | 11 (48%) | 12 (52%)
Adrenal medulla | (25) | (23) | (25) | (23) | (21) | (22)
Islets, pancreatic | (24) | (23) | (25) | (25) | (24) | (23)
Hyperplasia | 13 (54%) | 9 (39%) | 15 (60%) | 10 (40%) | 14 (58%) | 6 (26%)
Parathyroid gland | (23) | (20) | (24) | (18) | (19) | (23)
Cyst | | | 1 (4%)
Pituitary gland | (24) | (21) | (25) | (25) | (24) | (23)
Thyroid gland | (25) | (23) | (25) | (23) | (23) | (23)
Ectopic thymus | 2 (8%) | | 1 (4%)
Follicle, degeneration | | | | | | 1 (4%)
General Body System
Tissue NOS | (1) | (0) | (1) | (3) | (0) | (0)
Abscess | | | | 1 (33%)
Abdominal, fat, necrosis | | | 1 (100%)
Genital System
Epididymis | (25) | (23) | (25) | (25) | (24) | (23)
Exfoliated germ cell | | 1 (4%) | | | | 1 (4%)
Hypospermia | | | | | | 1 (4%)
Preputial gland | (25) | (24) | (25) | (25) | (24) | (23)
Infiltration cellular, lymphocyte | | | 1 (4%)
Infiltration cellular, plasma cell | | 1 (4%)
Inflammation, suppurative | | 1 (4%)
Inflammation, chronic active | 1 (4%) | 1 (4%)
Acinus, degeneration | 3 (12%) | 2 (8%) | 3 (12%) | 3 (12%) | 1 (4%) | 5 (22%)
Duct, ectasia | 3 (12%) | 2 (8%) | 2 (8%) | 4 (16%) | 1 (4%) | 5 (22%)
Prostate | (25) | (23) | (25) | (25) | (24) | (23)
Infiltration cellular, lymphocyte | | | 1 (4%)
Inflammation, suppurative | | | 1 (4%)
Seminal vesicle | (25) | (23) | (24) | (25) | (24) | (23)
Testes | (25) | (24) | (24) | (25) | (24) | (23)
Seminiferous tubule, degeneration | | 1 (4%) | 1 (4%) | 2 (8%) | | 1 (4%)
Hematopoietic System
Bone marrow | (23) | (24) | (24) | (25) | (24) | (23)
Hyperplasia | 3 (13%) | 3 (13%) | 1 (4%) | 2 (8%) | 2 (8%)
Lymph node | (2) | (2) | (1) | (1) | (2) | (1)
Mediastinal, hyperplasia, lymphoid | 1 (50%) | | | 1 (100%)
Lymph node, mandibular | (25) | (23) | (25) | (25) | (24) | (23)
Hyperplasia, lymphoid | 2 (8%) | 1 (4%) | 2 (8%) | 2 (8%) | 2 (8%) | 5 (22%)
Lymph node, mesentenc | (24) | (23) | (25) | (25) | (24) | (23)
Congestion | | 1 (4%)
Hyperplasia, lymphoid | 9 (38%) | 5 (22%) | 12 (48%) | 11 (44%) | 11 (46%) | 9 (39%)
Infiltration cellular, plasma cell | | | 1 (4%) | 2 (8%) | 1 (4%)
Spleen | (25) | (23) | (24) | (25) | (24) | (23)
Congestion | | | | | 1 (4%)
Hematopoietic cell proliferation | 7 (28%) | 11 (48%) | 4 (17%) | 5 (20%) | 11 (46%) | 6 (26%)
Hyperplasia, lymphoid | 12 (48%) | 14 (61%) | 16 (67%) | 18 (72%) | 14 (58%) | 12 (52%)
Thymus | (24) | (22) | (24) | (23) | (22) | (20)
Atrophy | 2 (8%) | 1 (5%) | | 1 (4%) | 1 (5%) | 1 (5%)
Cyst | | 1 (5%)
Hyperplasia, lymphoid | 2 (8%) | | | 1 (4%) | 3 (14%) | 1 (5%)
Integumentary System
Mammary gland | (1) | (0) | (0) | (1) | (1) | (0)
Skin | (25) | (24) | (25) | (25) | (24) | (24)
Cyst | | 1 (4%)
Granuloma | | 1 (4%)
Inflammation, suppurative | | | | | | 1 (4%)
Epithelium, hyperplasia | | | | | | 1 (4%)
Musculoskeletal System
Bone | (3) | (0) | (1) | (1) | (0) | (1)
Bone, femur | (25) | (24) | (25) | (25) | (25) | (24)
Fibro-osseous lesion | 1 (4%)
Skeletal muscle | (3) | (2) | (1) | (0) | (0) | (0)
Nervous System
Brain, brain stem | (25) | (23) | (25) | (25) | (24) | (23)
Brain, cerebellum | (25) | (23) | (25) | (25) | (24) | (23)
Compression | | | 1 (4%)
Hemorrhage | | 1 (4%)
Brain, cerebrum | (25) | (23) | (25) | (25) | (24) | (23)
Mineralization | 2 (8%) | 3 (13%) | 4 (16%) | 4 (16%) | 2 (8%) | 1 (4%)
Peripheral nerve | (1) | (0) | (0) | (0) | (0) | (0)
Spinal cord, cervical | (1) | (0) | (0) | (0) | (0) | (0)
Spinal cord, lumbar | (1) | (0) | (0) | (0) | (0) | (0)
Spinal cord, thoracic | (1) | (0) | (0) | (0) | (0) | (0)
Compression | 1 (100%)
Respiratory System
Lung | (25) | (24) | (25) | (25) | (24) | (23)
Hemorrhage | | 1 (4%) | | | 1 (4%)
Infiltration cellular, histiocyte | | 1 (4%) | 1 (4%)
Inflammation, chronic | | | | 1 (4%)
Mineralization | | 1 (4%) | | 1 (4%)
Alveolar epithelium, hyperplasia | | | | 1 (4%) | | 1 (4%)
Nose | (25) | (24) | (25) | (25) | (25) | (24)
Hyaline droplet | | | 1 (4%) | | 2 (8%)
Trachea | (25) | (23) | (25) | (25) | (24) | (23)
Special Senses System
Eye | (22) | (22) | (23) | (23) | (24) | (23)
Inflammation, chronic active | | 1 (5%)
Cornea, ulcer | | 1 (5%)
Harderian gland | (25) | (22) | (25) | (25) | (24) | (23)
Infiltration cellular, lymphocyte | 1 (4%)
Urinary System
Kidney | (25) | (23) | (25) | (25) | (24) | (23)
Casts protein | 3 (12%) | 4 (17%) | 6 (24%) | 7 (28%) | 8 (33%) | 10 (43%)
Hemorrhage | | | | 1 (4%)
Hydronephrosis | 1 (4%) | 8 (35%) | 7 (28%) | 5 (20%) | 9 (38%) | 12 (52%)
Infiltration cellular, lymphocyte | 8 (32%) | 2 (9%) | 10 (40%) | 6 (24%) | 2 (8%) | 7 (30%)
Metaplasia, osseous | | | 1 (4%) | | 1 (4%)
Nephropathy | 1 (4%) | 1 (4%) | 2 (8%) | | | 1 (4%)
Renal tubule, regeneration | | | 1 (4%)
Transitional epithelium, hyperplasia | | | 1 (4%)
Urinary bladder | (25) | (23) | (25) | (25) | (24) | (23)
Hemorrhage | | | | | 1 (4%)
Infiltration cellular, histiocyte | | | | 1 (4%)
Infiltration cellular, lymphocyte | 2 (8%) | | | 2 (8%) | 1 (4%) | 1 (4%)
Lumen, dilatation | 1 (4%) | | 1 (4%) | 1 (4%)

a Number of animals examined microscopically at the site and the number of animals with lesion. AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

TABLE A7 Summary of the Incidence of Neoplasms in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Disposition Summary
Animals initially in study | 25 | 25 | 25 | 25
Early deaths
Moribund | | 2 | 2 | 2
Natural deaths | | 1 | 1 | 1
Survivors
Died/moribund after day 320 | | | | 1
Terminal kill | 25 | 22 | 19 | 21
Removals | | | 3
Animals examined microscopically | 25 | 25 | 22 | 25
Alimentary System
Esophagus | (25) | (25) | (22) | (25)
Gallbladder | (25) | (23) | (21) | (24)
Intestine large, cecum | (25) | (24) | (21) | (23)
Intestine large, colon | (25) | (25) | (21) | (24)
Intestine large, rectum | (25) | (24) | (21) | (23)
Intestine small, duodenum | (25) | (24) | (21) | (24)
Sarcoma | | | | 1 (4%)
Intestine small, ileum | (25) | (24) | (21) | (23)
Intestine small, jejunum | (25) | (24) | (21) | (23)
Liver | (25) | (25) | (22) | (25)
Mesentery | (0) | (0) | (0) | (2)
Pancreas | (25) | (25) | (21) | (24)
Salivary glands | (25) | (25) | (22) | (25)
Stomach, forestomach | (25) | (25) | (21) | (24)
Stomach, glandular | (25) | (25) | (21) | (23)
Cardiovascular System
Blood vessel | (25) | (25) | (22) | (25)
Heart | (25) | (25) | (22) | (25)
Endocrine System
Adrenal cortex | (25) | (25) | (22) | (25)
Adrenal medulla | (23) | (25) | (21) | (24)
Islets, pancreatic | (25) | (25) | (22) | (25)
Parathyroid gland | (20) | (21) | (21) | (23)
Pituitary gland | (25) | (24) | (22) | (23)
Pars intermedia, adenoma | | | | 1 (4%)
Thyroid gland | (23) | (25) | (22) | (25)
General Body System
None
Genital System
Clitoral gland | (24) | (24) | (22) | (22)
Ovary | (25) | (25) | (22) | (25)
Uterus | (25) | (25) | (22) | (25)
Polyp stromal | | | 1 (5%) | 1 (4%)
Vagina | (25) | (25) | (22) | (23)
Hematopoietic System
Bone marrow | (25) | (25) | (22) | (24)
Lymph node | (1) | (3) | (1) | (4)
Lymph node, mandibular | (25) | (25) | (22) | (25)
Lymph node, mesenteric | (25) | (25) | (21) | (24)
Spleen | (25) | (25) | (22) | (25)
Thymus | (25) | (25) | (21) | (24)
Integumentary System
Mammary gland | (25) | (25) | (22) | (25)
Adenoacanthoma | | | | 1 (4%)
Adenocarcinoma | 1 (4%)
Skin | (25) | (25) | (22) | (25)
Musculoskeletal System
Bone | (0) | (2) | (1) | (0)
Cranium, osteosarcoma | | | 1 (100%)
Vertebra, osteosarcoma | | 1 (50%)
Bone, femur | (25) | (25) | (22) | (25)
Nervous System
Brain, brain stem | (25) | (25) | (21) | (25)
Brain, cerebellum | (25) | (25) | (21) | (25)
Brain, cerebrum | (25) | (25) | (21) | (25)
Respiratory System
Lung | (25) | (25) | (22) | (25)
Adenocarcinoma, metastatic, mammary gland | 1 (4%)
Alveolar/bronchiolar adenoma | 1 (4%) | | 1 (5%) | 1 (4%)
Nose | (25) | (25) | (22) | (25)
Trachea | (25) | (25) | (21) | (25)
Special Senses System
Eye | (25) | (24) | (21) | (23)
Harderian gland | (25) | (25) | (22) | (24)
Adenoma | | | | 1 (4%)
Urinary System
Kidney | (25) | (25) | (22) | (25)
Urinary bladder | (25) | (25) | (22) | (25)
Systemic Lesions
Multiple organs^b^ | (25) | (25) | (22) | (25)
Histiocytic sarcoma | | | 1 (5%) | 1 (4%)
Lymphoma malignant | 2 (8%) | 2 (8%) | 4 (18%) | 4 (16%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 4 | 3 | 7 | 9
Total primary neoplasms | 4 | 3 | 8 | 11
Total animals with benign neoplasms | 1 | | 2 | 4
Total benign neoplasms | 1 | | 2 | 4
Total animals with malignant neoplasms | 3 | 3 | 6 | 6
Total malignant neoplasms | 3 | 3 | 6 | 7
Total animals with metastatic neoplasms | 1
Total metastatic neoplasms | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm. AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A8 Statistical Analysis of Primary Neoplasms in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison^a^

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
All Organs: Malignant Lymphoma
Overall rate^b^ | 2/25 (8.0%) | 2/25 (8.0%) | 4/22 (18.2%) | 4/25 (16.0%)
Adjusted rate^c^ | 2/25.0 (8.0%) | 2/24.4 (8.2%) | 4/22.0 (18.2%) | 4/24.5 (16.3%)
Terminal rate^d^ | 2/25 (8.0%) | 0/22 (0.0%) | 1/19 (5.3%) | 2/21 (9.5%)
First incidence (days) | 316 (T) | 186 | 101 | 247
Poly-3 test^e^ | P=0.156 | P=0.687 | P=0.274 | P=0.324
All Organs: Benign Neoplasms
Overall rate | 1/25 (4.0%) | 0/25 (0.0%) | 2/22 (9.1%) | 4/25 (16.0%)
Adjusted rate | 1/25.0 (4.0%) | 0/23.4 (0.0%) | 2/19.7 (10.2%) | 4/24.1 (16.6%)
Terminal rate | 1/25 (4.0%) | 0/22 (0.0%) | 2/19 (10.5%) | 3/21 (14.3%)
First incidence (days) | 316 (T) | —^f^ | 318 (T) | 275
Poly-3 test | P=0.036 | P=0.513N | P=0.417 | P=0.162
All Organs: Malignant Neoplasms
Overall rate | 3/25 (12.0%) | 3/25 (12.0%) | 6/22 (27.3%) | 6/25 (24.0%)
Adjusted rate | 3/25.0 (12.0%) | 3/25.0 (12.0%) | 6/22.0 (27.3%) | 6/25.0 (24.0%)
Terminal rate | 3/25 (12.0%) | 0/22 (0.0%) | 3/19 (15.8%) | 2/21 (9.5%)
First incidence (days) | 316 (T) | 186 | 101 | 247
Poly-3 test | P=0.092 | P=0.665 | P=0.170 | P=0.233
All Organs: Benign or Malignant Neoplasms
Overall rate | 4/25 (16.0%) | 3/25 (12.0%) | 7/22 (31.8%) | 9/25 (36.0%)
Adjusted rate | 4/25.0 (16.0%) | 3/25.0 (12.0%) | 7/22.0 (31.8%) | 9/25.0 (36.0%)
Terminal rate | 4/25 (16.0%) | 0/22 (0.0%) | 4/19 (21.1%) | 5/21 (23.8%)
First incidence (days) | 316 (T) | 186 | 101 | 247
Poly-3 test | P=0.023 | P=0.500N | P=0.176 | P=0.097

(T) Terminal kill

a AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg

b Number of neoplasm-bearing animals/number of animals with tissue examined microscopically

c Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

d Observed incidence at terminal kill

e Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in a dose group is indicated by N.

f Not applicable; no neoplasms in animal group.

TABLE A9 Summary of the Incidence of Nonneoplastic Lesions in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: Combination Dose Comparison

| Vehicle Control | AZT/3TC/NVP-L | AZT/3TC/NVP-M | AZT/3TC/NVP-H
Disposition Summary
Animals initially in study | 25 | 25 | 25 | 25
Early deaths
Moribund | | 2 | 2 | 2
Natural deaths | | 1 | 1 | 1
Survivors
Died/moribund after day 320 | | | | 1
Terminal kill | 25 | 22 | 19 | 21
Removals | | | 3
Animals examined microscopically | 25 | 25 | 22 | 25
Alimentary System
Esophagus | (25) | (25) | (22) | (25)
Gallbladder | (25) | (23) | (21) | (24)
Intestine large, cecum | (25) | (24) | (21) | (23)
Intestine large, colon | (25) | (25) | (21) | (24)
Intestine large, rectum | (25) | (24) | (21) | (23)
Intestine small, duodenum | (25) | (24) | (21) | (24)
Intestine small, ileum | (25) | (24) | (21) | (23)
Intestine small, jejunum | (25) | (24) | (21) | (23)
Liver | (25) | (25) | (22) | (25)
Basophilic focus | | | 1 (5%)
Clear cell focus | | | 1 (5%)
Infiltration cellular, lymphocyte | 1 (4%) | 2 (8%) | 4 (18%) | 4 (16%)
Inflammation, chronic active | 1 (4%) | 1 (4%) | | 3 (12%)
Necrosis | | 1 (4%)
Tension lipidosis | 2 (8%) | | 4 (18%) | 3 (12%)
Vacuolization cytoplasmic | 14 (56%) | 17 (68%) | 13 (59%) | 15 (60%)
Centrilobular, degeneration | | | | 3 (12%)
Mesentery | (0) | (0) | (0) | (2)
Fat, necrosis | | | | 2 (100%)
Pancreas | (25) | (25) | (21) | (24)
Infiltration cellular, lymphocyte | 2 (8%) | 3 (12%) | 5 (24%) | 2 (8%)
Necrosis | 1 (4%)
Salivary glands | (25) | (25) | (22) | (25)
Infiltration cellular, lymphocyte | 22 (88%) | 18 (72%) | 12 (55%) | 20 (80%)
Stomach, forestomach | (25) | (25) | (21) | (24)
Ulcer | 1 (4%)
Epithelium, hyperplasia | 2 (8%) | | | 1 (4%)
Stomach, glandular | (25) | (25) | (21) | (23)
Cardiovascular system
Blood vessel | (25) | (25) | (22) | (25)
Heart | (25) | (25) | (22) | (25)
Endocrine System
Adrenal cortex | (25) | (25) | (22) | (25)
Accessory adrenal cortical nodule | 1 (4%)
Hypertrophy | 1 (4%)
Infiltration cellular, polymorphonuclear | | | | 1 (4%)
Vacuolization cytoplasmic | 16 (64%) | 15 (60%) | 16 (73%) | 18 (72%)
Subcapsular, hyperplasia | 25 (100%) | 24 (96%) | 20 (91%) | 24 (96%)
Adrenal medulla | (23) | (25) | (21) | (24)
Islets, pancreatic | (25) | (25) | (22) | (25)
Hyperplasia | | 1 (4%) | | 1 (4%)
Parathyroid gland | (20) | (21) | (21) | (23)
Cyst | | 1 (5%)
Pituitary gland | (25) | (24) | (22) | (23)
Pars distalis, hyperplasia | | | | 1 (4%)
Thyroid gland | (23) | (25) | (22) | (25)
Cyst | | | 1 (5%)
Ectopic thymus | 3 (13%) | 1 (4%) | 2 (9%) | 2 (8%)
General Body System
None
Genital System
Clitoral gland | (24) | (24) | (22) | (22)
Acinus, degeneration | 9 (38%) | 6 (25%) | 5 (23%) | 11 (50%)
Duct, ectasia | | | | 1 (5%)
Ovary | (25) | (25) | (22) | (25)
Atrophy | 1 (4%) | | 1 (5%)
Cyst | 1 (4%) | 3 (12%) | 1 (5%)
Hemorrhage | | | | 1 (4%)
Uterus | (25) | (25) | (22) | (25)
Endometrium, hyperplasia, cystic | 22 (88%) | 18 (72%) | 16 (73%) | 17 (68%)
Vagina | (25) | (25) | (22) | (23)
Infiltration cellular, polymorphonuclear | | 1 (4%) | | 2 (9%)
Hematopoietic System
Bone marrow | (25) | (25) | (22) | (24)
Hyperplasia | 1 (4%) | | | 3 (13%)
Lymph node | (1) | (3) | (1) | (4)
Lumbar, hyperplasia, lymphoid | | 1 (33%)
Pancreatic, hyperplasia, lymphoid | | 1 (33%)
Renal, hyperplasia, lymphoid | | 1 (33%)
Lymph node, mandibular | (25) | (25) | (22) | (25)
Hyperplasia, lymphoid | 3 (12%) | 4 (16%) | 2 (9%) | 1 (4%)
Lymph node, mesenteric | (25) | (25) | (21) | (24)
Hyperplasia, lymphoid | 1 (4%) | 3 (12%) | 2 (10%) | 3 (13%)
Spleen | (25) | (25) | (22) | (25)
Hematopoietic cell proliferation | 2 (8%) | 2 (8%) | 8 (36%) | 7 (28%)
Hyperplasia, lymphoid | 20 (80%) | 19 (76%) | 16 (73%) | 16 (64%)
Thymus | (25) | (25) | (21) | (24)
Atrophy | 1 (4%)
Hyperplasia, lymphoid | 6 (24%) | 9 (36%) | 2 (10%) | 5 (21%)
Integumentary System
Mammary gland | (25) | (25) | (22) | (25)
Skin | (25) | (25) | (22) | (25)
Musculoskeletal System
Bone | (0) | (2) | (1) | (0)
Bone, femur | (25) | (25) | (22) | (25)
Fibro-osseous lesion | 1 (4%)
Nervous System
Brain, brain stem | (25) | (25) | (21) | (25)
Brain, cerebellum | (25) | (25) | (21) | (25)
Brain, cerebrum | (25) | (25) | (21) | (25)
Mineralization | 2 (8%) | 1 (4%) | 2 (10%)
Respiratory System
Lung | (25) | (25) | (22) | (25)
Hemorrhage | | 1 (4%)
Infiltration cellular, lymphocyte | | 1 (4%) | | 3 (12%)
Metaplasia, osseous | | 1 (4%)
Nose | (25) | (25) | (22) | (25)
Hyaline droplet | 1 (4%) | 4 (16%) | 1 (5%) | 6 (24%)
Trachea | (25) | (25) | (21) | (25)
Special Senses System
Eye | (25) | (24) | (21) | (23)
Cataract | | | | 1 (4%)
Harderian gland | (25) | (25) | (22) | (24)
Infiltration cellular, lymphocyte | 2 (8%) | 1 (4%)
Urinary System
Kidney | (25) | (25) | (22) | (25)
Casts protein | 14 (56%) | 15 (60%) | 9 (41%) | 15 (60%)
Hydronephrosis | | | | 3 (12%)
Infarct | 1 (4%)
Infiltration cellular, lymphocyte | 11 (44%) | 13 (52%) | 7 (32%) | 11 (44%)
Metaplasia, osseous | | | | 1 (4%)
Urinary bladder | (25) | (25) | (22) | (25)
Infiltration cellular, lymphocyte | 8 (32%) | 5 (20%) | 5 (23%) | 3 (12%)

a Number of animals examined microscopically at the site and the number of animals with lesion. AZT/3TC/NVP-L = 80/50/56 mg/kg AZT/3TC/NVP; M = 160/100/112 mg/kg; H = 240/150/168 mg/kg.

TABLE A10 Summary of the Incidence of Neoplasms in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
Disposition Summary
Animals initially in study | 25 | 25 | 25 | 25 | 25 | 25
Early deaths
Moribund | | 2 | 3 | 2 | 4 | 2
Natural deaths | | 2 | 2 | 2 | 1 | 1
Survivors
Died/moribund after day 320 | | 1 | | 1 | | 1
Terminal kill | 25 | 20 | 20 | 20 | 19 | 21
Missexed | | | | | 1
Animals examined microscopically | 25 | 25 | 25 | 25 | 24 | 25
Alimentary System
Esophagus | (25) | (25) | (25) | (25) | (22) | (25)
Gallbladder | (25) | (23) | (23) | (22) | (23) | (24)
Intestine large, cecum | (25) | (23) | (23) | (22) | (23) | (23)
Intestine large, colon | (25) | (23) | (23) | (22) | (23) | (24)
Intestine large, rectum | (25) | (23) | (23) | (22) | (23) | (23)
Intestine small, duodenum | (25) | (23) | (23) | (22) | (23) | (24)
Sarcoma | | | | | | 1 (4%)
Intestine small, ileum | (25) | (23) | (23) | (22) | (23) | (23)
Intestine small, jejunum | (25) | (23) | (23) | (22) | (23) | (23)
Liver | (25) | (25) | (23) | (24) | (23) | (25)
Carcinoma NOS, metastatic, pancreas | | 1 (4%)
Hepatocellular carcinoma | | | | | 1 (4%)
Mesentery | (0) | (1) | (0) | (0) | (0) | (2)
Carcinoma NOS, metastatic, pancreas | | 1 (100%)
Pancreas | (25) | (25) | (25) | (22) | (23) | (24)
Carcinoma NOS | | 1 (4%)
Salivary glands | (25) | (25) | (25) | (24) | (23) | (25)
Stomach, forestomach | (25) | (24) | (24) | (24) | (23) | (24)
Stomach, glandular | (25) | (23) | (23) | (22) | (23) | (23)
Cardiovascular System
Blood vessel | (25) | (25) | (25) | (25) | (23) | (25)
Heart | (25) | (25) | (25) | (25) | (24) | (25)
Endocrine System
Adrenal cortex | (25) | (24) | (24) | (25) | (23) | (25)
Adrenal medulla | (23) | (24) | (24) | (25) | (23) | (24)
Islets, pancreatic | (25) | (24) | (25) | (25) | (23) | (25)
Parathyroid gland | (20) | (23) | (21) | (20) | (18) | (23)
Pituitary gland | (25) | (25) | (24) | (25) | (23) | (23)
Pars intermedia, adenoma | | | | | | 1 (4%)
Thyroid gland | (23) | (24) | (25) | (23) | (22) | (25)
C-cell, adenoma | | | | 1 (4%)
General Body System
Tissue NOS | (0) | (0) | (0) | (1) | (0) | (0)
Genital System
Clitoral gland | (24) | (24) | (23) | (21) | (21) | (22)
Ovary | (25) | (24) | (25) | (24) | (23) | (25)
Uterus | (25) | (25) | (25) | (23) | (23) | (25)
Polyp stromal | | | | | | 1 (4%)
Vagina | (25) | (24) | (24) | (24) | (23) | (23)
Hematopoietic System
Bone marrow | (25) | (24) | (24) | (23) | (23) | (24)
Lymph node | (1) | (3) | (1) | (3) | (4) | (4)
Mediastinal, carcinoma NOS, metastatic, pancreas | | 1 (33%)
Renal, carcinoma NOS, metastatic, pancreas | | 1 (33%)
Lymph node, mandibular | (25) | (25) | (24) | (24) | (23) | (25)
Lymph node, mesenteric | (25) | (24) | (23) | (24) | (23) | (24)
Carcinoma NOS, metastatic, pancreas | | 1 (4%)
Spleen | (25) | (25) | (24) | (24) | (23) | (25)
Thymus | (25) | (21) | (22) | (22) | (24) | (24)
Integumentary System
Mammary gland | (25) | (25) | (25) | (23) | (23) | (25)
Adenoacanthoma | | 1 (4%) | 1 (4%) | | | 1 (4%)
Adenocarcinoma | 1 (4%) | | 3 (12%) | | 2 (9%)
Skin | (25) | (25) | (25) | (25) | (23) | (25)
Hemangiosarcoma | | | | 1 (4%)
Musculoskeletal System
Bone | (0) | (0) | (2) | (0) | (0) | (0)
Mandible, osteosarcoma | | | 1 (50%)
Pelvis, osteosarcoma | | | 1 (50%)
Bone, femur | (25) | (25) | (25) | (25) | (24) | (25)
Skeletal muscle | (0) | (1) | (2) | (0) | (0) | (0)
Rhabdomyosarcoma | | | 1 (50%)
Sarcoma | | 1 (100%)
Nervous System
Brain, brain stem | (25) | (24) | (25) | (24) | (23) | (25)
Brain, cerebellum | (25) | (24) | (25) | (24) | (23) | (25)
Brain, cerebrum | (25) | (24) | (25) | (24) | (23) | (25)
Peripheral nerve | (0) | (0) | (1) | (0) | (0) | (0)
Spinal cord, cervical | (0) | (0) | (1) | (0) | (0) | (0)
Spinal cord, lumbar | (0) | (0) | (1) | (0) | (0) | (0)
Spinal cord, thoracic | (0) | (0) | (1) | (0) | (0) | (0)
Respiratory System
Lung | (25) | (24) | (24) | (24) | (24) | (25)
Adenocarcinoma, metastatic, mammary gland | 1 (4%) | | | | 1 (4%)
Alveolar/bronchiolar adenoma | 1 (4%) | | | | | 1 (4%)
Osteosarcoma, metastatic, bone | | | 1 (4%)
Nose | (25) | (25) | (25) | (24) | (24) | (25)
Neuroblastoma | | | | 1 (4%)
Trachea | (25) | (24) | (24) | (24) | (23) | (25)
Special Senses System
Eye | (25) | (23) | (23) | (22) | (23) | (23)
Harderian gland | (25) | (24) | (25) | (25) | (23) | (24)
Adenoma | | 1 (4%) | | 2 (8%) | | 1 (4%)
Urinary System
Kidney | (25) | (24) | (24) | (24) | (23) | (25)
Urinary bladder | (25) | (24) | (24) | (23) | (23) | (25)
Systemic Lesions
Multiple organs^b^ | (25) | (25) | (25) | (25) | (24) | (25)
Histiocytic sarcoma | | | | 1 (4%) | 1 (4%) | 1 (4%)
Leukemia granulocytic | | | | 1 (4%)
Lymphoma malignant | 2 (8%) | 2 (8%) | 1 (4%) | 5 (20%) | 4 (17%) | 4 (16%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 4 | 6 | 8 | 12 | 8 | 9
Total primary neoplasms | 4 | 6 | 8 | 12 | 8 | II
Total animals with benign neoplasms | 1 | 1 | | 3 | | 4
Total benign neoplasms | 1 | 1 | | 3 | | 4
Total animals with malignant neoplasms | 3 | 4 | 8 | 9 | 8 | 6
Total malignant neoplasms | 3 | 4 | 8 | 9 | 8 | 7
Total animals with metastatic neoplasms | 1 | 1 | 1 | | 1
Total metastatic neoplasms | 1 | 5 | 1 | | 1
Total animals with uncertain neoplasms-benign or malignant | | 1
Total uncertain neoplasms | | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm. AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A11 Statistical Analysis of Primary Neoplasms in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
Bone: Osteosarcoma
Overall rate^b^ | 0/25 (0.0%) | 0/25 (0.0%) | 2/25 (8.0%) | 0/25 (0.0%) | 0/24 (0.0%) | 0/25 (0.0%)
Adjusted rate^c^ | 0/25.0 (0.0%) | 0/23.8 (0.0%) | 2/23.5 (8.5%) | 0/23.2 (0.0%) | 0/20.7 (0.0%) | 0/23.7 (0.0%)
Terminal rate^d^ | 0/25 (0.0%) | 0/20 (0.0%) | 1/20 (5.0%) | 0/20 (0.0%) | 0/19 (0.0%) | 0/21 (0.0%)
First incidence (days) | —^f^ | — | 297 | — | — | —
| Vehicle Control | —^g^ | P=0.221 | — | — | —
| | AZT-H | P=0.232 | — | — | —
Poly-3 test^e^ | | | 3TC-H | P=0.237N | P=0.263N | P=0.232N
| | | | NVP-H | — | —
| | | | | AZT/3TC-H | —
Harderian Gland: Adenoma
Overall rate | 0/25 (0.0%) | 1/24 (4.2%) | 0/25 (0.0%) | 2/25 (8.0%) | 0/23 (0.0%) | 1/24 (4.2%)
Adjusted rate | 0/25.0 (0.0%) | 1/23.1 (4.3%) | 0/23.2 (0.0%) | 2/23.2 (8.6%) | 0/20.7 (0.0%) | 1/23.3 (4.3%)
Terminal rate | 0/25 (0.0%) | 1/20 (5.0%) | 0/20 (0.0%) | 2/20 (10.0%) | 0/19 (0.0%) | 1/21 (4.8%)
First incidence (days) | — | 320 (T) | — | 320 (T) | — | 318 (T)
| Vehicle Control | P=0.484 | — | P=0.218 | — | P=0.486
| | AZT-H | P=0.499N | P=0.501 | P=0.522N | P=0.759N
Poly-3 test | | | 3TC-H | P=0.234 | — | P=0.501
| | | | NVP-H | P=0.260N | P=0.498N
| | | | | AZT/3TC-H | P=0.523
Mammary Gland: Adenocarcinoma
Overall rate | 1/25 (4.0%) | 0/25 (0.0%) | 3/25 (12.0%) | 0/23 (0.0%) | 2/23 (8.7%) | 0/25 (0.0%)
Adjusted rate | 1/25.0 (4.0%) | 0/23.8 (0.0%) | 3/23.6 (12.7%) | 0/21.8 (0.0%) | 2/21.1 (9.5%) | 0/23.7 (0.0%)
Terminal rate | 1/25 (4.0%) | 0/20 (0.0%) | 2/20 (10.0%) | 0/20 (0.0%) | 1/19 (5.3%) | 0/21 (0.0%)
First incidence (days) | 319 (T) | — | 277 | — | 280 | —
| Vehicle Control | P=0.510N | P=0.282 | P=0.527N | P=0.440 | P=0.510N
| | AZT-H | P=0.112 | — | P=0.208 | —
Poly-3 test | | | 3TC-H | P=0.128N | P=0.553N | P=0.112N
| | | | NVP-H | P=0.226 | —
| | | | | AZT/3TC-H | P=0.208N
Mammary Gland: Adenoacanthoma or Adenocarcinoma
Overall rate | 1/25 (4.0%) | 1/25 (4.0%) | 4/25 (16.0%) | 0/23 (0.0%) | 2/23 (8.7%) | 1/25 (4.0%)
Adjusted rate | 1/25.0 (4.0%) | 1/23.9 (4.2%) | 4/24.0 (16.6%) | 0/21.8 (0.0%) | 2/21.1 (9.5%) | 1/23.9 (4.2%)
Terminal rate | 1/25 (4.0%) | 0/20 (0.0%) | 2/20 (10.0%) | 0/20 (0.0%) | 1/19 (5.3%) | 0/21 (0.0%)
First incidence (days) | 319 (T) | 313 | 271 | — | 280 | 302
| Vehicle Control | P=0.750 | P=0.161 | P=0.527N | P=0.440 | P=0.751
| | AZT-H | P=0.174 | P=0.518N | P=0.456 | P=0.760N
Poly-3 test | | | 3TC-H | P=0.066N | P=0.397N | P=0.173N
| | | | NVP-H | P=0.226 | P=0.519
| | | | | AZT/3TC-H | P=0.455N
All Organs: Malignant Lymphoma
Overall rate | 2/25 (8.0%) | 2/25 (8.0%) | 1/25 (4.0%) | 5/25 (20.0%) | 4/24 (16.7%) | 4/25 (16.0%)
Adjusted rate | 2/25.0 (8.0%) | 2/24.4 (8.2%) | 1/23.7 (4.2%) | 5/23.7 (21.1%) | 4/23.6 (16.9%) | 4/24.5 (16.3%)
Terminal rate | 2/25 (8.0%) | 0/20 (0.0%) | 0/20 (0.0%) | 4/20 (20.0%) | 0/19 (0.0%) | 2/21 (9.5%)
First incidence (days) | 316 (T) | 277 | 258 | 251 | 102 | 247
| Vehicle Control | P=0.686 | P=0.518N | P=0.186 | P=0.307 | P=0.324
| | AZT-H | P=0.509N | P=0.196 | P=0.319 | P=0.336
Poly-3 test | | | 3TC-H | P=0.092 | P=0.171 | P=0.182
| | | | NVP-H | P=0.502N | P=0.479N
| | | | | AZT/3TC-H | P=0.628N
All Organs: Benign Neoplasms
Overall rate | 1/25 (4.0%) | 1/25 (4.0%) | 0/25 (0.0%) | 3/25 (12.0%) | 0/24 (0.0%) | 4/25 (16.0%)
Adjusted rate | 1/25.0 (4.0%) | 1/23.8 (4.2%) | 0/23.2 (0.0%) | 3/23.2 (13.0%) | 0/20.7 (0.0%) | 4/24.1 (16.6%)
Terminal rate | 1/25 (4.0%) | 1/20 (5.0%) | 0/20 (0.0%) | 3/20 (15.0%) | 0/19 (0.0%) | 3/21 (14.3%)
First incidence (days) | 316 (T) | 320 (T) | — | 320 (T) | — | 275
| Vehicle Control | P=0.749 | P=0.515N | P=0.275 | P=0.537N | P=0.162
| | AZT-H | P=0.504N | P=0.293 | P=0.527N | P=0.177
Poly-3 test | | | 3TC-H | P=0.112 | — | P=0.059
| | | | NVP-H | P=0.134N | P=0.523
| | | | | AZT/3TC-H | P=0.075
All Organs: Malignant Neoplasms
Overall rate | 3/25 (12.0%) | 4/25 (16.0%) | 8/25 (32.0%) | 9/25 (36.0%) | 8/24 (33.3%) | 6/25 (24.0%)
Adjusted rate | 3/25.0 (12.0%) | 4/24.7 (16.2%) | 8/25.0 (32.0%) | 9/24.9 (36.2%) | 8/24.0 (33.3%) | 6/25.0 (24.0%)
Terminal rate | 3/25 (12.0%) | 0/20 (0.0%) | 3/20 (15.0%) | 5/20 (25.0%) | 3/19 (15.8%) | 2/21 (9.5%)
First incidence (days) | 316 (T) | 277 | 258 | 251 | 102 | 247
| Vehicle Control | P=0.493 | P=0.084 | P=0.044 | P=0.071 | P=0.233
| | AZT-H | P=0.167 | P=0.100 | P=0.146 | P=0.373
Poly-3 test | | | 3TC-H | P=0.495 | P=0.580 | P=0.378N
| | | | NVP-H | P=0.536N | P=0.267N
| | | | | AZT/3TC-H | P=0.344N
All Organs: Benign or Malignant Neoplasms
Overall rate | 4/25 (16.0%) | 6/25 (24.0%) | 8/25 (32.0%) | 12/25 (48.0%) | 8/24 (33.3%) | 9/25 (36.0%)
Adjusted rate | 4/25.0 (16.0%) | 6/25.0 (24.0%) | 8/25.0 (32.0%) | 12/24.9 (48.2%) | 8/24.0 (33.3%) | 9/25.0 (36.0%)
Terminal rate | 4/25 (16.0%) | 1/20 (5.0%) | 3/20 (15.0%) | 8/20 (40.0%) | 3/19 (15.8%) | 5/21 (23.8%)
First incidence (days) | 316 (T) | 277 | 258 | 251 | 102 | 247
| Vehicle Control | P=0.364 | P=0.161 | P=0.013 | P=0.141 | P=0.097
| | AZT-H | P=0.378 | P=0.066 | P=0.344 | P=0.271
Poly-3 test | | | 3TC-H | P=0.191 | P=0.580 | P=0.500
| | | | NVP-H | P=0.223N | P=0.281N
| | | | | AZT/3TC-H | P=0.541

(T) Terminal kill

a AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP

b Number of neoplasm-bearing animals/number of animals with tissue examined microscopically

c Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

d Observed incidence at terminal kill

e Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between that dosed group and the group stated to the left on the same row. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence is indicated by N. Significant P values are bolded.

f Not applicable; no neoplasms in animal group

g Value of statistic cannot be computed.

TABLE A12 Summary of the Incidence of Nonneoplastic Lesions in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT, 3TC, and NVP: High Dose Comparison^a^

| Vehicle Control | AZT-H | 3TC-H | NVP-H | AZT/3TC-H | AZT/3TC/NVP-H
Disposition Summary
Animals initially in study | 25 | 25 | 25 | 25 | 25 | 25
Early deaths
Moribund | | 2 | 3 | 2 | 4 | 2
Natural deaths | | 2 | 2 | 2 | 1 | 1
Survivors
Died/moribund after day 320 | | 1 | | 1 | | 1
Terminal kill | 25 | 20 | 20 | 20 | 19 | 21
Missexed | | | | | 1
Animals examined microscopically | 25 | 25 | 25 | 25 | 24 | 25
Alimentary System
Esophagus | (25) | (25) | (25) | (25) | (22) | (25)
Gallbladder | (25) | (23) | (23) | (22) | (23) | (24)
Intestine large, cecum | (25) | (23) | (23) | (22) | (23) | (23)
Hyperplasia, lymphoid | | | 1 (4%)
Intestine large, colon | (25) | (23) | (23) | (22) | (23) | (24)
Intestine large, rectum | (25) | (23) | (23) | (22) | (23) | (23)
Intestine small, duodenum | (25) | (23) | (23) | (22) | (23) | (24)
Intestine small, ileum | (25) | (23) | (23) | (22) | (23) | (23)
Intestine small, jejunum | (25) | (23) | (23) | (22) | (23) | (23)
Liver | (25) | (25) | (23) | (24) | (23) | (25)
Basophilic focus | | 1 (4%)
Clear cell focus | | | 1 (4%)
Hematopoietic cell proliferation | | 1 (4%) | | 1 (4%)
Hepatodiaphragmatic nodule | | | 1 (4%)
Infiltration cellular, lymphocyte | 1 (4%) | 3 (12%) | 2 (9%) | 6 (25%) | 3 (13%) | 4 (16%)
Inflammation, chronic active | 1 (4%) | 2 (8%) | 1 (4%) | 2 (8%) | 2 (9%) | 3 (12%)
Tension lipidosis | 2 (8%) | | 2 (9%) | 3 (13%) | 2 (9%) | 3 (12%)
Vacuolization cytoplasmic | 14 (56%) | 13 (52%) | 14 (61%) | 11 (46%) | 13 (57%) | 15 (60%)
Centrilobular, degeneration | | | | 1 (4%) | | 3 (12%)
Mesentery | (0) | (1) | (0) | (0) | (0) | (2)
Fat, necrosis | | | | | | 2 (100%)
Pancreas | (25) | (25) | (25) | (22) | (23) | (24)
Infiltration cellular, lymphocyte | 2 (8%) | 4 (16%) | 2 (8%) | 1 (5%) | 3 (13%) | 2 (8%)
Necrosis | 1 (4%)
Salivary glands | (25) | (25) | (25) | (24) | (23) | (25)
Infiltration cellular, lymphocyte | 22 (88%) | 17 (68%) | 18 (72%) | 19 (79%) | 16 (70%) | 20 (80%)
Stomach, forestomach | (25) | (24) | (24) | (24) | (23) | (24)
Inflammation, suppurative | | 1 (4%)
Inflammation, chronic active | | | | | 1 (4%)
Ulcer | 1 (4%) | 1 (4%) | | | 1 (4%)
Epithelium, hyperplasia | 2 (8%) | 1 (4%) | | | 1 (4%) | 1 (4%)
Stomach, glandular | (25) | (23) | (23) | (22) | (23) | (23)
Cardiovascular System
Blood vessel | (25) | (25) | (25) | (25) | (23) | (25)
Heart | (25) | (25) | (25) | (25) | (24) | (25)
Inflammation, chronic active | | | 1 (4%)
Mineralization | | | 1 (4%) | 1 (4%)
Endocrine System
Adrenal cortex | (25) | (24) | (24) | (25) | (23) | (25)
Accessory adrenal cortical nodule | 1 (4%) | | | 1 (4%)
Hypertrophy | 1 (4%)
Infiltration cellular, polymorphonuclear | | | | | | 1 (4%)
Vacuolization cytoplasmic | 16 (64%) | 14 (58%) | 16 (67%) | 16 (64%) | 13 (57%) | 18 (72%)
Subcapsular, hyperplasia | 25 (100%) | 24 (100%) | 24 (100%) | 24 (96%) | 22 (96%) | 24 (96%)
Adrenal medulla | (23) | (24) | (24) | (25) | (23) | (24)
Islets, pancreatic | (25) | (24) | (25) | (25) | (23) | (25)
Hyperplasia | | 2 (8%) | | 1 (4%) | | 1 (4%)
Parathyroid gland | (20) | (23) | (21) | (20) | (18) | (23)
Infiltration cellular, lymphocyte | | | | | 1 (6%)
Pituitary gland | (25) | (25) | (24) | (25) | (23) | (23)
Fibrosis | | | 1 (4%)
Pars distalis, hyperplasia | | | | | | 1 (4%)
Thyroid gland | (23) | (24) | (25) | (23) | (22) | (25)
Cyst | | | | 1 (4%)
Ectopic thymus | 3 (13%) | | 1 (4%) | | 1 (5%) | 2 (8%)
General Body System
Tissue NOS | (0) | (0) | (0) | (1) | (0) | (0)
Genital System
Clitoral gland | (24) | (24) | (23) | (21) | (21) | (22)
Acinus, degeneration | 9 (38%) | 12 (50%) | 6 (26%) | 5 (24%) | 6 (29%) | 11 (50%)
Duct, ectasia | | | | | | 1 (5%)
Ovary | (25) | (24) | (25) | (24) | (23) | (25)
Atrophy | 1 (4%) | 1 (4%) | 1 (4%)
Cyst | 1 (4%) | 3 (13%) | 1 (4%) | 2 (8%) | 3 (13%)
Cyst dermoid | | | 1 (4%)
Hemorrhage | | | | | | 1 (4%)
Uterus | (25) | (25) | (25) | (23) | (23) | (25)
Atrophy | | | 1 (4%)
Degeneration, cystic | | 1 (4%)
Endometrium, hyperplasia, cystic | 22 (88%) | 19 (76%) | 19 (76%) | 19 (83%) | 17 (74%) | 17 (68%)
Vagina | (25) | (24) | (24) | (24) | (23) | (23)
Infiltration cellular, polymorphonuclear | | 2 (8%) | | 2 (8%) | | 2 (9%)
Hematopoietic System
Bone marrow | (25) | (24) | (24) | (23) | (23) | (24)
Fibrosis | | | 1 (4%)
Hyperplasia | 1 (4%) | 2 (8%) | 2 (8%) | 1 (4%) | 3 (13%) | 3 (13%)
Lymph node | (1) | (3) | (1) | (3) | (4) | (4)
Lumbar, sinus, dilatation | | 1 (33%)
Renal, angiectasis | | 1 (33%)
Renal, thrombus | | 1 (33%)
Lymph node, mandibular | (25) | (25) | (24) | (24) | (23) | (25)
Hyperplasia, lymphoid | 3 (12%) | | 3 (13%) | 4 (17%) | 2 (9%) | 1 (4%)
Lymph node, mesenteric | (25) | (24) | (23) | (24) | (23) | (24)
Angiectasis | | 1 (4%)
Hyperplasia, lymphoid | 1 (4%) | 3 (13%) | 3 (13%) | 4 (17%) | 3 (13%) | 3 (13%)
Spleen | (25) | (25) | (24) | (24) | (23) | (25)
Hematopoietic cell proliferation | 2 (8%) | 8 (32%) | 7 (29%) | 6 (25%) | 6 (26%) | 7 (28%)
Hyperplasia, lymphoid | 20 (80%) | 16 (64%) | 17 (71%) | 14 (58%) | 14 (61%) | 16 (64%)
Thymus | (25) | (21) | (22) | (22) | (24) | (24)
Atrophy | 1 (4%) | | 2 (9%)
Hyperplasia, lymphoid | 6 (24%) | 2 (10%) | 2 (9%) | 8 (36%) | 6 (25%) | 5 (21%)
Integumentary System
Mammary gland | (25) | (25) | (25) | (23) | (23) | (25)
Skin | (25) | (25) | (25) | (25) | (23) | (25)
Inflammation, suppurative | | 1 (4%)
Ulcer | | 1 (4%)
Musculoskeletal System
Bone | (0) | (0) | (2) | (0) | (0) | (0)
Bone, femur | (25) | (25) | (25) | (25) | (24) | (25)
Fibro-osseous lesion | 1 (4%)
Skeletal muscle | (0) | (1) | (2) | (0) | (0) | (0)
Degeneration | | | 1 (50%)
Nervous System
Brain, brain stem | (25) | (24) | (25) | (24) | (23) | (25)
Brain, cerebellum | (25) | (24) | (25) | (24) | (23) | (25)
Hemorrhage | | 1 (4%)
Brain, cerebrum | (25) | (24) | (25) | (24) | (23) | (25)
Mineralization | 2 (8%) | | | 3 (13%)
Peripheral nerve | (0) | (0) | (1) | (0) | (0) | (0)
Axon, degeneration | | | 1 (100%)
Spinal cord, cervical | (0) | (0) | (1) | (0) | (0) | (0)
Spinal cord, lumbar | (0) | (0) | (1) | (0) | (0) | (0)
Spinal cord, thoracic | (0) | (0) | (1) | (0) | (0) | (0)
Respiratory System
Lung | (25) | (24) | (24) | (24) | (24) | (25)
Hemorrhage | | | | 1 (4%)
Infiltration cellular, lymphocyte | | 1 (4%) | | | | 3 (12%)
Inflammation, chronic active | | | | | 1 (4%)
Metaplasia, osseous | | 1 (4%)
Nose | (25) | (25) | (25) | (24) | (24) | (25)
Hyaline droplet | 1 (4%) | 3 (12%) | 4 (16%) | 1 (4%) | 6 (25%) | 6 (24%)
Trachea | (25) | (24) | (24) | (24) | (23) | (25)
Special Senses System
Eye | (25) | (23) | (23) | (22) | (23) | (23)
Cataract | | | | | | 1 (4%)
Harderian gland | (25) | (24) | (25) | (25) | (23) | (24)
Infiltration cellular, lymphocyte | 2 (8%) | | | | 1 (4%)
Inflammation, chronic active | | | 1 (4%)
Urinary System
Kidney | (25) | (24) | (24) | (24) | (23) | (25)
Casts protein | 14 (56%) | 14 (58%) | 8 (33%) | 10 (42%) | 12 (52%) | 15 (60%)
Hydronephrosis | | | | | | 3 (12%)
Infarct | 1 (4%)
Infiltration cellular, lymphocyte | 11 (44%) | 10 (42%) | 11 (46%) | 15 (63%) | 11 (48%) | 11 (44%)
Metaplasia, osseous | | | | | | 1 (4%)
Mineralization | | | 1 (4%)
Renal tubule, regeneration | | | 1 (4%)
Urinary bladder | (25) | (24) | (24) | (23) | (23) | (25)
Infiltration cellular, lymphocyte | 8 (32%) | 4 (17%) | 8 (33%) | 4 (17%) | 8 (35%) | 3 (12%)

a Number of animals examined microscopically at the site and the number of animals with lesion. AZT-H = 240 mg/kg AZT; 3TC-H = 150 mg/kg 3TC; NVP-H = 168 mg/kg NVP; AZT/3TC-H = 240/150 mg/kg AZT/3TC; AZT/3TC/NVP-H = 240/150/168 mg/kg AZT/3TC/NVP