# REFERENCES

Ács, N., Bánhidy, F., Puhó, E.H., and Czeizel, A.E. (2009). Senna treatment in pregnant women and congenital abnormalities in their offspring−a population-based case-control study. Reprod. Toxicol. 28, 100–104.19491001
Agra, Y., Sacristán, A., González, M., Ferrari, M., Portugués, A., and Calvo, M.J. (1998). Efficacy of senna versus lactulose in terminal cancer patients treated with opioids. J. Pain Symptom Manage. 15, 1–7.9436336
Al-Dakan, A.A., al-Tuffail, M., and Hannan, M.A. (1995). Cassia senna inhibits mutagenic activities of benzo[a]-pyrene, aflatoxin B1, shamma and methyl methanesulfonate. Pharmacol. Toxicol. 77, 288–292.8577642
Al-Yahya, M.A., Al-Farhan, A.H., and Adam, S.E.I. (2002). Toxicological interactions of Cassia senna and Nerium oleander in the diet of rats. Am. J. Chin. Med. 30, 579–587.12568285
Armitage, P. (1971). Statistical Methods in Medical Research, pp. 362–365. John Wiley and Sons, Inc., New York.
Beuers, U., Spengler, U., and Pape G.R. (1991). Hepatitis after chronic abuse of senna. Lancet 337, 372–373.
Blumenthal, M., Ed. (2000). Senna. In Herbal Medicine. Expanded Commission E Monographs, pp. 341–345. Integrative Medicine Communications, Newton, MA.
Boorman, G.A., Montgomery, C.A., Jr., Eustis, S.L., Wolfe, M.J., McConnell, E.E., and Hardisty, J.F. (1985). Quality assurance in pathology for rodent carcinogenicity studies. In Handbook of Carcinogen Testing (H.A. Milman and E.K. Weisburger, Eds.), pp. 345–357. Noyes Publications, Park Ridge, NJ.
Boorman, G.A., Hickman, R.L., Davis, G.W., Rhodes, L.S., White, N.W., Griffin, T.A., Mayo, J., and Hamm, T.E., Jr. (1986). Serological titers to murine viruses in 90 day and 2 year studies. In Complications of Viral and Mycoplasmal Infections in Rodents to Toxicology Research and Testing (T.E. Hamm, Jr., Ed.), pp. 11–23. Hemisphere Publishing Corporation, Washington, DC.
Borrelli, F., Capasso, R., Aviello, G., Di Carlo, G., Izzo, A.A., Mascolo, N., and Capasso, F. (2005). Senna and the formation of aberrant crypt foci and tumors in rats treated with azoxymethane. Phytomedicine 12, 501–505.16008128
Bouras, E.P., and Tangalos, E.G. (2009). Chronic constipation in the elderly. Gastroentrol. Clin. N. Am. 38, 463–480.
Boyd, J.T., and Doll, R. (1954). Gastro-intestinal cancer and the use of liquid paraffin. Br. J. Cancer 8, 231–237.13190089
Breimer, D.D., and Baars, A.J. (1976). Pharmacokinetics and metabolism of anthraquinone laxatives. Pharmacology 14 (Suppl. 1), 30–47.790405
Brown, J.P., and Dietrich, P.S. (1979). Mutagenicity of anthraquinone and benzanthrone derivatives in the Salmonella/microsome test: Activation of anthraquinone glycosides by enzymic extracts of rat cecal bacteria. Mutat. Res. 66, 9–24.370585
Brusick, D., and Mengs, U. (1997). Assessment of the genotoxic risk from laxative senna products. Environ. Mol. Mutagen. 29, 1–9.
Bryant-Waugh, R., Turner, H., East, P., Gamble, C., and Mehta, R. (2006). Misuse of laxatives among adult outpatients with eating disorders: Prevalence and profiles. Int. J. Eat. Disord. 39, 404–409.16528732
Cameron, B.D., Phillips, M.W.A., and Fenerty, C.A. (1988). Milk transfer of rhein in the rhesus monkey. Pharmacology 36 (Suppl. 1), 221–225.3368522
Cance, J.D., Ashley, O.S., and Penne, M.A. (2005). Unhealthy weight control behaviors and MDMA (Ecstasy) use among adolescent females. J. Adolesc. Health 37, 409.
Cherniack, E.P., Ceron-Fuentes, J., Florez, H., Sandals, L., Rodriguez, O., and Palacios, J.C. (2008). Influence of race and ethnicity on alternative medicine as a self-treatment preference for common medical conditions in a population of multi-ethnic urban elderly. Complement. Ther. Clin. Pract. 14, 116–123.18396255
Code of Federal Regulations (CFR) 21, Part 58.
Code of Federal Regulations (CFR) 21, § 172.510.
Code of Federal Regulations (CFR) 21, § 310.545.
Code of Federal Regulations (CFR) 21, Part 334.
Cox, D.R. (1972). Regression models and life-tables. J. R. Stat. Soc. B34, 187–220.
Cullen, G., and O’Donoghue, D. (2007). Constipation and pregnancy. Best Pract. Res. Clin. Gastroenterol. 21, 807–818.17889809
Cupp, M.J. (2000). Senna. In Forensic Science: Toxicology and Clinical Pharmacology of Herbal Products. (M.J. Cupp, Ed.), pp. 273–282. Humana Press, Inc., Totowa, NJ.
Dahms, M., Lotz, R., Lang, W., Renner, U., Bayer, E., and Spahn-Langguth, H. (1997). Elucidation of phase I and phase II metabolic pathways of rhein: Species differences and their potential relevance. Drug Metab. Dispos. 25, 442–452.9107544
De Lima, L., and Doyle, D. (2007). International Association for Hospice and Palliative Care list of essential medicines for palliative care. J. Pain Palliat. Care Pharmacother. 21, 29–36.18032353
Dertinger, S.D., Camphausen, K., Macgregor, J.T., Bishop, M.E., Torous, D.K., Avlasevich, S., Cairns, S., Tometsko, C.R., Menard, C., Muanza, T., Chen, Y., Miller, R.K., Cederbrant, K., Sandelin, K., Pontén, I., and Bolcsfoldi, G. (2004). Three-color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ. Mol. Mutagen. 44, 427–435.15517570
de Witte, P. (1993). Metabolism and pharmacokinetics of anthranoids. Pharmacology 47 (Suppl. 1), 86–97.8234447
de Witte, P., and Lemli, J. (1988). Metabolism of ^14^C-rhein and ^14^C-rhein anthrone in rats. Pharmacology 36 (Suppl. 1), 152–157.3368514
Doi, A.M., Irwin, R.D., and Bucher, J.R. (2005). Influence of functional group substitutions on the carcinogenicity of anthraquinone in rats and mice: Analysis of long-term bioassays by the National Cancer Institute and the National Toxicology Program. J. Toxicol. Environ. Health B. Crit. Rev. 8, 109–126.15804751
Donehower, L.A., Harvey, M., Slagle, B.L., McArthur, M.J., Montgomery, C.A., Jr., Butel, J.S., and Bradley, A. (1992). Mice deficient for p53 are developmentally normal but susceptible to spontaneous tumours. Nature 356, 215–221.1552940
Donehower, L.A., Harvey, M., Vogle, H., McArthur, M.J., Montgomery, C.A., Jr., Park, S.H., Thompson, T., Ford, R.J., and Bradley, A. (1995). Effects of genetic background on tumorigenesis in p53-deficient mice. Mol. Carcinog. 14, 16–22.7546219
Dreessen, M., and Lemli, J. (1982). Qualitative and quantitative interactions between the sennosides and some human intestinal bacteria. Pharm. Acta Helv. 57, 350–352.7156174
Dreessen, M., Eyssen, H., and Lemli, J. (1981). The metabolism of sennosides A and B by the intestinal microflora: in vitro and in vivo studies on the rat and the mouse. J. Pharm. Pharmacol. 33, 679–681.6117629
Dufour, P., and Gendre, P. (1984). Ultrastructure of mouse intestinal mucosa and changes observed after long term anthraquinone administration. Gut 25, 1358–1363.6510768
Dunnick, J.K., Hardisty, J.F., Herbert, R.A., Seeley, J.C., Furedi-Machacek, E.M., Foley, J.F., Lacks, G.D., Stasiewicz, S., and French, J.E. (1997). Phenolphthalein induces thymic lymphomas accompanied by loss of the p53 wild type allele in heterozygous p53-deficient (±) mice. Toxicol. Pathol. 25, 533–540.9437796
Dunnett, C.W. (1955). A multiple comparison procedure for comparing several treatments with a control. J. Am. Stat. Assoc. 50, 1096–1121.
European Commission Database (2010). Ingredient: Cassia angustifolia leaf. <http://ec.europa.eu/enterprise/cosmetics/cosing/index.cfm>
Ewe, K. (1980). Effect of rhein on the transport of electrolytes, water, and carbohydrates in the human jejunum and colon. Pharmacology 20 (Suppl. 1), 27–35.
Faber, P., and Strenge-Hesse, A. (1988). Relevance of rhein excretion into breast milk. Pharmacology 36 (Suppl. 1), 212–220.3368521
Fioramonti, J., Dupuy, C., and Buéno, L. (1993). In vivo motility of rat colon chronically pretreated with sennosides. Pharmacology 47 (Suppl. 1), 155–161.8234424
Food and Drug Administration (FDA) (1994). Dietary Supplement Health and Education Act of 1994, Public Law 103-417, 103^rd^ Congress. <http://www.fda.gov/RegulatoryInformation/Legislation/FederalFoodDrugandCosmeticActFDCAct/SignificantAmendmentstotheFDCAct/ucm148003.htm>
Food and Drug Administration (FDA) (1999). Laxative drug products for over-the-counter human use. Food and Drug Administration, Health and Human Services. Final rule. Fed. Regist. 64, 4535–4540.10557608
Foxx-Orenstein, A.E., McNally, M.A., and Odunsi, S.T. (2008). Update on constipation: One treatment does not fit all. Cleve. Clin. J. Med. 75, 813–824.19068963
Franz, G. (1993). The senna drug and its chemistry. Pharmacology 47 (Suppl. 1), 2–6.8234429
Freireich, E.J., Gehan, E.A., Rall, D.P., Schmidt, L.H., and Skipper, H.E. (1966). Quantitative comparison of toxicity of anticancer agents in mouse, rat, hamster, dog, monkey, and man. Cancer Chemother. Rep. 50, 219–244.4957125
French, J.E. (2004). Identification and characterization of potential human carcinogens using B6.129tm1Trp53 heterozygous null mice and loss of heterozygosity at the Trp53 locus. IARC Sci. Publ. 157, 271–287.
French, J.E., Lacks, G.D., Trempus, C., Dunnick, J.K., Foley, J., Mahler, J., Tice, R.R., and Tennant, R.W. (2001a). Loss of heterozygosity frequency at the Trp53 locus in p53-deficient (+/−) mouse tumors is carcinogen- and tissue dependent. Carcinogenesis 21, 99–106.
French, J.E., Storer, R.D., and Donehower, L.A. (2001b). The nature of the heterozygous Trp53 knockout model for identification of mutagenic carcinogens. Toxicol. Pathol. 29, 24–29.11695559
Fujita, Y., Shimizu, T., and Shimizu, H. (2004). A case of interstitial granulomatous drug reaction due to sennoside. Br. J. Dermatol. 150, 1035–1037.15149527
Garcia-Villar, R. (1988). Evaluation of the effects of sennosides on uterine motility in the pregnant ewe. Pharmacology 36 (Suppl. 1), 203–211.3368520
Gart, J.J., Chu, K.C., and Tarone, R.E. (1979). Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. JNCI 62, 957–974.285297
Geboes, K., Nijs, G., Mengs, U., Geboes, K.P.J., Van Damme, A., and de Witte, P. (1993). Effects of ‘contact laxatives’ on intestinal and colonic epithelial cell proliferation. Pharmacology 47 (Suppl. 1), 187–195.8234428
Grimminger, W., and Leng-Peschlow, E. (1988). Instability of rhein-9-anthrone as a problem in pharmacological and analytical use. Pharmacology 36 (Suppl. 1), 129–137.3368511
Grimminger, W., and Witthohn, K. (1993). Analytics of senna drugs with regard to the toxicological discussion of anthranoids. Pharmacology 47 (Suppl. 1), 98–109.
Hardcastle, J.D., and Wilkins, J.L. (1970). The action of sennosides and related compounds on human colon and rectum. Gut 11, 1038–1042.4929273
Hattori, M., Akao, T., Kobashi, K., and Namba, T. (1993). Cleavages of the O- and C-glucosyl bonds of anthrone and 10,10′-bianthrone derivatives by human intestinal bacteria. Pharmacology 47 (Suppl. 1), 125–133.8234419
Heaton, K.W., and Cripps, H.A. (1993). Straining at stool and laxative taking in an English population. Dig. Dis. Sci. 38, 1004–1008.8508693
Heidemann, A., Miltenburger, H.G., and Mengs, U. (1993). The genotoxicity status of senna. Pharmacology 47 (Suppl. 1), 178–186.8234427
Heidemann, A., Völkner, W., and Mengs, U. (1996). Genotoxicity of aloeemodin in vitro and in vivo. Mutat. Res. 367, 123–133.8600368
Helin, T., and Mäkinen-Kiljunen, S. (1996). Occupational asthma and rhinoconjuctivitis caused by senna. Allergy 51, 181–184.8781673
Hietala, P., Marvola, M., Parviainen, T., and Lainonen, H. (1987). Laxative potency and acute toxicity of some anthraquinone derivatives, senna extracts and fractions of senna extracts. Pharmacol. Toxicol. 61, 153–156.3671329
Higgins, P.D.R., and Johanson, J.F. (2004). Epidemiology of constipation in North America: A systematic review. Am. J. Gastroenterol. 99, 750–759.15089911
International Trade Centre (ITC) (2006). Medicinal plants and extracts. Market News Serv. 18, 54.
International Trade Centre (ITC) (2007). Medicinal plants and extracts. Market News Serv. 24, 32.
Jahnke, G.D., Price, C.J., Marr, M.C., Myers, C.B., and George, J.D. (2004). Developmental toxicity evaluation of emodin in rats and mice. Birth Defects Res. B. Dev. Reprod. Toxicol. 71, 89–101.15098202
Kaplan, E.L., and Meier, P. (1958). Nonparametric estimation from incomplete observations. J. Am. Stat. Assoc. 53, 457–481.
Kawasaki, Y., Goda, Y., and Yoshihira, K. (1992). The mutagenic constituents of Rubia tinctorum. Chem. Pharm. Bull. 40, 1504–1509.
Kennedy, J. (2005). Herb and supplement use in the U.S. adult population. Clin. Ther. 27, 1847–1858.16368456
Kissling, G.E., Dertinger, S.D., Hayashi, M., and MacGregor, J.T. (2007). Sensitivity of the erythrocyte micronucleus assay: Dependence on number of cells scored and inter-animal variability. Mutat. Res. 634, 235–240.17851117
Kleibeuker, J.H., Cats, A., Zwart, N., Mulder, N.H., Hardonk, M.J., and de Vries, E.G.E. (1995). Excessively high cell proliferation in sigmoid colon after an oral purge with anthraquinone glycosides. J. Natl. Cancer Inst. 87, 452–453.7677825
Kobashi, K., Nishimura, T., Kusaka, M., Hattori, M., and Namba, T. (1980). Metabolism of sennosides by human intestinal bacteria. Planta. Med. 40, 225–236.7443842
Krumbiegel, G., and Schulz, H.U. (1993). Rhein and aloe-emodin kinetics from senna laxatives in man. Pharmacology 47 (Suppl. 1), 120–124.8234418
Lang, W. (1988). Pharmacokinetics of ^14^C-labelled rhein in rats. Pharmacology 36 (Suppl. 1), 158–171.3368515
Lang, W. (1993). Pharmacokinetic-metabolic studies with ^14^C-aloe emodin after oral administration to male and female rats. Pharmacology 47 (Suppl. 1), 110–119.8234417
Langmead, L., and Rampton, D.S. (2001). Review article: Herbal treatment in gastrointestinal and liver disease− benefits and dangers. Aliment. Pharmacol. Ther. 15, 1239–1252.11552894
Lee, H.-Z., Lin, C.-J., Yang, W.-H., Leung, W.-C., and Chang, S.-P. (2006). Aloe-emodin induced DNA damage through generation of reactive oxygen species in human lung carcinoma cells. Cancer Lett. 239, 55–63.16300878
Lemli, J. (1988). Metabolism of sennosides – an overview. Pharmacology 36 (Suppl. 1), 126–128.3368510
Lemli, J., and Lemmens, L. (1980). Metabolism of sennosides and rhein in rat. Pharmacology 20 (Suppl. 1), 50–57.7375506
Lemli, J., Toppet, S., Cuveele, J., and Janssen, G. (1981). Naphthalene glycosides in Cassia senna and Cassia angustifolia. Planta Med. 43, 11–17.17402001
Leng-Peschlow, E. (1986). Dual effect of orally administered sennosides on large intestine transit and fluid absorption in the rat. J. Pharm. Pharmacol. 38, 606–610.2876077
Leng-Peschlow, E. (1988). Effect of sennosides and related compounds on intestinal transit in the rat. Pharmacology 36 (Suppl. 1), 40–48.3368525
Leng-Peschlow, E. (1989). Effects of sennosides A + B and bisacodyl on rat large intestine. Pharmacology 38 (Suppl. 1), 310–318.2762373
Leng-Peschlow, E., Ed. (1992). Senna and its rational use: Classification of senna as a laxative. Pharmacology 44 (Suppl. 1), 6–9.1565675
Leng-Peschlow, E. (1993). Sennoside-induced secretion and its relevance for the laxative effect. Pharmacology 47 (Suppl. 1), 14–21.8234422
Lydén-Sokolowski, A., Nilsson, A., and Sjöberg, P. (1993). Two-year carcinogenicity study with sennosides in the rat: Emphasis on gastro-intestinal alterations. Pharmacology 47 (Suppl. 1), 209–215.
McConnell, E.E., Solleveld, H.A., Swenberg, J.A., and Boorman, G.A. (1986). Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. JNCI 76, 283–289.3456066
Makena, P.S., and Chung, K.-T. (2007). Effects of various plant polyphenols on bladder carcinogen benzidine-induced mutagenicity. Food Chem. Toxicol. 45, 1899–1909.17560706
Marks, G.B., Salome, C.M., and Woolcock, A.J. (1991). Asthma and allergy associated with occupational exposure to ispaghula and senna products in a pharmaceutical work force. Am. Rev. Respir. Dis. 144, 1065–1069.1952432
Maronpot, R.R., and Boorman, G.A. (1982). Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol. Pathol. 10, 71–80.28094716
Martindale: The Extra Pharmacopoeia (1999). 32nd ed. (K. Parfitt, Ed.), pp. 1212–1213, 1981. The Pharmaceutical Press, London.
Marvola, M., Koponen, A., Hiltunen, R., and Hieltala, P. (1981). The effect of raw material purity on the acute toxicity and laxative effect of sennosides. J. Pharm. Pharmacol. 33, 108–109.6111590
Mascolo, N., Mereto, E., Borrelli, F., Orsi, P., Sini, D., Izzo, A.A., Massa, B., Boggio, M., and Capasso, F. (1999). Does senna extract promote growth of aberrant crypt foci and malignant tumors in rat colon? Dig. Dis. Sci. 44, 2226–2230.10573366
Mengs, U. (1986). Reproductive toxicological investigation with sennosides. Arzneimittelforschung 36, 1355–1358.3790186
Mengs, U. (1988). Toxic effects of sennosides in laboratory animals and in vitro. Pharmacology 36 (Suppl. 1), 180–187.3368517
Mengs, U., and Heidemann, A. (1993). Genotoxicity of sennosides and rhein in vitro and in vivo. Med. Sci. Res. 21, 749–750.
Mengs, U., Krumbiegel, G., and Völkner, W. (1997). Lack of emodin genotoxicity in the mouse micronucleus assay. Mutat. Res. 393, 289–293.9393621
Mengs, U., Grimminger, W., Krumbiegel, G., Schuler, D., Silber, W., and Völkner, W. (1999). No clastogenic activity of a senna extract in the mouse micronucleus assay. Mutat. Res. 444, 421–426.10521682
Mengs, U., Schuler, D., and Marshall, R.R. (2001). No induction of chromosomal aberrations in Chinese hamster ovary cells by chrysophanol. Mutat. Res. 492, 69–72.11377245
Mengs, U., Mitchell, J., McPherson, S., Gregson, R., and Tigner, J. (2004). A 13-week oral toxicity study of senna in the rat with an 8-week recovery period. Arch. Toxicol. 78, 269–275.14997282
Mereto, E., Ghia, M., and Brambilla, G. (1996). Evaluation of the potential carcinogenic activity of senna and cascara glycosides for the rat colon. Cancer Lett. 101, 79–83.8625286
Mitchell, J.M., Mengs, U., McPherson, S., Zijlstra, J., Dettmar, P., Gregson, R., and Tigner, J.C. (2006). An oral carcinogenicity and toxicity study of senna (Tinnevelly senna fruits) in the rat. Arch. Toxicol. 80, 34–44.16205914
Mond, J.M., Hay, P.J., Rodgers, B., Owen, C., and Michell, J.E. (2006). Correlates of self-induced vomiting and laxative misuse in a community sample of women. J. Nerv. Ment. Dis. 194, 40–46.16462554
Morales, M.A., Hernández, D., Bustamante, S., Bachiller, I., and Rojas, A. (2009). Is senna laxative use associated to cathartic colon, genotoxicity, or carcinogenicity? J. Toxicol. Epublication September 10, 2009.
Mori, H., Sugie, S., Niwa, K., Takahashi, M., and Kawai, K. (1985). Induction of intestinal tumours in rats by chrysazin. Br. J. Cancer 52, 781–783.4063151
Mori, H., Sugie, S., Niwa, K., Yoshimi, N., Tanaka, T., and Hirono, I. (1986). Carcinogenicity of chrysazin in large intestine and liver of mice. Jpn. J. Cancer Res. 77, 871–876.3095283
Mori, H., Yoshimi, N., Iwata, H., Mori, Y., Hara, A., Tanaka, T., and Kawai, K. (1990). Carcinogenicity of naturally occurring 1-hydroxyanthraquinone in rats: Induction of large bowel, liver and stomach neoplasms. Carcinogenesis 11, 799–802.2335008
Moussally, K., Oraichi, D., and Bérard, A. (2009). Herbal products use during pregnancy: Prevalence and predictors. Pharmacoepidemiol. Drug Saf. 18, 454–461.19326360
Mueller, S.O., Stopper, H., and Dekant, W. (1998). Biotransformation of the anthraquinones emodin and chrysophanol by cytochrome P450 enzymes. Bioactivation to genotoxic metabolites. Drug Metab. Dispos. 26, 540–546.9616189
Mukhopadhyay, M.J., Saha, A., Dutta, A., De, B., and Mukherjee, A. (1998). Genotoxicity of sennosides on the bone marrow cells of mice. Food Chem. Toxicol. 36, 937–940.9771555
Müller, S.O., Eckert, I., Lutz, W.K., and Stopper, H. (1996). Genotoxicity of the laxative drug components emodin, aloe-emodin and danthron in mammalian cells: Topoisomerase II mediated? Mutat. Res. 371, 165–173.9008718
National Toxicology Program (NTP) (2001). Toxicology and Carcinogenesis Studies of Emodin (CAS No. 518-82-1) in F344/N Rats and B6C3F_1_ Mice (Feed Studies). Technical Report 493. NIH Publication No. 01-3952. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (2004). Danthron. In 11th Report on Carcinogens, pp. III-77–III-78. U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program, Research Triangle Park, NC.
National Toxicology Program (NTP) (2005a). Toxicology Studies of Aspartame (CAS No. 22839-47-0) in Genetically Modified (FVB Tg.AC Hemizygous) and B6.129-Cdkn2a^tm1Rdp^ (N2) Deficient Mice and Carcinogenicity Studies of Aspartame in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Feed Studies). Genetically Modified Model Report No. 1. NIH Publication No. 06-4459. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2005b). Toxicology Studies of Acesulfame Potassium (CAS No. 55589-62-3) in Genetically Modified (FVB Tg.AC Hemizygous) Mice and Carcinogenicity Studies of Acesulfame Potassium in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Feed Studies). Genetically Modified Model Report No. 2. NIH Publication No. 06-4460. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007a). Toxicology Studies of Bromodichloromethane (CAS No. 75-27-4) in Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal, Drinking Water, and Gavage Studies) and Carcinogenicity Studies of Bromodichloromethane in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Drinking Water and Gavage Studies). Genetically Modified Model Report No. 5. NIH Publication No. 07-4422. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007b). Toxicology Studies of Sodium Bromate (CAS No. 7789-38-0) in Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal and Drinking Water Studies) and Carcinogenicity Studies of Sodium Bromate in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Drinking Water Studies). Genetically Modified Model Report No. 6. NIH Publication No. 07-4423. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007c). Toxicology Studies of Dicyclohexylcarbodiimide (CAS No. 538-75-0) in F344/N Rats, B6C3F_1_ Mice, and Genetically Modified (FVB Tg.AC Hemizygous) Mice and Carcinogenicity Study of Dicyclohexylcarbodiimide in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Dermal Studies). Genetically Modified Model Report No. 9. NIH Publication No. 07-4426. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007d). Toxicology Study of Diisopropylcarbodiimide (CAS No. 693-13-0) in Genetically Modified (FVB Tg.AC Hemizygous) Mice and Carcinogenicity Study of Diisopropylcarbodiimide in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Dermal Studies). Genetically Modified Model Report No. 10. NIH Publication No. 07-4427. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007e). Toxicology Studies of Dichloroacetic Acid (CAS No. 79-43-6) in Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal and Drinking Water Studies) and Carcinogenicity Studies of Dichloroacetic Acid in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Drinking Water Studies). Genetically Modified Model Report No. 11. NIH Publication No. 07-4428. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2008). Toxicology Studies of Allyl Bromide (CAS No. 106-95-6) in Genetically Modified (FVB Tg.AC Hemizygous) Mice and Carcinogenicity Studies of Allyl Bromide in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Dermal and Gavage Studies). Genetically Modified Model Report No. 7. NIH Publication No. 08-4424. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2010). Photocarcinogenesis Study of Aloe Vera (CAS No. 481-82-1) in SKH1 Mice (Simulated Solar Light and Topical Application Study). Technical Report 553. NIH Publication No. 10-5894. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2012). Toxicology and Carcinogenicity Studies of 3′-Azido-3′-Deoxythymidine (CAS No. 30516-87-1) in Genetically Modified C3B6.129F1-Trp53^tm1Brd^ N12 Haploinsufficient (+/−) (Heterozygous F1 p53^+/−^) Mice (In Utero and Postnatal Gavage Studies). Genetically Modified Model Report No. 14. NIH Publication No. 12-5967. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC (in press).
Nesslany, F., Simar-Meintières, S., Ficheux, H., and Marzin, D. (2009). Aloe-emodin-induced DNA fragmentation in the mouse in vivo comet assay. Mutat. Res. 678, 13–19.19559101
Newall, C.A., Anderson, L.A., and Phillipson, J.D. (1996). Senna. In Herbal Medicines: A Guide for Health-care Professionals, pp. 243–244. The Pharmaceutical Press, London.
Nijs, G., de Witte, P., Geboes, K., Meulemans, A., Schuurkes, J., and Lemli J. (1993). Influence of rhein anthrone on peristaltic reflex of guinea-pig isolated ileum: Involvement of prostaglandins. Br J. Pharmacol. 108, 269–273.8094026
Novartis (2010). Product information for Ex-Lax Maximum Strength^®^. <http://ex-lax.com/product-max.shtml>
Occhipinti, K.E., and Di Palma, J.A. (2009). How to choose the best preparation for colonoscopy. Nat. Rev. Gastroenterol. Hepatol. 6, 279–286.19404268
Patra, D.D., Chand, S., Sastry, K.P., Singh, S.P., Bahl, J.R., and Khanuja, S.P.S. (2005). Agrotechnologies of senna (Cassia angustifolia). J. Medicin. Aromat. Plant Sci. 27, 101–105.
PDR for Herbal Medicines (2007). Senna. 4th ed., pp. 743–747. Thomson Healthcare, Inc., Montvale, NJ.
Prather, C.M. (2004). Pregnancy-related constipation. Curr. Gastroenterol. Rep. 6, 402–404.15341717
Pritchard, J.B., French, J.E., Davis, B.J., and Haseman, J.K. (2003). The role of transgenic mouse models in carcinogen identification. Environ. Health Perspect. 111, 444–454.12676597
Rao, G.N., Haseman, J.K., and Edmondson, J. (1989a). Influence of viral infections on body weight, survival, and tumor prevalence in Fischer 344/Ncr rats on two-year studies. Lab. Anim. Sci. 39, 389–393.2554057
Rao, G.N., Piegorsch, W.W., Crawford, D.D., Edmondson, J., and Haseman, J.K. (1989b). Influence of viral infections on body weight, survival, and tumor prevalence of B6C3F1 (C57BL/6N × C3H/HeN) mice in carcinogenicity studies. Fundam. Appl. Toxicol. 13, 156–164.2767355
Rao, S.S.C. (2009). Constipation: Evaluation and treatment of colonic and anorectal motility disorders. Gastrointest. Endoscopy Clin. N. Am. 19, 117–139.
Ruby, C.M., Fillenbaum, G.G., Kuchibhatla, M.N., and Hanlon, J.T. (2003). Laxative use in the community-dwelling elderly. Am. J. Geriatr. Pharmacother. 1, 11–17.15555462
Rudolph, R.L., and Mengs, U. (1988). Electron microscopical studies on rat intestine after long-term treatment with sennosides. Pharmacology 36 (Suppl. 1), 188–193.
Rumsey, R.D.E., Squires, P.E., and Read, N.W. (1993). In vitro effects of sennoside on contractile activity and fluid flow in the perfused large intestine of the rat. Pharmacology 47 (Suppl. 1), 32–39.8234440
Samuelsson, G. (1999). Drugs of Natural Origin: A Textbook of Pharmacognosy, 4th ed., p. 201. Swedish Pharmaceutical Society, Stockholm.
Sandnes, D., Johansen, T., Teien, G., and Ulsaker, G. (1992). Mutagenicity of crude senna and senna glycosides in Salmonella typhimurium. Pharmacol. Toxicol. 71, 165–172.1438037
Sasaki, K., Yamauchi, K., and Kuwano, S. (1979). Metabolic activation of sennoside A in mice. Planta Med. 37, 370–378.538110
Satia, J.A., Littman, A., Slatore, C.G., Galanko, J.A., and White, E. (2009). Cancer Epidemiol. Biomarkers Prev. 18, 1419–1428.19423520
Seybold, U., Landauer, N., Hillebrand, S., and Goebel, F.D. (2004). Senna-induced hepatitis in a poor metabolizer. Ann. Intern. Med. 14, 650–651.
Shah, N.D., Chitkara, D.K., Locke, G.R., Meek, P.D., and Talley, N.J. (2008). Ambulatory care for constipation in the United States, 1993-2004. Am. J. Gastroenterol. 103, 1746–1753.18557708
Shah, S.A., Ravishankara, M.N., Nirmal, A., Shishoo, C.J., Rathod, I.S., and Suhagia, B.N. (2000). Estimation of individual sennosides in plant materials and marketed formulations by an HPTLC method. J. Pharm. Pharmacol. 52, 445–449.10813557
Siegers, C.-P., Siemers, J., and Baretton, G. (1993a). Sennosides and aloin do not promote dimethylhydrazine-induced colorectal tumors in mice. Pharmacology 47 (Suppl. 1), 205–208.8234430
Siegers, C.-P., von Hertzberg-Lottin, E., Otte, M., and Schneider, B. (1993b). Anthranoid laxative abuse − a risk for colorectal cancer? Gut 34, 1099–1101.8174962
Silva, C.R., Monteiro, M.R., Rocha, H.M., Ribeiro, A.F., Caldeira-de-Araujo, A., Leitão, A.C., Bezerra, R.J.A.C., and Pádula, M. (2008). Assessment of antimutagenic and genotoxic potential of senna (Cassia angustifolia Vahl.) aqueous extract using in vitro assays. Toxicol. in Vitro 22, 212–218.17826029
Smith, B. (1968). Effect of irritant purgatives on the myenteric plexus in man and the mouse. Gut 9, 139–143.5655023
Smitherman, L.C., Janisse, J., and Mathur, A. (2005). The use of folk remedies among children in an urban black community: Remedies for fever, colic, and teething. Pediatrics 115, e297–e304.15741355
Spiller, H.A., Winter, M.L., Weber, J.A., Krenzelok, E.P., Anderson, D.L., and Ryan, M.L. (2003). Skin breakdown and blisters from senna-containing laxatives in young children. Ann. Pharmacother. 37, 636–639.12708936
Srivastava, M., Srivastava, S., Khatoon, S., Rawat, A.K.S., Mehrotra, S., and Pushpangadan, P. (2006). Pharmacognostical evaluation of Cassia angustifolia seeds. Pharm. Bio. 44, 202–207.
Steffen, K.J., Roerig, J.L., Mitchell, J.E., and Crosby, R.D. (2006). A survey of herbal and alternative medication use among participants with eating disorder symptoms. Int. J. Eat. Disord. 39, 741–746.16941628
Storer, R.D., French, J.E., Haseman, J., Hajian, G., LeGrand, E.K., Long, G.G., Mixson, L.A., Ochoa, R., Sagartz, J.E., and Soper, K.A. (2001). P53^(+/−)^ hemizygous knockout mouse: Overview of available data. Toxicol. Pathol. 29, 30–50.11695560
Strickland, F.M., Muller, H.K., Stephens, L.C., Bucana, C.D., Donawho, C.K., Sun, Y., and Pelley, R.P. (2000). Induction of primary cutaneous melanomas in C3H mice by combined treatment with ultraviolet radiation, ethanol, and aloe emodin. Photochem. Photobiol. 72, 407–414.10989613
Sugita, K., Izu, K., and Tokura, Y. (2006). Erythema multiforme-like drug eruption caused by sennoside. Int. J. Dermatol. 45, 1123.16961536
Tarone, R.E. (1975). Tests for trend in life table analysis. Biometrika 62, 679–682.
Tennant, R.W., French, J.E., and Spalding, J.W. (1995). Identifying chemical carcinogens and assessing potential risk in short-term bioassays using transgenic mouse models. Environ. Health Perspect. 103, 942–950.8529591
Terreaux, C., Wang, Q., Ioset, J.-R., Ndjoko, K., Grimminger, W., and Hostettmann, K. (2002). Complete LC/MS analysis of a Tinnevelli senna pod extract and subsequent isolation and identification of two new benzophenone glucosides. Planta Med. 68, 349–354.11988861
Tillett, J., Kostich, L.M., and VandeVusse, L. (2003). Use of over-the-counter medications during pregnancy. J. Perinat. Neonat. Nurs. 17, 3–18.
Toyoda, K., Nishikawa, A., Furukawa, F., Kawanishi, T., Hayashi, Y., and Takahashi, M. (1994). Cell proliferation induced by laxatives and related compounds in the rat intestine. Cancer Lett. 83, 43–49.8062233
Tozzi, F., Thornton, L.M., Mitchell, J., Fichter, M.M., Klump, K.L., Lilenfeld, L.R., Reba, L., Strober, M., Kaye, W.H., Bulik, C.M., and the Price Foundation Collaborative Group (2006). Features associated with laxative abuse in individuals with eating disorders. Psychosom. Med. 68, 470–477.16738081
Van den Berg, M.M., Benninga, M.A., and Di Lorenzo, C. (2006). Epidemiology of childhood constipation: A systematic review. Am. J. Gastroenterol. 101, 2401–2409.17032205
van Gorkom, B.A.P., de Vries, E.G.E., Karrenbeld, A., and Kleibeuker, J.H. (1999). Review article: Anthranoid laxatives and their potential carcinogenic effects. Aliment. Pharmacol. Ther. 13, 443–452.10215727
van Gorkom, B.A.P., Karrenbeld, A., van der Sluis, T., Koudstaal, J., de Vries, E.G.E., and Kleibeuker, J.H. (2000). Influence of a highly purified senna extract on colonic epithelium. Digestion 61, 113–120.10705175
van Gorkom, B.A.P., Karrenbeld, A., van der Sluis, T., Zwart, N., de Vries, E.G.E., and Kleibeuker, J.H. (2001). Apoptosis induction by sennoside laxatives in man; escape from a protective mechanism during chronic sennoside use? J. Pathol. 194, 493–499.11523059
van Tilberg, M.A.L, Palsson, O.S., Levy, R.L., Feld, A.D., Turner, M.J., Drossman, D.A., and Whitehead, W.E. (2008). Complementary and alternative medicine use and cost in functional bowel disorders: A six month prospective study in a large HMO. BMC Complement. Altern. Med. 8, 46.18652682
Vanderperren, B., Rizzo, M., Angenot, L., Haufroid, V., Jadoul, M., and Hantson, P. (2005). Acute liver failure with renal impairment related to the abuse of senna anthraquinone glycosides. Ann. Pharmacother. 39, 1353–1357.15956233
Wanitschke, R., and Karbach, U. (1988). Influence of rhein on rat colonic Na^+^, K^+^-ATPase and permeability in vitro. Pharmacology 36 (Suppl. 1), 98–103.2835785
Westendorf, J., Marquardt, H., Poginsky, B., Dominiak, M., Schmidt, J., and Marquardt, H. (1990). Genotoxicity of naturally occurring hydroxyanthraquinones. Mutat. Res. 240, 1–12.
Williams, D.A. (1971). A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics 27, 103–117.5547548
Williams, D.A. (1972). The comparison of several dose levels with a zero dose control. Biometrics 28, 519–531.5037867
Witt, K.L., Livanos, E., Kissling G.E., Torous, D.K., Caspary, W., Tice, R.R., and Recio, L. (2008). Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat. Res. 649, 101–113.17869571
World Health Organization (WHO) (1999). WHO Monographs on Selected Medicinal Plants. Vol. 1. World Health Organization, Geneva.
Yagi, T., and Yamauchi, K. (1999). Synergistic effects of anthraquinones on the purgative activity of rhein anthrone in mice. J. Pharm. Pharmacol. 51, 93–95.10197424
Yagi, T., Yamauchi, K., and Kuwano, S. (1997). The synergistic purgative action of aloe-emodin anthrone and rhein anthrone in mice: Synergism in large intestinal propulsion and water secretion. J. Pharm. Pharmacol. 49, 22–25.9120764
Yamauchi, K., Yagi, T., and Kuwano, S. (1993). Suppression of the purgative action of rhein anthrone, the active metabolite of sennosides A and B, by calcium channel blockers, calmodulin antagonists and indometacin. Pharmacology 47 (Suppl. 1), 22–31.8234433
Zeiger, E., Anderson, B., Haworth, S., Lawlor, T., and Mortelmans, K. (1992). Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ. Mol. Mutagen. 19 (Suppl. 21), 2–141.1541260