# SUMMARY OF PEER REVIEW PANEL COMMENTS

On April 5, 2011, the draft Report on the toxicology and carcinogenesis studies of senna received public review by the National Toxicology Program’s Peer Review Panel. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. I. Surh, NIEHS, introduced the study of senna by describing how it is derived, the nomination of senna for study by the FDA, the selection of the p53 heterozygous mouse model, and the major components of senna. She also illustrated the metabolism of sennosides A and B, the main ingredients for laxative action in senna. The proposed conclusions were:

Under the conditions of this 40-week feed study, there was no evidence of carcinogenic activity of senna in male or female C3B6.129F1/Tac-Trp53^tm1Brd^ N12 haploinsufficient mice exposed to 100, 300, 1,000, 3,000, or 10,000 ppm. Senna induced epithelial hyperplasia of the large intestine (colon and cecum) in male and female mice.

Dr. Klaunig, the first primary reviewer, had no criticisms of the scientific performance of the study and felt that the report was well written. He was particularly pleased with the discussion of the rationale for the construction of the test mice and would have liked a clarification of the rationale for the 5-week study. Dr. Klaunig noted the mention of a reduction in heart weight in the 5-week study but not in the chronic study and wished to see some comment on that issue. He also wondered why the 5-week study had been conducted on wild-type mice and not the transgenics.

Dr. Rogers, the second primary reviewer, agreed with Dr. Klaunig about the quality of the study and draft report, but felt that the choice of the p53 haploinsufficient mouse model may have been incorrect. He recommended that in the future if a substance is to be tested that presents with a lower bowel phenotype, models that would be prone to developing inflammatory bowel disease or bowel cancer should be considered. He said the p53 haploinsufficiency in the chosen model might have actually had a protective effect.

Dr. Barlow, the third primary reviewer, questioned whether the doses were set high enough in the studies to truly test the compound’s carcinogenic potential. He also noted the mention in the report of reduction in heart weight in the 5-week study, but felt that since it was biologically meaningless, it should be removed from the report, rather than discussed further.

Dr. Miller expressed “a great deal of concern about the choice of the p53 model,” in that it is known to be unsusceptible to lower GI tumors, and there are many other choices of models that would have been more susceptible to such tumors. Thus, he said, a mouse was selected for a study of colon cancer that was unlikely to get colon cancer, constituting what he characterized as a “fatal flaw” in terms of valid conclusions.

Dr. J.R. Bucher, NIEHS, replied that the p53 model is one of the most evaluated of mouse models, and is accepted by the FDA for genotoxicity and carcinogenicity studies. He cited studies involving another laxative using that model as a precedent for the choice of models in the senna studies. Also, he said, the p53 model was not chosen based on a presumption of colon cancer.

Dr. Miller asked if any positive controls with known carcinogens had been employed. Dr. J.E. French, NIEHS, responded that studies in p53 haploinsufficient mouse models had shown induction of colorectal tumors by azoxymethane, which has been described in publication. Other panel members expressed similar concerns about the p53 model and lack of positive controls.

Dr. Surh said the 5-week study had been conducted to set doses for the 40-week study. She added that it had been felt that the 10,000 ppm dose was a sufficient challenge in the mouse model used.

Dr. Klaunig moved and Dr. Barlow seconded that the conclusions be accepted as written. The motion was approved with five yes votes and two no votes. Dr. Miller voted against the motion, citing his concerns about the choice of mouse model. Dr. Heiger-Bernays also voted no, based on the appropriateness of the model, as well as feeling that the study should have lasted longer. Following the vote, Dr. Bucher added that NTP had had similar discussions about the mouse model, and had been fairly concerned about the epithelial hyperplasia and the appearance of the colon in the test animals. He asked for the panel’s impression of whether further studies of senna would be in the best interest of the NTP.

Dr. Rogers endorsed further studies with animals with a pro-inflammatory bowel phenotype. Dr. Klaunig mentioned that there had been a 2-year rat study of senna, and asked if anyone was familiar with the results. Dr. Surh replied that the rat study had shown no increase in tumors.