# NATIONAL TOXICOLOGY PROGRAM TECHNICAL REPORTS PEER REVIEW PANEL

The members of the Peer Review Panel who evaluated the draft NTP Report on senna on April 5, 2011, are listed below. Panel members serve as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, panel members have five major responsibilities in reviewing the NTP studies:

- to ascertain that all relevant literature data have been adequately cited and interpreted,
- to determine if the design and conditions of the NTP studies were appropriate,
- to ensure that the Technical Report presents the experimental results and conclusions fully and clearly,
- to judge the significance of the experimental results by scientific criteria, and
- to assess the evaluation of the evidence of carcinogenic activity and other observed toxic responses.

- John Cullen, V.M.D., Ph.D., Chairperson
  College of Veterinary Medicine
  North Carolina State University
  Raleigh, NC
- Lucy M. Anderson, Ph.D.,
  Consultant
  Catonsville, MD
- Norman J. Barlow, D.V.M., Ph.D., M.B.A., M.L.D.,
  Primary Reviewer
  Preclinical Safety
  Sanofi-aventis
  Bridgewater, NJ
- Diane F. Birt, Ph.D.
  Department of Food Science and Human Nutrition
  Iowa State University
  Ames, IA
- Wendy J. Heiger-Bernays, Ph.D.
  School of Public Health
  Boston University
  Boston, MA
- James E. Klaunig, Ph.D., Primary Reviewer
  Department of Environmental Health
  Indiana University
  Indianapolis, IN
- Mark S. Miller, M.Phil., Ph.D.
  School of Medicine
  Wake Forest University
  Winston-Salem, NC
- Arlin B. Rogers, D.V.M., Ph.D., Primary Reviewer
  Lineberger Comprehensive Cancer Center
  University of North Carolina at Chapel Hill
  Chapel Hill, NC