# DISCUSSION AND CONCLUSIONS

These studies provide data on the carcinogenic potential of senna in a genetically-modified mouse model.

Treatment-related epithelial hyperplasia in the large intestine occurred in both the 5-week senna study in C57BL/6NTac mice and in the 40-week senna study in C3B6.129F1/Tac-Trp53^tm1Brd^ N12 haploinsufficient mice (also referred to in this study as heterozygous F1 p53^+/−^ mice); in both studies, senna was administered in feed. The daily senna exposure concentrations in these studies overlapped daily exposures in humans taking senna in laxative preparations.

In the 40-week study, the average senna consumption of males exposed to 100, 300, 1,000, 3,000, or 10,000 ppm was 12, 36, 120, 365, or 1,260 mg/kg per day. Based on the percent total weight values for sennosides A and B (approximately 2% of senna by weight), the sennosides A and B consumption was approximately 0.24, 0.72, 2.4, 7.3, or 25.4 mg/kg or 0.72, 2.2, 7.2, 21.9, or 76.1 mg/m^3^ (on a body surface area basis) per day (Freireich et al., 1966). Senna consumption by females was similar to that by males. For a typical over-the-counter senna laxative preparation taken twice daily, the amount of sennosides consumed is approximately 1.4 mg/kg per day or 51.8 mg/m^3^ (body surface area basis) per day (Novartis, 2010). In some cases, laxatives may be taken in greater than recommended amounts (Cance et al., 2005; Bryant-Waugh et al., 2006; Mond et al., 2006; Tozzi et al., 2006).

Colon and cecum epithelial hyperplasias were seen in 5,000 and 10,000 ppm males and females in the 5-week C57BL/6NTac mouse study. A few female mice exposed to 10,000 ppm also had epithelial hyperplasia of the rectum. Colon/cecum epithelium hyperplastic lesions also occurred in male and female mice in the 40-week heterozygous F1 p53^+/−^ mouse study. In humans, senna may be associated with increased cell proliferation in the intestine (Kleibuker et al., 1995; van Gorkom et al., 2000).

The C3B6.129F1/Tac-Trp53^tm1Brd^ N12 haploinsufficient mouse used in these senna studies was a different strain than that used in earlier NTP GMM studies. Those studies used the B6.129F1-Trp53^tm1Brd^ (N5) haploinsufficient mouse, a strain resulting from back-crossing the p53^+/−^ mouse five times to the C57/B6 mouse (Pritchard et al., 2003; NTP, 2005a,b; 2007a,b,c,d,e; 2008). The source of the knockout gene is the same in both p53^+/−^ mouse strains (Donehower et al., 1992, 1995). There have been no comparisons for chemical carcinogenic effects in these two p53^+/−^ mouse trains.

Senna had a laxative effect in rats receiving daily doses of 300 mg/kg or greater by oral gavage for 13 consecutive weeks (Mengs et al., 2004); however, in the current studies no laxative effect was observed at comparable or higher doses in mice, this possibly indicates species-dependent differences in sensitivity or kinetics in formation of rhein anthrone, primarily responsible for the purgative activity of senna (Leng-Peschlow, 1992; Yamauchi et al., 1993), or difference in kinetics between gavage and feed. Rhein anthrone is formed by intestinal bacteria at the site of action and is purportedly metabolized through a free radical (Lemli and Lemmens, 1980; Dreessen et al., 1981; Lemli, 1988), a possible mechanism in the formation of the intestinal hyperplastic response observed at the high dose in the current studies.

Two different lots of senna were tested in four independent bacterial mutagenicity assays (Appendix B). Two of the samples, one of which was the same lot of senna used in the 40-week study, gave positive results. Most of the positive responses observed with these two senna samples occurred in tests conducted with rat or hamster liver S9 preparations. Results from the testing of the two other samples that came from the same lot of senna used in the 40-week mouse study were negative. The variability in responses among different lots may be related to sample constituents. Information from the literature indicates that some metabolites and/or constituents of senna are potentially genotoxic (Dreessen et al., 1981; Dreessen and Lemli, 1982; Grimminger and Leng-Peschlow, 1988; Krumbiegel and Schulz, 1993; Lang, 1993; Brusick and Mengs, 1997; Morales et al., 2009). Rhein is mutagenic in Salmonella typhimurium strains TA98 and TA100 when tested in the presence of induced rat or hamster liver S9 mix (Appendix B); no in vivo mutagenicity data are available for rhein. Aloe-emodin is a well documented in vitro mutagen, with or without S9, in both bacterial and mammalian systems (Heidemann et al., 1993; Müller et al., 1996; Nesslany et al., 2009); in vivo DNA damage studies with aloe-emodin in mice using the comet assay gave positive results in both colon and kidney cells (Nesslany et al., 2009). Emodin is also a well documented in vitro mutagen but data from in vivo studies suggest that emodin does not induce chromosomal damage in erythrocytes (micronucleus test) (Mengs et al., 1997; NTP, 2001). Overall, in vitro studies provide evidence of mutagenicity of some senna constituents and metabolites. Additional in vivo studies may help to define any potential genotoxic hazard associated with senna exposure.

Other carcinogenicity studies have been conducted with senna. Mitchell et al. (2006) conducted a 2-year oral gavage study of senna in Sprague-Dawley rats (0, 25, 100, or 300 mg/kg per day). There were no treatment-related carcinogenic effects in any target organ and there was only a slight intestinal hyperplasia in the treated groups. In another 2-year study in Sprague-Dawley rats administered a senna extract (reported to contain up to 35% to 42% sennosides) in drinking water (to deliver 0, 5, 15, or 25 mg/kg per day of the test article), no intestinal lesions were observed in treated or control groups (Lydén-Sokolowski et al., 1993). Also, administration of 30 and 60 mg/kg senna extract by oral gavage (six times per week) for 110 weeks in male Wistar rats did not induce aberrant crypt foci or tumors (Borrelli et al., 2005).

Chronic exposure of rodents to specific anthraquinones has resulted in increased incidences of tumors in some tissues (Mori et al., 1985, 1986, 1990; Doi et al., 2005). In studies of a series of anthraquinones conducted by the NTP, the occurrence and site of carcinogenicity appeared to be directly related to the number, position, or type of side chain substitutions (Doi et al., 2005). Further, in rodent studies conducted by Mori et al. (1985, 1986, 1990), exposure to hydroxyanthraquinones (1-hydroxyanthraquinone and danthron), structurally similar to rhein, caused tumors in the large intestine of rats.

In the current study, senna administered in the feed caused intestinal hyperplasia in heterozygous F1 p53^+/−^ mice. Although senna was evaluated in this current study, specific senna constituents or metabolites have not been evaluated in this model.

## Conclusions

Under the conditions of this 40-week feed study, there was no evidence of carcinogenic activity^*^ of senna in male or female C3B6.129F1/Tac-Trp53^tm1Brd^ N12 haploinsufficient mice exposed to 100, 300, 1,000, 3,000, or 10,000 ppm.

Senna induced epithelial hyperplasia of the large intestine (colon and cecum) in male and female mice.

* Explanation of Levels of Evidence of Carcinogenic Activity is on page 8. A summary of the Technical Reports Peer Review Panel comments and the public discussion on this Report appears on page 10.