# RESULTS

## 5-Week Study in C57BL/6NTac Mice

All mice survived to the end of the study (Table 2). Final mean body weights and body weight gains of exposed groups were similar to those of the controls. Feed consumption by exposed groups was similar to that by the controls. Concentrations of 625, 1,250, 2,500, 5,000, and 10,000 ppm senna in feed resulted in average daily doses of 115, 245, 490, 975, and 2,075 mg senna/kg body weight to males and 160, 310, 625, 1,190, and 2,570 mg/kg to females. There were no treatment-related clinical findings. Significant decreases in absolute heart weights occurred in all exposed groups of males (Table C1). Relative heart weights were significantly decreased in 625, 5,000, and 10,000 ppm males.

TABLE 2 Survival, Body Weights, and Feed Consumption of C57BL/6NTac Mice in the 5-Week Feed Study of Senna^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%) | Feed Consumption Week 1 | Feed Consumption Week 5
Male
0 | 5/5 | 19.4 ± 0.3 | 23.5 ± 0.3 | 4.1 ± 0.4 | | 4.0 | 4.3
625 | 5/5 | 19.3 ± 0.3 | 23.2 ± 0.3 | 3.8 ± 0.3 | 99 | 3.9 | 3.9
1,250 | 5/5 | 19.3 ± 0.6 | 22.6 ± 0.5 | 3.3 ± 0.3 | 96 | 4.2 | 4.0
2,500 | 5/5 | 19.4 ± 0.5 | 23.2 ± 0.8 | 3.8 ± 0.4 | 99 | 4.2 | 4.3
5,000 | 5/5 | 19.4 ± 0.7 | 23.3 ± 0.3 | 4.0 ± 0.5 | 99 | 4.3 | 4.0
10,000 | 5/5 | 19.3 ± 0.5 | 22.5 ± 0.2 | 3.2 ± 0.4 | 96 | 4.3 | 4.3
Female
0 | 5/5 | 16.0 ± 0.5 | 20.3 ± 0.4 | 4.2 ± 0.2 | | 3.7 | 5.1
625 | 5/5 | 15.8 ± 0.5 | 19.2 ± 0.4 | 3.4 ± 0.2 | 95 | 4.5 | 4.9
1,250 | 5/5 | 16.0 ± 0.2 | 20.1 ± 0.3 | 4.1 ± 0.2 | 99 | 4.2 | 5.3
2,500 | 5/5 | 15.9 ± 0.6 | 20.2 ± 0.5 | 4.3 ± 0.3 | 100 | 4.4 | 4.8
5,000 | 5/5 | 15.7 ± 0.3 | 19.1 ± 0.6 | 3.4 ± 0.6 | 94 | 4.0 | 4.6
10,000 | 5/5 | 15.8 ± 0.6 | 19.5 ± 0.5 | 3.7 ± 0.3 | 96 | 4.7 | 4.6

a Weights and weight changes are given as mean ± standard error. Feed consumption is expressed as grams per animal per day. Differences in weights and weight changes from the control group are not significant by Dunnett’s test.

b Number of animals surviving at 5 weeks/number initially in group

Exposure to senna resulted in epithelial hyperplasia of the cecum and colon in males and of the cecum, colon, and rectum in females (Table 3). A no-observed-effect level (NOEL) could not be determined for the male mice because the 625 ppm group had two mice with minimal hyperplasia of the cecum, and one animal in the 1,250 ppm group had hyperplasia of the cecum and colon. The NOEL for female mice was 1,250 ppm, based upon the lack of lesions in that group and the presence of two animals in the 2,500 ppm group with cecal hyperplasia and one with hyperplasia of the colon. The hyperplasia was graded for severity semiquantitatively. In the cecum and colon, grade 1 (minimal) lesions were recorded when the epithelial thickness was approximately 150 to 200 µm, grade 2 (mild) when it was around 200 to 250 µm, and grade 3 (moderate) when sections of the epithelium were greater than 250 µm. None of the lesions had changes severe enough to warrant a severity score of 4 (marked). The severity grade also took into account the amount of the tissue in the section involved − minimal lesions might only involve a focal area, whereas lesions with higher severity scores involved more of the tissue on the section. The hyperplasia was characterized by a thickening of the mucosa by a lengthening of the crypts (Plates 1 and 2). This was due to increased numbers of epithelial cells, which were small, with basophilic cytoplasm and round to oval nuclei, which became more vesicular toward the luminal surface of the glands. Goblet cells were interspersed with these cells, but did not constitute an increased proportion of the epithelial cells in the colon or cecum. Mitotic figures were numerous. Due to the naturally thicker mucosa found in the rectum, the same criteria for diagnosis used for the cecum and colon could not be applied to the rectum; severity grading for the rectum was done more subjectively.

Exposure Concentration Selection Rationale: There were no treatment-related clinical signs of toxicity in the 5-week study. Final mean body weights of exposed mice were within 10% of those of the control mice. Epithelial hyperplasia was seen in the cecum of all exposed groups of males, in the colon of 1,250 ppm or greater males, in the cecum and colon of 2,500 ppm or greater females, and in the rectum of 10,000 ppm females. Because intestinal lesions were not considered to be of sufficient severity to cause mortality in a 40-week p53^(+/−)^ mouse study, the high dose of 10,000 ppm was selected. In order to expose mice to senna in a broader range, 0, 100, 300, 1,000, 3,000, and 10,000 ppm were selected as the exposure concentrations for the 40-week study.

TABLE 3 Incidences of Hyperplasia in the Large Intestine in C57BL/6NTac Mice in the 5-Week Feed Study of Senna

| 0 ppm | 625 ppm | 1,250 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm
Male
Cecum^a^ | 5 | 5 | 5 | 5 | 5 | 5
Hyperplasia, epithelial^b^ | 0 | 2 (1.0)^c^ | 1 (10) | 1 (1.0) | 3 (1.0) | 5^**^ (1.8)
Colon | 5 | 5 | 5 | 5 | 5 | 5
Hyperplasia, epithelial | 0 | 0 | 1 (10) | 1 (1.0) | 4^*^ (1.3) | 5^**^ (2.0)
Female
Cecum | 5 | 5 | 5 | 5 | 5 | 5
Hyperplasia, epithelial | 0 | 0 | 0 | 2 (1.0) | 4^*^ (1.0) | 5^**^ (1.8)
Colon | 5 | 5 | 5 | 5 | 5 | 5
Hyperplasia, epithelial | 0 | 0 | 0 | 1 (1.0) | 5^**^ (1.4) | 5^**^ (3.0)
Rectum | 5 | 5 | 5 | 5 | 5 | 5
Hyperplasia, epithelial | 0 | 0 | 0 | 0 | 0 | 3 (1.0)

* Significantly different (P≤0.05) from the control group by the Fisher exact test

** P≤0.01

a Number of animals with tissue examined microscopically

b Number of animals with lesion

c Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## 40-Week Study in Heterozygous F1 p53^+/−^ Mice

### Survival

Estimates of 40-week survival probabilities for male and female mice are shown in Table 4 and in the Kaplan-Meier survival curves (Figure 3). Survival of all exposed groups was similar to that of the control groups.

#### Body Weights, Feed and Compound Consumption, Organ Weights, and Clinical Findings

Mean body weights of exposed male and female mice were within 10% of those of the controls throughout the study (Figure 4; Tables 5 and 6). Feed consumption by exposed mice was generally similar to that by the controls throughout the study (Tables E1 and E2).

Concentrations of 100, 300, 1,000, 3,000, and 10,000 ppm in feed resulted in average daily doses of 12, 36, 120, 365, and 1,260 mg/kg to males and 14, 42, 140, 435, and 1,520 mg/kg to females. The absolute and relative liver weights of 10,000 ppm males were significantly less than those of the controls (Table C2). There were no exposure-related clinical findings.

TABLE 4 Survival of Heterozygous F1 p53^+/−^ Mice in the 40-Week Feed Study of Senna

| 0 ppm | 100 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
Animals initially in study | 25 | 25 | 25 | 25 | 25 | 25
Natural deaths | 0 | 1 | 0 | 0 | 2 | 1
Animals surviving to study termination | 25 | 24 | 25 | 25 | 23 | 24
Percent probability of survival at end of study^a^ | 100 | 96 | 100 | 100 | 92 | 96
Mean survival (days)^b^ | 276 | 274 | 276 | 276 | 275 | 266
Survival analysis^c^ | P=0.657 | P=1.000 | —^d^ | —^d^ | P=0.471 | P=1.000
Female
Animals initially in study | 25 | 25 | 25 | 25 | 25 | 25
Moribund | 2 | 2 | 2 | 2 | 2 | 1
Natural deaths | 0 | 0 | 0 | 1 | 1 | 0
Animals surviving to study termination | 23 | 23 | 23 | 22 | 22 | 24
Percent probability of survival at end of study | 92 | 92 | 92 | 88 | 88 | 96
Mean survival (days) | 273 | 272 | 272 | 267 | 261 | 275
Survival analysis | P=0.679N | P=1.000 | P=1.000 | P=0.940 | P=0.970 | P=0.991N

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice).

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

d Value of the statistic cannot be computed.

FIGURE 3 Kaplan-Meier Survival Curves for Heterozygous F1 p53^+/−^ Mice Exposed to Senna in Feed for 40 Weeks

FIGURE 4 Growth Curves for Heterozygous F1 p53^+/−^ Mice Exposed to Senna in Feed for 40 Weeks

TABLE 5 Mean Body Weights and Survival of Male Heterozygous F1 p53^+/−^ Mice in the 40-Week Feed Study of Senna

Days | 0 ppm | | 100 ppm | | | 300 ppm | | | 1,000 ppm | | | 3,000 ppm | | | 10,000 ppm
Days | Av. Wt (g) | No. of Survivors | Av. Wt (g) | Wt (% of) controls) | No. of Survivors | Av. Wt (g) | Wt (% of) controls) | No. of Survivors | Av. Wt (g) | Wt (% of) controls) | No. of Survivors | Av. Wt (g) | Wt (% of) controls) | No. of Survivors | Av. Wt (g) | Wt (% of) controls) | No. of Survivors
1 | 25.3 | 25 | 25.2 | 100 | 25 | 25.5 | 101 | 25 | 25.3 | 100 | 25 | 25.3 | 100 | 25 | 25.2 | 100 | 25
8 | 25.9 | 25 | 26.1 | 101 | 25 | 26.0 | 100 | 25 | 25.8 | 99 | 25 | 25.8 | 100 | 25 | 25.0 | 96 | 25
15 | 26.9 | 25 | 26.7 | 99 | 25 | 27.1 | 101 | 25 | 26.8 | 100 | 25 | 26.8 | 100 | 25 | 25.5 | 95 | 25
22 | 27.8 | 25 | 27.6 | 99 | 25 | 28.0 | 100 | 25 | 27.6 | 99 | 25 | 27.6 | 99 | 25 | 26.7 | 96 | 24
29 | 28.7 | 25 | 28.9 | 101 | 25 | 29.1 | 101 | 25 | 28.6 | 100 | 25 | 28.9 | 101 | 25 | 27.6 | 96 | 24
36 | 30.0 | 25 | 29.9 | 100 | 25 | 30.2 | 101 | 25 | 29.5 | 98 | 25 | 29.8 | 99 | 25 | 28.3 | 94 | 24
43 | 31.0 | 25 | 30.7 | 99 | 25 | 31.6 | 102 | 25 | 30.4 | 98 | 25 | 31.2 | 101 | 25 | 29.4 | 95 | 24
50 | 31.7 | 25 | 31.8 | 100 | 25 | 32.3 | 102 | 25 | 31.3 | 99 | 25 | 31.9 | 101 | 25 | 30.2 | 95 | 24
57 | 32.6 | 25 | 32.9 | 101 | 25 | 33.4 | 103 | 25 | 32.0 | 98 | 25 | 33.0 | 101 | 25 | 31.2 | 96 | 24
64 | 33.4 | 25 | 33.7 | 101 | 25 | 34.4 | 103 | 25 | 33.1 | 99 | 25 | 33.8 | 101 | 25 | 32.0 | 96 | 24
71 | 34.5 | 25 | 34.3 | 100 | 25 | 35.5 | 103 | 25 | 34.3 | 99 | 25 | 34.6 | 101 | 25 | 32.8 | 95 | 24
78 | 35.1 | 25 | 35.2 | 100 | 25 | 36.3 | 104 | 25 | 35.0 | 100 | 25 | 35.3 | 101 | 25 | 33.2 | 95 | 24
85 | 36.1 | 25 | 36.3 | 101 | 25 | 37.4 | 104 | 25 | 35.7 | 99 | 25 | 36.8 | 102 | 25 | 34.3 | 95 | 24
92 | 36.7 | 25 | 36.6 | 100 | 25 | 37.9 | 103 | 25 | 36.4 | 99 | 25 | 37.1 | 101 | 25 | 34.8 | 95 | 24
99 | 37.0 | 25 | 36.8 | 100 | 25 | 38.8 | 105 | 25 | 37.1 | 100 | 25 | 37.9 | 103 | 25 | 35.2 | 95 | 24
106 | 38.0 | 25 | 38.0 | 100 | 25 | 39.5 | 104 | 25 | 37.8 | 100 | 25 | 38.4 | 101 | 25 | 35.9 | 95 | 24
113 | 39.2 | 25 | 38.6 | 99 | 25 | 40.2 | 103 | 25 | 38.7 | 99 | 25 | 39.2 | 100 | 25 | 36.3 | 93 | 24
120 | 40.1 | 25 | 39.3 | 98 | 25 | 41.5 | 104 | 25 | 39.7 | 99 | 25 | 39.8 | 99 | 25 | 37.7 | 94 | 24
127 | 40.1 | 25 | 39.6 | 99 | 25 | 41.7 | 104 | 25 | 39.8 | 99 | 25 | 40.3 | 101 | 25 | 37.8 | 94 | 24
134 | 41.0 | 25 | 40.5 | 99 | 25 | 42.8 | 105 | 25 | 40.5 | 99 | 25 | 41.6 | 101 | 25 | 38.8 | 95 | 24
141 | 41.3 | 25 | 41.0 | 99 | 25 | 43.7 | 106 | 25 | 41.0 | 99 | 25 | 42.1 | 102 | 25 | 39.1 | 95 | 24
148 | 41.9 | 25 | 41.4 | 99 | 25 | 43.9 | 105 | 25 | 41.8 | 100 | 25 | 42.5 | 101 | 25 | 39.4 | 94 | 24
155 | 43.2 | 25 | 42.4 | 98 | 25 | 44.9 | 104 | 25 | 42.5 | 98 | 25 | 43.5 | 101 | 25 | 39.9 | 92 | 24
162 | 43.7 | 25 | 42.8 | 98 | 25 | 45.7 | 105 | 25 | 43.0 | 98 | 25 | 44.2 | 101 | 25 | 41.2 | 94 | 24
169 | 44.5 | 25 | 43.2 | 97 | 25 | 46.5 | 105 | 25 | 43.7 | 98 | 25 | 44.8 | 101 | 25 | 41.6 | 94 | 24
176 | 44.8 | 25 | 44.2 | 99 | 25 | 47.1 | 105 | 25 | 44.5 | 99 | 25 | 45.4 | 101 | 25 | 42.2 | 94 | 24
183 | 45.4 | 25 | 44.6 | 98 | 25 | 47.3 | 104 | 25 | 45.2 | 100 | 25 | 46.1 | 102 | 25 | 42.6 | 94 | 24
190 | 46.4 | 25 | 45.1 | 97 | 25 | 47.7 | 103 | 25 | 45.8 | 99 | 25 | 46.7 | 101 | 25 | 43.2 | 93 | 24
197 | 46.5 | 25 | 45.5 | 98 | 25 | 48.2 | 104 | 25 | 46.0 | 99 | 25 | 47.2 | 102 | 25 | 43.3 | 93 | 24
204 | 46.9 | 25 | 46.1 | 98 | 25 | 48.3 | 103 | 25 | 46.5 | 99 | 25 | 47.4 | 101 | 25 | 43.7 | 93 | 24
211 | 47.3 | 25 | 46.9 | 99 | 25 | 48.6 | 103 | 25 | 46.6 | 99 | 25 | 47.7 | 101 | 25 | 44.6 | 94 | 24
218 | 47.7 | 25 | 47.0 | 99 | 25 | 48.8 | 102 | 25 | 46.7 | 98 | 25 | 47.8 | 100 | 25 | 45.0 | 94 | 24
225 | 47.4 | 25 | 47.2 | 100 | 25 | 49.3 | 104 | 25 | 47.0 | 99 | 25 | 47.7 | 101 | 25 | 45.2 | 95 | 24
232 | 48.1 | 25 | 48.0 | 100 | 24 | 49.5 | 103 | 25 | 47.4 | 99 | 25 | 48.5 | 101 | 25 | 45.7 | 95 | 24
239 | 48.0 | 25 | 47.9 | 100 | 24 | 49.5 | 103 | 25 | 48.0 | 100 | 25 | 48.8 | 102 | 25 | 45.8 | 95 | 24
246 | 48.3 | 25 | 48.8 | 101 | 24 | 50.1 | 104 | 25 | 48.2 | 100 | 25 | 49.1 | 102 | 25 | 45.8 | 95 | 24
253 | 48.5 | 25 | 48.8 | 101 | 24 | 50.4 | 104 | 25 | 48.1 | 99 | 25 | 48.6 | 100 | 25 | 46.1 | 95 | 24
260 | 48.8 | 25 | 49.0 | 101 | 24 | 50.5 | 104 | 25 | 48.1 | 99 | 25 | 48.7 | 100 | 24 | 46.6 | 96 | 24
267 | 48.8 | 25 | 49.3 | 101 | 24 | 50.9 | 104 | 25 | 48.1 | 99 | 25 | 49.1 | 101 | 23 | 46.6 | 96 | 24
274 | 49.3 | 25 | 49.6 | 101 | 24 | 51.1 | 104 | 25 | 48.1 | 98 | 25 | 49.6 | 101 | 23 | 46.8 | 95 | 24
Mean for Weeks
1–13 | 30.7 | | 30.7 | 100 | | 31.3 | 102 | | 30.4 | 99 | | 30.8 | 101 | | 29.3 | 96
14–40 | 44.4 | | 44.0 | 99 | | 46.1 | 104 | | 43.9 | 99 | | 44.8 | 101 | | 41.9 | 94

TABLE 6 Mean Body Weights and Survival of Female Heterozygous F1 p53^+/−^ Mice in the 40-Week Feed Study of Senna

Days | 0 ppm | | 100 ppm | | | 300 ppm | | | 1,000 ppm | | | 3,000 ppm | | | 10,000 ppm
Days | Av. Wt (g) | No. of Survivors | Av. Wt (g) | Wt (% of) controls) | No. of Survivors | Av. Wt (g) | Wt (% of) controls) | No. of Survivors | Av. Wt (g) | Wt (% of) controls) | No. of Survivors | Av. Wt (g) | Wt (% of) controls) | No. of Survivors | Av. Wt (g) | Wt (% of) controls) | No. of Survivors
1 | 20.7 | 25 | 20.9 | 101 | 25 | 20.9 | 101 | 25 | 20.8 | 100 | 25 | 20.9 | 101 | 25 | 21.0 | 102 | 25
8 | 21.1 | 25 | 21.2 | 100 | 25 | 21.1 | 100 | 25 | 21.2 | 101 | 25 | 21.1 | 100 | 25 | 21.0 | 100 | 25
15 | 22.6 | 25 | 22.2 | 98 | 25 | 21.9 | 97 | 25 | 22.4 | 99 | 25 | 22.3 | 99 | 25 | 21.7 | 96 | 25
22 | 23.4 | 25 | 22.9 | 98 | 25 | 22.8 | 97 | 25 | 23.2 | 99 | 25 | 23.0 | 98 | 25 | 22.8 | 97 | 25
29 | 24.6 | 25 | 24.1 | 98 | 25 | 23.9 | 97 | 25 | 24.3 | 99 | 25 | 24.2 | 98 | 25 | 23.8 | 96 | 25
36 | 25.1 | 25 | 24.5 | 98 | 25 | 24.7 | 99 | 25 | 24.9 | 99 | 25 | 24.7 | 99 | 25 | 24.2 | 97 | 25
43 | 25.9 | 25 | 25.7 | 99 | 25 | 25.4 | 98 | 25 | 26.0 | 100 | 25 | 26.0 | 100 | 25 | 25.3 | 98 | 25
50 | 26.9 | 25 | 26.9 | 100 | 25 | 26.2 | 97 | 25 | 27.0 | 100 | 25 | 26.7 | 99 | 25 | 26.1 | 97 | 25
57 | 28.5 | 25 | 28.1 | 99 | 25 | 27.2 | 95 | 25 | 28.2 | 99 | 25 | 26.9 | 94 | 25 | 27.2 | 95 | 25
64 | 29.0 | 25 | 28.4 | 98 | 25 | 27.9 | 96 | 25 | 28.6 | 99 | 25 | 27.9 | 96 | 25 | 27.4 | 95 | 25
71 | 29.9 | 25 | 28.7 | 96 | 25 | 28.4 | 95 | 25 | 29.7 | 99 | 25 | 29.1 | 97 | 24 | 27.8 | 93 | 25
78 | 31.0 | 25 | 30.3 | 98 | 25 | 29.4 | 95 | 25 | 30.8 | 100 | 25 | 29.8 | 96 | 24 | 28.8 | 93 | 25
85 | 31.3 | 25 | 31.2 | 100 | 25 | 30.3 | 97 | 25 | 31.3 | 100 | 25 | 30.9 | 99 | 24 | 29.4 | 94 | 25
92 | 32.0 | 25 | 31.5 | 98 | 25 | 30.5 | 95 | 25 | 32.2 | 101 | 25 | 31.7 | 99 | 24 | 30.5 | 95 | 25
99 | 32.5 | 25 | 31.6 | 97 | 25 | 31.1 | 96 | 25 | 32.6 | 100 | 25 | 31.8 | 98 | 24 | 30.6 | 94 | 25
106 | 33.5 | 25 | 32.6 | 97 | 25 | 31.7 | 95 | 25 | 33.2 | 99 | 25 | 32.3 | 96 | 24 | 30.8 | 92 | 25
113 | 33.8 | 25 | 32.9 | 98 | 25 | 32.0 | 95 | 25 | 33.5 | 99 | 25 | 32.3 | 96 | 24 | 31.2 | 92 | 25
120 | 34.6 | 25 | 34.0 | 98 | 25 | 32.7 | 95 | 25 | 34.4 | 100 | 25 | 32.8 | 95 | 24 | 31.8 | 92 | 25
127 | 34.8 | 25 | 34.1 | 98 | 25 | 33.3 | 96 | 25 | 34.9 | 100 | 25 | 33.5 | 96 | 24 | 32.0 | 92 | 25
134 | 35.4 | 25 | 34.5 | 98 | 25 | 33.2 | 94 | 25 | 35.0 | 99 | 25 | 34.1 | 96 | 24 | 32.9 | 93 | 25
141 | 35.9 | 25 | 35.0 | 98 | 25 | 34.1 | 95 | 25 | 35.4 | 99 | 25 | 34.3 | 96 | 23 | 32.9 | 92 | 25
148 | 36.4 | 25 | 35.9 | 99 | 25 | 34.7 | 95 | 25 | 36.2 | 100 | 25 | 34.8 | 96 | 23 | 33.7 | 93 | 25
155 | 36.8 | 25 | 36.7 | 100 | 25 | 35.2 | 96 | 25 | 36.7 | 100 | 25 | 35.2 | 96 | 23 | 34.3 | 93 | 25
162 | 37.2 | 25 | 37.2 | 100 | 25 | 35.6 | 96 | 25 | 36.8 | 99 | 25 | 35.1 | 94 | 23 | 34.9 | 94 | 25
169 | 38.1 | 25 | 37.7 | 99 | 25 | 36.1 | 95 | 25 | 37.6 | 99 | 25 | 35.6 | 93 | 23 | 34.8 | 91 | 25
176 | 38.3 | 25 | 38.4 | 100 | 25 | 36.8 | 96 | 25 | 37.6 | 98 | 25 | 36.8 | 96 | 23 | 35.8 | 93 | 25
183 | 38.4 | 25 | 38.9 | 101 | 25 | 37.8 | 98 | 25 | 38.2 | 99 | 25 | 37.3 | 97 | 23 | 35.8 | 93 | 25
190 | 38.6 | 25 | 38.7 | 100 | 25 | 37.0 | 96 | 25 | 38.5 | 100 | 25 | 37.4 | 97 | 23 | 36.0 | 93 | 25
197 | 38.7 | 25 | 39.0 | 101 | 25 | 37.2 | 96 | 25 | 38.9 | 101 | 25 | 38.1 | 99 | 23 | 36.5 | 94 | 25
204 | 38.4 | 25 | 38.9 | 101 | 25 | 37.2 | 97 | 25 | 38.8 | 101 | 24 | 37.9 | 99 | 23 | 36.5 | 95 | 25
211 | 38.8 | 25 | 39.2 | 101 | 25 | 37.0 | 96 | 25 | 38.9 | 100 | 23 | 38.2 | 99 | 23 | 36.9 | 95 | 25
218 | 39.4 | 25 | 39.2 | 99 | 25 | 37.8 | 96 | 25 | 39.2 | 100 | 23 | 38.9 | 99 | 23 | 37.6 | 95 | 25
225 | 40.3 | 24 | 39.5 | 98 | 24 | 37.7 | 94 | 25 | 39.9 | 99 | 22 | 38.8 | 97 | 23 | 37.5 | 93 | 25
232 | 40.8 | 24 | 40.5 | 99 | 24 | 38.5 | 94 | 24 | 40.0 | 98 | 22 | 39.3 | 96 | 23 | 38.0 | 93 | 25
239 | 41.4 | 24 | 40.3 | 97 | 24 | 38.4 | 93 | 24 | 40.3 | 97 | 22 | 39.5 | 95 | 23 | 38.5 | 93 | 25
246 | 41.1 | 24 | 40.7 | 99 | 24 | 39.1 | 95 | 23 | 40.2 | 98 | 22 | 39.9 | 97 | 23 | 38.6 | 94 | 25
253 | 41.8 | 24 | 40.5 | 97 | 24 | 39.2 | 94 | 23 | 40.1 | 96 | 22 | 39.9 | 96 | 23 | 38.5 | 92 | 25
260 | 42.2 | 24 | 40.3 | 96 | 24 | 39.7 | 94 | 23 | 40.5 | 96 | 22 | 40.1 | 95 | 23 | 38.5 | 91 | 25
267 | 42.4 | 23 | 41.1 | 97 | 23 | 39.6 | 94 | 23 | 40.8 | 96 | 22 | 39.6 | 94 | 23 | 38.6 | 91 | 24
274 | 41.8 | 23 | 41.2 | 99 | 23 | 40.1 | 96 | 23 | 41.3 | 99 | 22 | 40.6 | 97 | 22 | 38.9 | 93 | 24
Mean for Weeks
1–13 | 26.2 | | 25.8 | 99 | | 25.4 | 97 | | 26.0 | 100 | | 25.7 | 98 | | 25.1 | 96
14–40 | 37.9 | | 37.4 | 99 | | 36.0 | 95 | | 37.5 | 99 | | 36.5 | 96 | | 35.3 | 93

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of bone and liver neoplasms and nonneoplastic lesions of the large intestine. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Appendix A for male and female mice. Historical control incidences for neoplasms in heterozygous F1 p53^+/−^ mice are shown in Appendix F.

Large Intestine: Significant increases in the incidences of epithelial hyperplasia of the colon and cecum occurred in 10,000 ppm males and females, and the incidence of hyperplasia of the colon was significantly increased in 3,000 ppm females (Tables 7, A2, and A4). Three 3,000 ppm males had epithelial hyperplasia of the colon and single occurrences of epithelial hyperplasia of the rectum were recorded in the 10,000 ppm males and females; although lacking statistical significance, these lesions are considered biologically noteworthy.

Epithelial hyperplasia of the colon, cecum, and rectum (Plates 3 through 8) was similar in character to that observed in C57BL/6NTac mice exposed to senna for 5 weeks. The changes were characterized by a thickening of the mucosa by a lengthening of the crypts. This was due to increased numbers of epithelial cells that appeared crowded together. These cells were small and had basophilic cytoplasm and round to oval nuclei, which became more vesicular toward the luminal surface of the glands. Goblet cells were interspersed with these cells, but did not constitute an increased proportion of the epithelial cells in the colon or cecum. Mitotic figures were numerous. The cecum was usually less severely affected than the colon.

Normal crypt depth in controls was up to 175 µm. Hyperplasia of the colon was graded based upon crypt depth, as follows: in minimal (grade 1) hyperplasia, crypt depth was approximately 200 µm (from basement membrane to surface of crypt epithelium, measured where an entire crypt was in longitudinal section), but only focally or multifocally; in mild (grade 2) hyperplasia, crypt depth was greater than or equal to 200 µm over much of the circumference, and was focally approximately 300 to 350 µm; in moderate (grade 3) hyperplasia almost the entire circumference of the section examined was involved with crypts 300 to 350 µm deep. Lesions severe enough to be recorded as marked (grade 4) hyperplasia were not observed. Due to the naturally thinner mucosa of the cecum and the naturally thicker mucosa found in the rectum, the same criteria for diagnosis used for the colon could not be applied; severity grading for the cecum and rectum was done more subjectively.

TABLE 7 Incidences of Hyperplasia in the Large Intestine in Heterozygous F1 p53^+/−^ Mice in the 40-Week Feed Study of Senna

| 0 ppm | 100 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
Cecum^a^ | 25 | 25 | 25 | 25 | 23 | 25
Epithelium, hyperplasia^b^ | 0 | 0 | 0 | 0 | 0 | 22^**^ (1.4)^c^
Colon | 25 | 25 | 25 | 25 | 24 | 25
Epithelium, hyperplasia | 0 | 0 | 0 | 0 | 3 (1.3) | 25^**^ (2.8)
Rectum | 24 | 25 | 25 | 25 | 24 | 25
Epithelium, hyperplasia | 0 | 0 | 0 | 0 | 0 | 1 (2.0)
Female
Cecum | 25 | 25 | 25 | 25 | 25 | 25
Epithelium, hyperplasia | 0 | 0 | 0 | 0 | 0 | 19^**^ (1.3)
Colon | 25 | 25 | 25 | 25 | 25 | 25
Epithelium, hyperplasia | 0 | 0 | 0 | 0 | 7^**^ (1.0) | 25^**^ (2.7)
Rectum | 25 | 25 | 25 | 25 | 25 | 25
Epithelium, hyperplasia | 0 | 0 | 0 | 0 | 0 | 1 (10)

** Significantly different (P≤0.01) from the control group by the Fisher exact test.

a Number of animals with tissue examined microscopically

b Number of animals with lesion

c Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

Bone: Osteosarcomas occurred in 1,000 and 3,000 ppm males but not in the control group; the incidences in these groups were within the historical control range (Tables 8, A1, and F1). In 1,000 ppm females, the incidence of osteosarcoma was greater than the historical control range but not significantly greater than the incidence in the concurrent control group (Tables 8, A3, and F2). Given that there was not a dose response and the incidences were generally within the historical and/or concurrent control ranges, the osteosarcomas were not considered to be related to senna exposure.

Liver: The incidence of hepatocellular adenoma in 300 ppm males was increased, but not significantly, and exceeded the historical control range (Tables 9, A1, and F1). The biological relevance of this finding is unknown.

## Genetic Toxicology

Four different samples of senna, including three samples of the same lot that was used in the 40-week mouse study, were tested for mutagenicity in bacterial test systems (Tables B1 and B2). The first sample produced a weak response in Salmonella typhimurium strain TA100 at high concentrations in the presence of induced rat or hamster liver S9. In strain TA98, significant increases in mutant colonies were seen with high concentrations of this senna sample in the presence of hamster or rat liver S9 mix. The second sample, from the same lot of senna used in the 40-week mouse study, was not mutagenic at concentrations up to 10,000 µg/plate, with or without S9, in S. typhimurium strains TA97, TA98, TA100, or TA1535; two trials, one in TA100 without S9 and one in TA98 with 10% hamster liver S9 gave equivocal responses that were not reproduced in the replicate trial. The third and fourth samples were also from the same lot of senna that was used in the 40-week mouse study. The third sample was tested only to a maximum concentration of 250 µg/plate; no evidence of mutagenicity was observed over this dose range, with or without S9, in any bacterial strain. The fourth sample was tested up to a concentration of 6,000 µg/plate; significant increases in mutant colonies were observed in TA100 with rat liver S9 and in TA98 with and without rat liver S9. Significant increases were seen at lower concentrations in the tests conducted with the fourth sample of senna in the presence of S9. Overall, there is a general lack of reproducibility in the mutagenic activity observed among different lots of senna.

TABLE 8 Incidences of Bone Neoplasms in Heterozygous F1 p53^+/−^ Mice in the 40-Week Feed Study of Senna

| 0 ppm | 100 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
Number examined microscopically | 25 | 25 | 25 | 25 | 25 | 25
Femur, osteoma | 0 | 0 | 1 (4%) | 0 | 0 | 0
Maxilla, osteosarcoma | 0 | 0 | 0 | 3 (12%) | 1 (4%) | 0
Vertebra, osteosarcoma | 0 | 0 | 0 | 0 | 1 (4%) | 0
Osteoma or osteosarcoma^a^ | 0 | 0 | 1 (4%) | 3 (12%) | 2 (8%) | 0
Female
Number examined microscopically | 25 | 25 | 25 | 25 | 25 | 25
Osteosarcoma (site not specified) | 0 | 0 | 0 | 0 | 0 | 1 (4%)
Femur, osteosarcoma | 0 | 0 | 0 | 0 | 0 | 1 (4%)
Maxilla, osteosarcoma | 0 | 1 (4%) | 0 | 1 (4%) | 0 | 0
Rib, osteosarcoma | 1 (4%) | 0 | 0 | 0 | 0 | 0
Tibia, osteosarcoma | 0 | 1 (4%) | 0 | 0 | 0 | 0
Vertebra, osteosarcoma | 1 (4%) | 0 | 1 (4%) | 2 (8%) | 0 | 0
Osteosarcoma^b^ | 2 (8%) | 2 (8%) | 1 (4%) | 3 (12%) | 0 | 2 (8%)

a Historical incidence for control groups in 9-month heterozygous F1 p53^+/−^ mouse studies: 5/77, range 0%-12%

b Historical incidence for control groups in 9-month heterozygous F1 p53^+/−^ mouse studies: 3/76, range 0%-8%

TABLE 9 Incidences of Hepatocellular Adenoma in Heterozygous F1 p53^+/−^ Male Mice in the 40-Week Feed Study of Senna

| 0 ppm | 100 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Hepatocellular Adenoma^a^
Overall rate^b^ | 1/25 (4%) | 0/25 (0%) | 5/25 (20%) | 0/25 (0%) | 2/25 (8%) | 1/25 (4%)
Terminal rate^c^ | 1/25 (4%) | 0/24 (0%) | 5/25 (20%) | 0/25 (0%) | 2/23 (9%) | 1/24 (4%)
First incidence (days) | 276 (T) | —^e^ | 276 (T) | — | 276 (T) | 276 (T)
Statistical analysis^d^ | P=0.477N | P=0.500N | P=0.095 | P=0.500N | P=0.500 | P=0.755N

(T)Terminal sacrifice

a Historical incidence for control groups in 9-month heterozygous F1 p53^+/−^ mouse studies: 5/76, range 4%-12%

b Number of animals with lesion per number of animals with liver examined microscopically

c Observed incidence at terminal kill

d The result of the Cochran-Armitage trend test (Armitage, 1971) is in the control column, and the results of the Fisher exact pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns. A negative trend or a lower incidence in an exposure group is indicated by N.

e Not applicable; no lesions in animal group

In addition to senna, the NTP also tested rhein (a component of senna) for mutagenicity in S. typhimurium strains TA98 and TA100; dose-related increases in mutant colonies were seen with both strains in the presence of rat or hamster liver S9 and at lower concentrations (approximately 100 to 166 µg/plate) than were required for the positive responses seen with senna samples (Table B3). Another component of senna, chrysophanic acid, was tested for mutagenicity in TA98, TA100, and TA1535; weak and inconsistent responses were seen in TA100 with rat and hamster liver S9 (Table B4). Sennosides A and B (up to 6,000 µg/plate) were also tested for mutagenicity in bacterial test systems; neither compound was mutagenic, with or without S9 metabolic activation, in S. typhimurium strains TA98 or TA100, or Escherichia coli strain WP2 uvrA/pKM101 (Tables B5 and B6).

In vivo, no significant increases in the frequencies of micronucleated reticulocytes (polychromatic erythrocytes; PCEs) or erythrocytes (normochromatic erythrocytes, NCEs) were seen in male mice exposed to senna (100 to 10,000 ppm) in dosed feed for 40 weeks (Table B7). Although the trend test was significant (P=0.016), the increase in micronucleated NCEs seen at the highest dose was small (less than 0.2 micronucleated cells per 1,000), no treatment groups were significantly elevated over the control group, and the frequency of micronucleated PCEs in the high dose group was not increased over the control. Furthermore, there was no dose-related increase in micronucleated PCEs (trend test P=0.825). Therefore, senna was judged to be negative in the erythrocyte micronucleus test. No significant changes in the percentage of PCEs among erythrocytes were observed in male mice suggesting that exposure to senna did not induce bone marrow toxicity.

PLATE 1 Colon from a control female C57BL/6NTac mouse in the 5-week feed study of senna

Plates 1 and 2 were taken at the same magnification. H&E

PLATE 2 Epithelial hyperplasia (grade 3) in the colon from a female C57BL/6NTac mouse exposed to 10,000 ppm senna in feed for 5 weeks

The lengths of the crypts and numbers of epithelial cells are increased, as evidenced by crowding, increased basophilia, and increased mitoses. H&E

PLATE 3 Colon from a control male heterozygous F1 p53^+/−^ mouse in the 40-week feed study of senna

Plates 3 and 4 were taken at the same magnification. H&E

PLATE 4 Moderate epithelial hyperplasia (grade 3) in the colon from a male heterozygous F1 p53^+/−^ mouse exposed to 10,000 ppm senna in feed for 40 weeks

H&E

PLATE 5 Colon of a control male heterozygous F1 p53^+/−^ mouse in the 40-week feed study of senna

H&E

PLATE 6 Moderate (grade 3) epithelial hyperplasia in the colon of a male heterozygous F1 p53^+/−^ mouse exposed to 10,000 ppm senna in feed for 40 weeks

The epithelium is thickened as evidenced by increased distance from the luminal surface to the base of the crypts. Epithelial cells are increased in number and are basophilic and crowded; the cells lack the orderly arrangement seen in the control mouse colon shown in Plate 5. There are numerous mitotic figures (arrows). H&E

PLATE 7 Cecum of a control male heterozygous F1 p53^+/−^ mouse in the 40-week feed study of senna

Plates 7 and 8 were taken at the same magnification. H&E

PLATE 8 Moderate hyperplasia (grade 3) in the cecum of a male heterozygous F1 p53^+/−^ mouse exposed to 10,000 ppm senna in feed for 40 weeks

H&E