# MATERIALS AND METHODS

## Procurement and Characterization of Senna

Senna was obtained from Madaus AG (Köln, Germany) in one lot (1999000). Identity and purity analyses were conducted by the analytical chemistry laboratory at Research Triangle Institute (Research Triangle Park, NC) and the study laboratory at Battelle Columbus Operations (Columbus, OH) (Appendix D). Reports on analyses performed in support of the senna studies are on file at the National Institute of Environmental Health Sciences.

The chemical, a brown, powdered raw plant material, was identified as senna using two similar high-performance liquid chromatography with ultraviolet detection (HPLC/UV) analytical systems. The bulk test material was characterized as a multi-component natural product with a complex mixture of constituents that were confirmed by identifying as many components as possible in methanol:water (50:50) extracts of the raw material. Chromatographic comparisons were made to purchased reference standard solutions of sennosides A and B, sennidins A and B, aloe-emodin, emodin, rhein, aloe-emodin-8-glucoside, chrysophanic acid, and physcione in the same solvent. In a parallel study conducted by the analytical chemistry laboratory, nine additional reference standards that assisted in identifying constituents in lot 1999000 were isolated and identified in methanol:water (50:50) extracts of a lot of senna obtained from Frontier Natural Products Co-op (Norway, IA). Forty-seven components with a peak area of at least 0.1% of the total peak area were observed in lot 1999000, accounting for 99.6% of the total peak area for the test material extract. Of these 47, 18 were considered major components (≥ 1% each). By comparison to the chromatographic profiles of the purchased and isolated reference standards, peaks were confirmed in lot 1999000 for sennosides A and B, sennidins A and B, rhein, aloe-emodin, quercetin 3-gentiobioside, kaempferol 3-gentiobioside, torachrysone-8-O-ß-D-glucopyranoside, quercetin, and torachrysone. Weight percentages of four postulated active components in the test article were estimated to be: 0.7% sennoside A, 1.3% sennoside B, 0.06% sennidin A, and 0.03% sennidin B. The identities of the marker compounds sennoside A and sennoside B in lot 1999000 were confirmed using resolution standard solutions of these chemicals in methanol:water (50:50).

The water content of lot 1999000 was determined by weight loss on drying and by Karl Fischer titration. The bulk purity of the test material was determined using broad gradient HPLC/UV with monitoring at 210 and 270 nm. Broad screening assays for residual volatiles were conducted on dimethylsulfoxide extracts of the test material using gas chromatography (GC) with flame ionization detection. Nutritional testing, trace metals screening, nitrosamines assays, and pesticide screening were performed on the bulk material using standard methods.

For lot 1999000, moisture content was determined to be 6.0% (w/w) by weight loss on drying and 5.8% by weight by Karl Fischer titration. Broad gradient HPLC/UV analyses with monitoring at 210 or 270 nm each detected 13 major (≥1% of the total peak areas) components accounting for 91% of the total peak areas and 25 minor (<1%) components. GC for residual volatiles detected methanol and isopropanol, both at levels below their estimated limits of quantitation (0.1% and 0.09% by weight, respectively), and a single unknown. Organochlorine and organophophorus pesticide levels were below the detection limits of 200 and 50 ppb, respectively. Mercury, thallium, and cadmium levels were less than the limits of detection, which were respectively 25, 20, and 500 ppb. Lead and selenium were present at 299 and 690 ppb, respectively. Nitrosamines were not present above the detection limit of 1.0 ppb. Results of the nutritional and contaminant tests were deemed acceptable for use in these studies.

Lot 1999000 was sterilized by exposure to cobalt-60. The irradiation procedure was performed by Neutron Products, Inc. (Dickerson, MD). Comparison of the irradiated material with the nonirradiated material indicated that all 10 major peaks present in the nonirradiated material were present in the irradiated material at a relative concentration of ≥ 90.7%. Examination of the chromatograms before and after indicated that no new significant peaks appeared after irradiation.

To ensure stability, the bulk chemical was stored at approximately 5° C in a sealed plastic bag inside a 6-gallon metal pail (5-week study) or in amber glass bottles (40-week study). All transferring and handling of the study material was done under yellow lights. Periodic reanalyses of the bulk chemical were performed during the 5- and 40-week studies using HPLC/UV, and no degradation of the test material was detected.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared once by mixing senna with feed (Table D2). Using HPLC/UV, homogeneity and stability studies of the 300 and 10,000 ppm dose formulations were performed by the analytical chemistry laboratory and homogeneity studies of the 625 and 10,000 ppm dose formulations were performed by the study laboratory. Homogeneity and stability studies of the 100 ppm dose formulation were performed by the study laboratory using HPLC with mass spectrometry (MS) detection. Homogeneity was confirmed and the stability of the dose formulations was confirmed for at least 42 days when stored in sealed containers, protected from light.

Periodic analyses of the dose formulations of senna (quantitating sennoside A as the analytical marker) were conducted by the study laboratory using HPLC/UV (5-week study) or HPLC/MS/MS (40-week study). During the 5-week study, the dose formulations were analyzed once, and all five dose formulations were within 10% of the target concentrations (Table D5). Animal room samples of these dose formulations were also analyzed, and four of five were within 10% of the target concentrations. During the 40-week study, the dose formulations were analyzed five times; animal room samples were also analyzed (Table D6). Of the dose formulations analyzed, 33 of 50 were within 10% of the target concentrations; four of 10 animal room samples were within 10% of the target concentrations.

## 5-Week Study in C57BL/6NTac Mice

Male and female C57BL/6NTac mice were obtained from Taconic Farms, Inc. (Germantown, NY). On receipt, the mice were 4 to 5 weeks old. Animals were quarantined for 13 days and were 6 to 7 weeks old on the first day of the study. Before the study began, three male and two female mice were randomly selected for parasite evaluation and gross observation for evidence of disease. At the end of the study, blood samples were collected from five male and five female sentinel mice. The sera were analyzed for antibody titers to rodent viruses (Boorman et al., 1986; Rao et al., 1989a,b). All results were negative.

The oral route of administration was selected to mimic oral exposures in humans taking senna in laxative preparations. Because senna is taken several times a day in laxative preparations, feed was selected as the route of administration to mimic human exposures. A dose of 10,000 ppm senna was selected as the maximum dose in the 5-week study, a dose expected to deliver daily doses that overlapped those used in the 13-week and 2-year senna rat studies (Mengs et al., 2004; Mitchell et al., 2006). The doses of 625, 1,250, 2,500, 5,000, and 10,000 ppm included a low dose estimated to deliver a dose similar to human exposure levels to a high dose estimated to be near a maximum tolerated dose for repeated exposure.

Groups of five male and five female mice were fed diets containing 0, 625, 1,250, 2,500, 5,000, or 10,000 ppm senna for 29 days. Feed and water were available ad libitum. Mice were housed individually. Clinical findings were recorded weekly. Feed consumption was recorded weekly by animal. The animals were weighed initially, weekly, and at the end of the study. Details of the study design and animal maintenance are summarized in Table 1.

Necropsies were performed on all study animals. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Histopathologic examinations were performed on all mice. Table 1 lists the tissues and organs examined.

## 40-Week Study in Heterozygous F1 p53^+/−^ Mice

Male and female heterozygous F1 p53^+/−^ mice were obtained from Taconic Farms, Inc. (Germantown, NY). On receipt, the mice were 5 to 7 weeks old. Animals were quarantined for 6 or 7 days and were 6 to 8 weeks old on the first day of the study. At the end of the quarantine period, serum samples for viral titer testing were collected from five male and five female mice randomly selected for parasite evaluation and gross observation for evidence of disease. Blood samples were collected from five male and five female sentinel mice 4 weeks after the start of the study and from five additional sentinel males and females at the end of the study and analyzed for antibody titers to rodent viruses. All results were negative.

Groups of 25 male and 25 female mice were fed diets containing 0, 100, 300, 1,000, 3,000, or 10,000 ppm senna for 40 weeks. Feed and water were available ad libitum. Mice were housed individually. Clinical findings were recorded weekly and at study termination. Feed consumption was recorded weekly by animal. The animals were weighed initially, weekly, and at the end of the study. Details of the study design and animal maintenance are summarized in Table 1.

Necropsies were performed on all animals. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed on all mice. Table 1 lists the tissues and organs routinely examined.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 40-week studies, a quality assessment pathologist evaluated slides from all tumors and all potential target organs, which included the cecum, colon, and rectum.

The quality assessment report and the reviewed slides were submitted to the NTP PWG coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and quality assessment pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and quality assessment pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the quality assessment pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups or previously rendered diagnoses. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman (1982) and Boorman et al. (1985). For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al. (1986).

TABLE 1 Experimental Design and Materials and Methods in the Feed Studies of Senna

5-Week Study | 40-Week Study
Study Laboratory
Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH)
Strain and Species
C57BL/6NTac mice | Heterozygous F1 p53^+/−^ mice
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
13 days | 6 (females) or 7 (males) days
Average Age When Studies Began
6 to 7 weeks | 6 to 8 weeks
Date of First Exposure
October 12, 2005 | June 25 (females) or 26 (males), 2007
Duration of Exposure
5 weeks | 40 weeks
Date of Last Exposure
November 9, 2005 | March 25–26 (females) or 27–28 (males), 2008
Necropsy Dates
November 9, 2005 | March 25–26 (females) or 27–28 (males), 2008
Average Age at Necropsy
10 to 11 weeks | 45 to 48 weeks
Size of Study Groups
5 males and 5 females | 25 males and 25 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 5-week study
Animals per Cage
1 | 1
Method of Animal Identification
Tail tattoo | Tail tattoo
Diet
Irradiated NTP-2000 open formula meal diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly | Same as 5-week study
Water
Tap water (Columbus municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum | Same as 5-week study
Cages
Polycarbonate (Lab Products, Inc., Seaford, DE), changed weekly | Same as 5-week study
Bedding
Irradiated Sani-Chips^®^ (P.J. Murphy Forest Products Corp., Montville, NJ), changed weekly | Same as 5-week study
Rack Filters
Spun-bonded polyester (Snow Filtration Co., Cincinnati, OH), changed every 2 weeks | Same as 5-week study
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed every 2 weeks | Same as 5-week study
Animal Room Environment
Temperature: 72° ± 3° F | Temperature: 72° ± 3° F
Relative humidity: 50% ± 15% | Relative humidity: 50% ± 15%
Room fluorescent light: 12 hours/day | Room fluorescent light: 12 hours/day
Room air changes: at least 10/hour | Room air changes: at least 10/hour
Exposure Concentrations
0, 625, 1,250, 2,500, 5,000, or 10,000 ppm in feed, available ad libitum | 0, 100, 300, 1,000, 3,000, or 10,000 ppm in feed, available ad libitum
Type and Frequency of Observation
Observed twice daily; animals were weighed initially, weekly, and at the end of the study; clinical findings were recorded weekly. Feed consumption was recorded weekly by animal. | Observed twice daily; animals were weighed initially, weekly, and at the end of the study; clinical findings were recorded weekly and at the end of the study. Feed consumption was recorded weekly by animal.
Method of Sacrifice
Carbon dioxide asphyxiation | Same as 5-week study
Necropsy
Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus | Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus
Histopathology
Histopathology was performed on all mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular, mediastinal, and mesenteric), ovary, pituitary gland, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, urinary bladder, and uterus. | Complete histopathology was performed on all mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, gallbladder, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis and seminal vesicle, thymus, thyroid gland, trachea, urinary bladder, and uterus.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier (1958) and is presented in the form of graphs. Animals found dead of other than natural causes were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s (1972) method for testing two groups for equality and Tarone’s (1975) life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation and Analysis of Lesion Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Tables A1, A2, A3, and A4 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test (Gart et al., 1979) and the Cochran-Armitage trend test (Armitage, 1971), procedures based on the overall proportion of affected animals, were used to determine significance.

### Analysis of Continuous Variables

Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett (1955) and Williams (1971, 1972).

## Quality Assurance Methods

The 40-week study was conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations (21 CFR, Part 58). In addition, as records from the 40-week study were submitted to the NTP Archives, this study was audited retrospectively by an independent quality assurance contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Report.

## Genetic Toxicology

### Bacterial Mutagenicity Test Protocol

Testing procedures used for senna at SRI International and BioReliance Corporation and for rhein and chrysophanic acid followed protocols reported by Zeiger et al. (1992); the remaining tests for senna and for sennosides A and B used a slightly modified procedure as described below. Senna, rhein, and chrysophanic acid were tested as coded samples. Test samples were incubated with two or more Salmonella typhimurium tester strains (TA97, TA98, TA100, and/or TA1535) either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague-Dawley rat or Syrian hamster liver) for 20 minutes at 37º C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following 2 days incubation at 37º C.

The protocol used for senna at SITEK Research Laboratories and ILS, Inc., and for sennosides A and B used only 10% rat liver S9 for exogenous metabolic activation and employed Escherichia coli strain WP2 uvrA/pKM101 as a bacterial tester strain in addition to S. typhimurium strains TA98 and TA100. Incubation of bacterial strains with coded senna and sennosides A and B samples and subsequent plating were carried out as described above.

For all tests, each trial consisted of triplicate plates of concurrent positive and negative controls and of at least five doses of test compound. In senna tests where no toxicity was observed, a high dose of 10,000 to 16,666 µg/plate was used. The lot of senna used in the 40-week study was tested to a maximum concentration of 10,000 µg/plate in one assay (sample 2), 250 µg/plate a second assay (sample three), and 6,000 µg/plate in the third assay (sample four). Rhein and chrysophanic acid were limited by toxicity to 666 µg/plate. Sennosides A and B were tested up to 6,000 µg/plate.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose-related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive.

### Mouse Peripheral Blood Micronucleus Protocol

The procedures used for the mouse peripheral blood micronucleus assay are described in detail by Dertinger et al. (2004) and Witt et al. (2008). Briefly, at the termination of the 40-week study of senna, one to two drops of blood from male and female mice were collected in microtubes with EDTA and shipped on ice to the genetic toxicity testing laboratory for processing and fixation in ultracold methanol, as per procedures described in the MicroFlow BASIC kit for mouse blood samples (Litron Laboratories, Rochester, NY). Upon arrival at the laboratory, it was discovered that the blood samples from the female mice had frozen during transport and were not amenable to analysis. A FACSCalibur flow cytometer (Becton Dickinson, San Jose, CA) was used to carry out the analyses of the samples from male mice. Reticulocytes (polychromatic erythrocytes, PCEs) were identified by the presence of an active transferrin receptor (CD71+) on the cell surface and mature erythrocytes (normochromatic erythrocytes, NCEs) were CD71-negative (CD71–). Micronuclei were detected using propidium iodide (a DNA stain) in conjunction with RNase treatment. Approximately 1 × 10^6^ erythrocytes and 20,000 reticulocytes were evaluated per male mouse for the presence of micronuclei (propidium iodide-associated fluorescence). In addition, for each blood sample, the percentage of reticulocytes in 1 × 10^6^ erythrocytes was determined as a measure of bone marrow toxicity.

Based on prior experience with the large number of cells scored using flow cytometric scoring techniques (Kissling et al., 2007), it is reasonable to assume that the proportion of micronucleated reticulocytes is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the control group depend on whether the variances among the groups are equal. Levene’s test at α=0.05 is used to test for equal variances. In the case of equal variances, linear regression is used to test for a linear trend with dose and Williams’ test is used to test for pairwise differences between each treatment group and the control group. In the case of unequal variances, Jonckheere’s test is used to test for linear trend and Dunn’s test is used for pairwise comparisons of each treatment group with the control group. To correct for multiple pairwise comparisons, the P value for each comparison with the control group is multiplied by the number of comparisons made. In the event that this product is greater than 1.00, it is replaced with 1.00. Trend tests and pairwise comparisons with the controls are considered statistically significant at P=0.025.

Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed, and the magnitudes of those effects.

### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the NTP. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple aliquots of a chemical were tested in the same assay and different results were obtained among aliquots and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Report presents a result that represents a scientific judgment of the overall evidence for activity of the chemical in an assay.