# APPENDIX H SENTINEL ANIMAL PROGRAM

## Methods

Rodents used in the Carcinogenesis Program of the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of chemical compounds. Under this program, the disease state of the rodents is monitored via serology on sera from extra (sentinel) animals in the study rooms. These animals and the study animals are subject to identical environmental conditions. The sentinel animals come from the same production source and weanling groups as the animals used for the studies of chemical compounds.

In the 5-week study, serum samples were collected from five male and five female sentinel mice at the end of the study. In the 40-week study, serum samples were collected from five male and five female sentinel mice at 1 month and from an additional five male and five female mice at the end of the study. Blood from each animal was collected and allowed to clot, and the serum was separated. The samples were processed appropriately and sent to BioReliance Corporation (Rockville, MD) for determination of antibody titers. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

[underlined: Method and Test] | [underlined: Time of Collection]
MICE
5-Week Study
ELISA
Ectromelia virus | Study termination
EDIM (epizootic diarrhea of infant mice) | Study termination
GDVII (mouse encephalomyelitis virus) | Study termination
LCM (lymphocytic choriomeningitis virus) | Study termination
Mouse adenoma virus-1 | Study termination
MHV (mouse hepatitis virus) | Study termination
MMV VP2 (mouse minute virus, viral protein 2) | Study termination
MPV VP2 (mouse parvovirus, viral protein 2) | Study termination
PVM (pneumonia virus of mice) | Study termination
Reovirus 3 | Study termination
Sendai | Study termination
Immunofluorescence Assay
Parvovirus | Study termination
40-Week Study
ELISA
Ectromelia virus | 1 month
EDIM | 1 month
GDVII | 1 month
LCM | 1 month
Mouse adenoma virus-1 | 1 month
MHV | 1 month
MMV | 1 month
MPV | 1 month
PVM | 1 month
Reovirus 3 | 1 month
Sendai | 1 month
Immunofluorescence Assay
MMV | 1 month
Multiplex Flourescent Immunoassay
Ectromelia virus | Study termination
EDIM | Study termination
GDVII | Study termination
LCM | Study termination
MHV | Study termination
MMV | Study termination
MNV (mouse norovirus) | Study termination
MPV | Study termination
Mycoplasma pulmonis | Study termination
Parvovirus NS-1 | Study termination
PVM | Study termination
Reovirus 3 | Study termination
Sendai | Study termination

## Results

All test results were negative.