# APPENDIX G INGREDIENTS, NUTRIENT COMPOSITION, AND CONTAMINANT LEVELS IN NTP-2000 RAT AND MOUSE RATION

TABLE G1 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground hard winter wheat | 22.26
Ground #2 yellow shelled corn | 22.18
Wheat middlings | 15.0
Oat hulls | 8.5
Alfalfa meal (dehydrated, 17% protein) | 7.5
Purified cellulose | 5.5
Soybean meal (49% protein) | 5.0
Fish meal (60% protein) | 4.0
Corn oil (without preservatives) | 3.0
Soy oil (without preservatives) | 3.0
Dried brewer’s yeast | 1.0
Calcium carbonate (USP) | 0.9
Vitamin premix^a^ | 0.5
Mineral premix^b^ | 0.5
Calcium phosphate, dibasic (USP) | 0.4
Sodium chloride | 0.3
Choline chloride (70% choline) | 0.26
Methionine | 0.2

a Wheat middlings as carrier

b Calcium carbonate as carrier

TABLE G2 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration^a^

| Amount | Source
Vitamins
A | 4,000 IU | Stabilized vitamin A palmitate or acetate
D | 1,000 IU | D-activated animal sterol
K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl acetate | 100 IU
Niacin | 23 mg
Folic acid | 1.1 mg
d-Pantothenic acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg
Thiamine | 4 mg | Thiamine mononitrate
B_12_ | 52 μg
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

a Per kg of finished product

TABLE G3 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by weight) | 15.1 ± 0.46 | 14.4 – 15.7 | 7
Crude fat (% by weight) | 8.2 ± 0.24 | 7.8 – 8.5 | 7
Crude fiber (% by weight) | 8.9 ± 0.68 | 8.0 – 9.7 | 7
Ash (% by weight) | 5.0 ± 0.24 | 4.6 – 5.4 | 7
Amino Acids (% of total diet)
Arginine | 0.775 ± 0.068 | 0.670 – 0.970 | 20
Cystine | 0.222 ± 0.025 | 0.150 – 0.250 | 20
Glycine | 0.701 ± 0.043 | 0.620 – 0.800 | 20
Histidine | 0.356 ± 0.081 | 0.270 – 0.680 | 20
Isoleucine | 0.543 ± 0.045 | 0.430 – 0.660 | 20
Leucine | 1.094 ± 0.069 | 0.960 – 1.240 | 20
Lysine | 0.706 ± 0.115 | 0.310 – 0.840 | 20
Methionine | 0.408 ± 0.048 | 0.260 – 0.490 | 20
Phenylalanine | 0.626 ± 0.041 | 0.540 – 0.720 | 20
Threonine | 0.502 ± 0.044 | 0.430 – 0.610 | 20
Tryptophan | 0.147 ± 0.027 | 0.110 – 0.200 | 20
Tyrosine | 0.394 ± 0.058 | 0.280 – 0.540 | 20
Valine | 0.666 ± 0.045 | 0.550 – 0.730 | 20
Essential Fatty Acids (% of total diet)
Linoleic | 3.92 ± 0.231 | 3.49 – 4.54 | 20
Linolenic | 0.30 ± 0.031 | 0.21 – 0.35 | 20
Vitamins
Vitamin A (IU/kg) | 4,223 ± 1,888 | 2,890 – 8,400 | 7
Vitamin D (IU/kg) | 1,000^a^
α-Tocopherol (ppm) | 82.8 ± 19.39 | 52.0 – 124.0 | 20
Thiamine (ppm)^b^ | 8.7 ± 3.86 | 6.2 – 17.3 | 7
Riboflavin (ppm) | 7.1 ± 1.96 | 4.20 – 11.20 | 20
Niacin (ppm) | 78.5 ± 9.39 | 66.4 – 98.2 | 20
Pantothenic acid (ppm) | 26.8 ± 13.16 | 17.4 – 81.0 | 20
Pyridoxine (ppm)^b^ | 9.46 ± 2.06 | 6.4 – 13.7 | 20
Folic acid (ppm) | 1.65 ± 0.50 | 1.15 – 3.27 | 20
Biotin (ppm) | 0.319 ± 0.11 | 0.200 – 0.704 | 20
Vitamin B_12_ (ppb) | 53.9 ± 41.6 | 18.3 – 174.0 | 20
Choline (ppm)^b^ | 2,939 ± 399 | 2,000 – 3,790 | 20
Minerals
Calcium (%) | 0.937 ± 0.060 | 0.872 – 1.040 | 7
Phosphorus (%) | 0.560 ± 0.044 | 0.481 – 0.625 | 7
Potassium (%) | 0.664 ± 0.028 | 0.626 – 0.732 | 20
Chloride (%) | 0.386 ± 0.040 | 0.300 – 0.474 | 20
Sodium (%) | 0.190 ± 0.016 | 0.160 – 0.222 | 20
Magnesium (%) | 0.217 ± 0.065 | 0.185 – 0.490 | 20
Sulfur (%) | 0.170 ± 0.029 | 0.116 – 0.209 | 14
Iron (ppm) | 184 ± 40.7 | 135 – 311 | 20
Manganese (ppm) | 51.8 ± 7.31 | 21.0 – 73.1 | 20
Zinc (ppm) | 53.5 ± 8.85 | 43.3 – 78.5 | 20
Copper (ppm) | 7.05 ± 2.677 | 3.21 – 16.30 | 20
Iodine (ppm) | 0.496 ± 0.215 | 0.158 – 0.972 | 20
Chromium (ppm) | 0.674 ± 0.283 | 0.330 – 1.380 | 19
Cobalt (ppm) | 0.27 ± 0.164 | 0.133 – 0.864 | 18

a From formulation

b As hydrochloride (thiamine and pyridoxine) or chloride (choline)

TABLE G4 Contaminant Levels in NTP-2000 Rat and Mouse Ration^a^

| Mean ± Standard Deviation^b^ | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.26 ± 0.054 | 0.20 – 0.36 | 7
Cadmium (ppm) | 0.07 ± 0.012 | 0.05 – 0.08 | 7
Lead (ppm) | 0.10 ± 0.009 | 0.08 – 0.11 | 7
Mercury (ppm) | <0.02 | | 7
Selenium (ppm) | 0.27 ± 0.160 | 0.16 – 0.63 | 7
Aflatoxins (ppb) | <5.00 | | 7
Nitrate nitrogen (ppm)^c^ | 21.9 ± 7.65 | 10.0 – 29.0 | 7
Nitrite nitrogen (ppm)^c^ | <0.61 | | 7
BHA (ppm)^d^ | <1.0 | | 7
BHT (ppm)^d^ | <1.0 | | 7
Aerobic plate count (CFU/g) | 10 ± 0 | 10 | 7
Coliform (MPN/g) | 3 ± 0 | 3 | 7
Escherichia coli (MPN/g) | <10 | | 7
Salmonella (MPN/g) | Negative | | 7
Total nitrosoamines (ppb)^e^ | 11.6 ± 4.66 | 7.9 – 20.4 | 7
N-Nitrosodimethylamine (ppb)^e^ | 4.4 ± 4.37 | 1.0 – 13.5 | 7
N-Nitrosopyrrolidine (ppb)^e^ | 7.2 ± 5.3 | 1.2 – 16.2 | 7
Pesticides (ppm)
α-BHC | <0.01 | | 7
β-BHC | <0.02 | | 7
γ-BHC | <0.01 | | 7
δ-BHC | <0.01 | | 7
Heptachlor | <0.01 | | 7
Aldrin | <0.01 | | 7
Heptachlor epoxide | <0.01 | | 7
DDE | <0.01 | | 7
DDD | <0.01 | | 7
DDT | <0.01 | | 7
HCB | <0.01 | | 7
Mirex | <0.01 | | 7
Methoxychlor | <0.05 | | 7
Dieldrin | <0.01 | | 7
Endrin | <0.01 | | 7
Telodrin | <0.01 | | 7
Chlordane | <0.05 | | 7
Toxaphene | <0.10 | | 7
Estimated PCBs | <0.20 | | 7
Ronnel | <0.01 | | 7
Ethion | <0.02 | | 7
Trithion | <0.05 | | 7
Diazinon | <0.10 | | 7
Methyl chlorpyrifos | 0.048 ± 0.039 | 0.020 – 0.113 | 7
Methyl parathion | <0.02 | | 7
Ethyl parathion | <0.02 | | 7
Malathion | 0.082 ± 0.070 | 0.020 – 0.187 | 7
Endosulfan I | <0.01 | | 7
Endosulfan II | <0.01 | | 7
Endosulfan sulfate | <0.03 | | 7

a All samples were irradiated. CFU=colony-forming units; MPN=most probable number; BHC=hexachlorocyclohexane or benzene hexachloride

b For values less than the limit of detection, the detection limit is given as the mean.

c Sources of contamination: alfalfa, grains, and fish meal

d Sources of contamination: soy oil and fish meal

e All values were corrected for percent recovery.