# APPENDIX F HISTORICAL CONTROL INCIDENCES

TABLE F1 Historical Incidences of Neoplasms in Control Male Heterozygous F1 p53^+/−^ Mice in the 9-Month NCTR Studies of AZT and AZT/3TC and the 40-Week NTP Study of Senna^a^

Neoplasm | AZT | AZT/3TC | Senna | Overall
Bone
Osteosarcoma | 0/27 | 1/25 | 0/25 | 1/77
Humerus, osteosarcoma | 1/27 | 1/25 | 0/25 | 2/77
Femur, osteosarcoma | 1/27 | 0/25 | 0/25 | 1/77
Tibia, osteosarcoma | 0/27 | 1/25 | 0/25 | 1/77
Any location, osteosarcoma | 2/27 | 3/25 | 0/25 | 5/77
Harderian gland
Adenoma | 1/27 | 0/25 | 0/25 | 1/77
Liver
Hepatocellular adenoma | 3/26 | 1/25 | 1/25 | 5/76
Lung
Alveolar/bronchiolar adenoma | 0/27 | 0/25 | 1/25 | 1/77
Lymph node
Mediastinal, sarcoma | 0/27 | 1/25 | 0/25 | 1/77
Mesenteric, sarcoma | 0/26 | 1/24 | 0/24 | 1/74
Mesentery
Sarcoma | 0/27 | 1/25 | 0/25 | 1/77
Pancreas
Sarcoma | 0/27 | 1/24 | 0/25 | 1/76
Skeletal muscle, diaphragm
Sarcoma | 0/27 | 1/25 | 0/25 | 1/77
Small intestine
Duodenum, leiomyosarcoma | 0/26 | 1/23 | 0/25 | 1/74
Jejunum, adenocarcinoma | 0/26 | 1/23 | 0/25 | 1/74
Tissue NOS
Sarcoma | 1/26 | 0/25 | 0/25 | 1/76
Abdominal sarcoma | 0/27 | 1/25 | 0/25 | 1/77
All organs
Malignant lymphoma | 1/27 | 1/25 | 1/25 | 3/77

a Data as of February 18, 2010. The AZT studies involved transplacental dosing and may not be comparable to the current NTP senna study.

TABLE F2 Historical Incidences of Neoplasms in Control Female Heterozygous F1 p53^+/−^ Mice in the 9-Month NCTR Studies of AZT and AZT/3TC and the 40-Week NTP Study of Senna^a^

Neoplasm | AZT | AZT/3TC | Senna | Overall
Adrenal medulla
Pheochromocytoma, benign | 0/25 | 0/25 | 1/25 | 1/75
Bone
Femur, osteosarcoma | 1/26 | 0/25 | 0/25 | 1/76
Rib, osteosarcoma | 0/26 | 0/25 | 1/25 | 1/76
Vertebra, osteosarcoma | 0/26 | 0/25 | 1/25 | 1/76
Any location, osteosarcoma | 1/26 | 0/25 | 2/25 | 3/76
Bone marrow
Sarcoma | 1/26 | 0/25 | 0/25 | 1/76
Brain, cerebrum
Sarcoma | 1/26 | 0/25 | 0/25 | 1/76
Large intestine, cecum
Polyp | 0/25 | 0/25 | 0/25 | 0/75
Liver
Sarcoma | 1/26 | 0/25 | 0/25 | 1/76
Lung
Alveolar/bronchiolar adenoma | 0/26 | 1/25 | 0/25 | 1/76
Mediastinum, sarcoma | 1/26 | 0/25 | 0/25 | 1/76
Lymph node
Mandibular, sarcoma | 1/26 | 0/25 | 0/25 | 1/76
Mesenteric, sarcoma | 1/26 | 0/25 | 0/23 | 1/74
Mammary gland
Adenocarcinoma | 0/25 | 1/25 | 0/25 | 1/75
Nose
Sarcoma | 1/26 | 0/25 | 0/25 | 1/76
Ovary
Cystadenoma | 0/26 | 0/25 | 1/25 | 1/76
Granuloma cell tumor, malignant | 0/26 | 0/25 | 1/25 | 1/76
Luteoma | 1/26 | 0/25 | 0/25 | 1/76
Spleen
Sarcoma | 1/26 | 0/25 | 0/25 | 1/76
All organs
Malignant lymphoma | 0/26 | 2/25 | 1/25 | 3/76
Malignant mesothelioma | 1/26 | 0/25 | 0/25 | 1/76

a Data as of February 18, 2010. The AZT studies involved transplacental dosing and may not be comparable to the current NTP senna study.