# APPENDIX E FEED AND COMPOUND CONSUMPTION IN THE 40-WEEK FEED STUDY OF SENNA

TABLE E1 Feed and Compound Consumption by Male Heterozygous F1 p53^+/−^ Mice in the 40-Week Feed Study of Senna

Weeks | 0 ppm | | 100 ppm | | | 300 ppm | | | 1,000 ppm | | | 3,000 ppm | | | 10,000 ppm
Weeks | Feed^a^ (g/day) | Body Weight (g) | Feed (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
2 | 4.6 | 25.9 | 4.7 | 26.1 | 18 | 4.7 | 26.0 | 54 | 4.7 | 25.8 | 183 | 4.7 | 25.8 | 546 | 4.6 | 25.0 | 1,844
3 | 4.8 | 26.9 | 4.6 | 26.7 | 17 | 4.9 | 27.1 | 54 | 4.7 | 26.8 | 175 | 4.8 | 26.8 | 537 | 4.8 | 25.5 | 1,884
4 | 4.6 | 27.8 | 4.7 | 27.6 | 17 | 4.8 | 28.0 | 52 | 4.5 | 27.6 | 163 | 4.7 | 27.6 | 510 | 4.5 | 26.7 | 1,689
5 | 4.7 | 28.7 | 4.7 | 28.9 | 16 | 4.7 | 29.1 | 49 | 4.5 | 28.6 | 158 | 4.7 | 28.9 | 487 | 4.5 | 27.6 | 1,632
6 | 4.6 | 30.0 | 4.7 | 29.9 | 16 | 4.6 | 30.2 | 48 | 4.5 | 29.5 | 153 | 4.7 | 29.8 | 473 | 4.6 | 28.3 | 1,627
7 | 4.4 | 31.0 | 4.7 | 30.7 | 15 | 5.0 | 31.6 | 48 | 4.5 | 30.4 | 148 | 4.8 | 31.2 | 462 | 4.7 | 29.4 | 1,600
8 | 4.5 | 31.7 | 4.8 | 31.8 | 15 | 4.8 | 32.3 | 45 | 4.6 | 31.3 | 147 | 4.8 | 31.9 | 451 | 4.6 | 30.2 | 1,523
9 | 4.9 | 32.6 | 4.8 | 32.9 | 15 | 4.8 | 33.4 | 43 | 4.6 | 32.0 | 144 | 4.7 | 33.0 | 427 | 4.7 | 31.2 | 1,509
10 | 4.6 | 33.4 | 4.7 | 33.7 | 14 | 4.7 | 34.4 | 41 | 4.8 | 33.1 | 145 | 4.7 | 33.8 | 417 | 4.7 | 32.0 | 1,468
11 | 4.5 | 34.5 | 4.5 | 34.3 | 13 | 4.7 | 35.5 | 40 | 4.6 | 34.3 | 134 | 4.8 | 34.6 | 416 | 4.6 | 32.8 | 1,402
12 | 4.7 | 35.1 | 4.7 | 35.2 | 13 | 4.8 | 36.3 | 40 | 4.7 | 35.0 | 134 | 4.7 | 35.3 | 399 | 4.4 | 33.2 | 1,326
13 | 4.7 | 36.1 | 4.7 | 36.3 | 13 | 4.8 | 37.4 | 39 | 4.5 | 35.7 | 126 | 4.9 | 36.8 | 400 | 4.6 | 34.3 | 1,341
14 | 4.6 | 36.7 | 4.4 | 36.6 | 12 | 4.8 | 37.9 | 38 | 4.6 | 36.4 | 126 | 4.6 | 37.1 | 372 | 4.7 | 34.8 | 1,351
15 | 4.5 | 37.0 | 4.4 | 36.8 | 12 | 4.7 | 38.8 | 36 | 4.6 | 37.1 | 124 | 4.7 | 37.9 | 372 | 4.6 | 35.2 | 1,307
16 | 4.5 | 38.0 | 4.7 | 38.0 | 12 | 4.7 | 39.5 | 36 | 4.6 | 37.8 | 122 | 4.6 | 38.4 | 359 | 4.6 | 35.9 | 1,280
17 | 4.6 | 39.2 | 4.5 | 38.6 | 12 | 4.7 | 40.2 | 35 | 4.8 | 38.7 | 124 | 4.7 | 39.2 | 360 | 4.4 | 36.3 | 1,211
18 | 4.7 | 40.1 | 4.6 | 39.3 | 12 | 4.9 | 41.5 | 35 | 4.8 | 39.7 | 121 | 4.7 | 39.8 | 355 | 4.7 | 37.7 | 1,248
19 | 4.4 | 40.1 | 4.4 | 39.6 | 11 | 4.5 | 41.7 | 32 | 4.4 | 39.8 | 111 | 4.5 | 40.3 | 335 | 4.3 | 37.8 | 1,139
20 | 4.6 | 41.0 | 4.6 | 40.5 | 11 | 4.8 | 42.8 | 34 | 4.4 | 40.5 | 109 | 4.8 | 41.6 | 346 | 4.6 | 38.8 | 1,186
21 | 4.4 | 41.3 | 4.5 | 41.0 | 11 | 4.8 | 43.7 | 33 | 4.6 | 41.0 | 112 | 4.6 | 42.1 | 328 | 4.5 | 39.1 | 1,151
22 | 4.6 | 41.9 | 4.5 | 41.4 | 11 | 4.6 | 43.9 | 31 | 4.6 | 41.8 | 110 | 4.6 | 42.5 | 325 | 4.4 | 39.4 | 1,118
23 | 4.8 | 43.2 | 4.9 | 42.4 | 12 | 4.9 | 44.9 | 33 | 4.7 | 42.5 | 111 | 4.8 | 43.5 | 331 | 4.5 | 39.9 | 1,127
24 | 4.7 | 43.7 | 4.7 | 42.8 | 11 | 4.9 | 45.7 | 32 | 4.6 | 43.0 | 107 | 4.8 | 44.2 | 326 | 4.8 | 41.2 | 1,166
25 | 4.7 | 44.5 | 4.6 | 43.2 | 11 | 4.7 | 46.5 | 30 | 4.6 | 43.7 | 105 | 4.7 | 44.8 | 315 | 4.5 | 41.6 | 1,082
26 | 4.6 | 44.8 | 4.8 | 44.2 | 11 | 4.8 | 47.1 | 31 | 4.7 | 44.5 | 106 | 4.7 | 45.4 | 311 | 4.6 | 42.2 | 1,091
27 | 4.8 | 45.4 | 4.6 | 44.6 | 10 | 4.7 | 47.3 | 30 | 4.6 | 45.2 | 102 | 4.8 | 46.1 | 312 | 4.6 | 42.6 | 1,079
28 | 4.8 | 46.4 | 4.6 | 45.1 | 10 | 4.7 | 47.7 | 30 | 4.7 | 45.8 | 103 | 4.8 | 46.7 | 309 | 4.6 | 43.2 | 1,064
29 | 4.5 | 46.5 | 4.6 | 45.5 | 10 | 4.8 | 48.2 | 30 | 4.7 | 46.0 | 102 | 4.8 | 47.2 | 305 | 4.5 | 43.3 | 1,039
30 | 4.5 | 46.9 | 4.7 | 46.1 | 10 | 4.7 | 48.3 | 29 | 4.6 | 46.5 | 99 | 4.7 | 47.4 | 297 | 4.5 | 43.7 | 1,030
31 | 4.6 | 47.3 | 4.8 | 46.9 | 10 | 4.9 | 48.6 | 30 | 4.7 | 46.6 | 101 | 4.8 | 47.7 | 302 | 4.8 | 44.6 | 1,076
32 | 5.0 | 47.7 | 4.9 | 47.0 | 10 | 5.1 | 48.8 | 31 | 4.7 | 46.7 | 101 | 4.8 | 47.8 | 301 | 4.8 | 45.0 | 1,066
33 | 4.6 | 47.4 | 4.7 | 47.2 | 10 | 5.2 | 49.3 | 32 | 4.9 | 47.0 | 104 | 4.8 | 47.7 | 302 | 4.8 | 45.2 | 1,062
34 | 5.1 | 48.1 | 5.1 | 48.0 | 11 | 5.2 | 49.5 | 32 | 5.1 | 47.4 | 108 | 5.2 | 48.5 | 322 | 5.0 | 45.7 | 1,095
35 | 4.8 | 48.0 | 4.8 | 47.9 | 10 | 5.0 | 49.5 | 30 | 5.1 | 48.0 | 106 | 5.0 | 48.8 | 308 | 4.9 | 45.8 | 1,071
36 | 4.9 | 48.3 | 5.1 | 48.8 | 11 | 5.2 | 50.1 | 31 | 5.0 | 48.2 | 104 | 5.0 | 49.1 | 306 | 4.7 | 45.8 | 1,026
37 | 4.9 | 48.5 | 4.9 | 48.8 | 10 | 5.2 | 50.4 | 31 | 4.9 | 48.1 | 102 | 4.8 | 48.6 | 296 | 4.8 | 46.1 | 1,041
38 | 4.9 | 48.8 | 4.9 | 49.0 | 10 | 5.1 | 50.5 | 30 | 5.0 | 48.1 | 104 | 4.6 | 48.7 | 284 | 4.9 | 46.6 | 1,052
39 | 4.9 | 48.8 | 5.0 | 49.3 | 10 | 5.2 | 50.9 | 31 | 4.8 | 48.1 | 100 | 5.1 | 49.1 | 311 | 4.8 | 46.6 | 1,029
40 | 5.0 | 49.3 | 5.0 | 49.6 | 10 | 5.1 | 51.1 | 30 | 4.9 | 48.1 | 102 | 5.1 | 49.6 | 308 | 4.9 | 46.8 | 1,046
Mean for Weeks
1–13 | 4.6 | 31.1 | 4.7 | 31.2 | 15 | 4.8 | 31.8 | 46 | 4.6 | 30.8 | 151 | 4.8 | 31.3 | 460 | 4.6 | 29.7 | 1,570
14–40 | 4.7 | 44.4 | 4.7 | 44.0 | 11 | 4.9 | 46.1 | 32 | 4.7 | 43.9 | 108 | 4.8 | 44.8 | 322 | 4.7 | 41.9 | 1,120

a Grams of feed consumed per animal per day

b Milligrams of senna consumed per kilogram body weight per day

TABLE E2 Feed and Compound Consumption by Female Heterozygous F1 p53^+/−^ Mice in the 40-Week Feed Study of Senna

Weeks | 0 ppm | | 100 ppm | | | 300 ppm | | | 1,000 ppm | | | 3,000 ppm | | | 10,000 ppm
Weeks | Feed^a^ (g/day) | Body Weight (g) | Feed (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
2 | 4.4 | 21.1 | 4.5 | 21.2 | 21 | 4.7 | 21.1 | 67 | 4.5 | 21.2 | 212 | 4.5 | 21.1 | 639 | 4.7 | 21.0 | 2,239
3 | 4.6 | 22.6 | 4.5 | 22.2 | 20 | 4.6 | 21.9 | 63 | 4.8 | 22.4 | 214 | 4.7 | 22.3 | 631 | 4.9 | 21.7 | 2,258
4 | 4.5 | 23.4 | 4.5 | 22.9 | 20 | 4.2 | 22.8 | 55 | 4.5 | 23.2 | 194 | 4.6 | 23.0 | 601 | 4.7 | 22.8 | 2,065
5 | 4.7 | 24.6 | 4.5 | 24.1 | 19 | 4.4 | 23.9 | 55 | 4.6 | 24.3 | 189 | 4.5 | 24.2 | 558 | 4.9 | 23.8 | 2,062
6 | 4.1 | 25.1 | 4.5 | 24.5 | 18 | 4.5 | 24.7 | 55 | 4.5 | 24.9 | 181 | 4.5 | 24.7 | 546 | 4.8 | 24.2 | 1,984
7 | 4.3 | 25.9 | 4.3 | 25.7 | 17 | 4.2 | 25.4 | 50 | 4.2 | 26.0 | 162 | 4.3 | 26.0 | 497 | 4.7 | 25.3 | 1,858
8 | 4.4 | 26.9 | 5.0 | 26.9 | 19 | 4.6 | 26.2 | 53 | 4.7 | 27.0 | 174 | 4.8 | 26.7 | 540 | 4.9 | 26.1 | 1,876
9 | 4.8 | 28.5 | 4.9 | 28.1 | 17 | 4.7 | 27.2 | 52 | 4.8 | 28.2 | 170 | 4.8 | 26.9 | 536 | 5.0 | 27.2 | 1,840
10 | 4.6 | 29.0 | 4.7 | 28.4 | 17 | 4.6 | 27.9 | 49 | 4.7 | 28.6 | 164 | 4.6 | 27.9 | 495 | 4.8 | 27.4 | 1,749
11 | 4.6 | 29.9 | 4.4 | 28.7 | 15 | 4.4 | 28.4 | 47 | 4.8 | 29.7 | 161 | 4.7 | 29.1 | 484 | 4.7 | 27.8 | 1,694
12 | 4.8 | 31.0 | 5.0 | 30.3 | 17 | 4.7 | 29.4 | 48 | 4.8 | 30.8 | 156 | 4.6 | 29.8 | 463 | 5.1 | 28.8 | 1,773
13 | 4.6 | 31.3 | 4.5 | 31.2 | 14 | 4.4 | 30.3 | 44 | 4.7 | 31.3 | 150 | 4.7 | 30.9 | 456 | 4.9 | 29.4 | 1,669
14 | 4.6 | 32.0 | 4.9 | 31.5 | 16 | 4.5 | 30.5 | 44 | 4.6 | 32.2 | 143 | 4.9 | 31.7 | 463 | 5.2 | 30.5 | 1,705
15 | 4.6 | 32.5 | 4.3 | 31.6 | 14 | 4.5 | 31.1 | 43 | 4.5 | 32.6 | 138 | 4.7 | 31.8 | 444 | 4.6 | 30.6 | 1,504
16 | 4.6 | 33.5 | 4.4 | 32.6 | 14 | 4.5 | 31.7 | 43 | 4.5 | 33.2 | 135 | 4.6 | 32.3 | 427 | 4.5 | 30.8 | 1,461
17 | 4.3 | 33.8 | 4.5 | 32.9 | 14 | 4.1 | 32.0 | 38 | 4.3 | 33.5 | 128 | 4.3 | 32.2 | 400 | 4.3 | 31.2 | 1,379
18 | 4.8 | 34.6 | 4.6 | 34.0 | 14 | 4.4 | 32.7 | 40 | 4.6 | 34.4 | 134 | 4.6 | 32.8 | 421 | 4.6 | 31.8 | 1,445
19 | 4.2 | 34.8 | 4.3 | 34.1 | 13 | 4.2 | 33.3 | 38 | 4.2 | 34.9 | 121 | 4.3 | 33.5 | 385 | 4.2 | 32.0 | 1,312
20 | 4.4 | 35.4 | 4.3 | 34.5 | 13 | 4.0 | 33.2 | 36 | 4.0 | 35.0 | 114 | 4.4 | 34.1 | 387 | 4.5 | 32.9 | 1,370
21 | 4.4 | 35.9 | 4.5 | 35.0 | 13 | 4.4 | 34.1 | 39 | 4.2 | 35.4 | 119 | 4.3 | 33.9 | 380 | 4.5 | 32.9 | 1,367
22 | 4.6 | 36.4 | 4.7 | 35.9 | 13 | 4.4 | 34.7 | 38 | 4.6 | 36.2 | 127 | 4.5 | 34.8 | 388 | 4.6 | 33.7 | 1,364
23 | 4.8 | 36.8 | 5.1 | 36.7 | 14 | 4.6 | 35.2 | 39 | 4.6 | 36.7 | 125 | 5.0 | 35.2 | 426 | 5.0 | 34.3 | 1,459
24 | 4.6 | 37.2 | 4.7 | 37.2 | 13 | 4.4 | 35.6 | 37 | 4.5 | 36.8 | 122 | 4.5 | 35.1 | 385 | 4.9 | 34.9 | 1,403
25 | 4.9 | 38.1 | 4.7 | 37.7 | 13 | 4.5 | 36.1 | 37 | 4.7 | 37.6 | 125 | 4.6 | 35.6 | 388 | 4.7 | 34.8 | 1,352
26 | 4.5 | 38.3 | 4.8 | 38.4 | 13 | 4.7 | 36.8 | 38 | 4.5 | 37.6 | 120 | 4.9 | 36.8 | 400 | 5.0 | 35.8 | 1,398
27 | 4.4 | 38.4 | 4.6 | 38.9 | 12 | 4.9 | 37.8 | 39 | 4.6 | 38.2 | 120 | 4.9 | 37.3 | 394 | 4.6 | 35.8 | 1,285
28 | 4.3 | 38.6 | 4.3 | 38.7 | 11 | 4.1 | 37.0 | 33 | 4.4 | 38.5 | 114 | 4.5 | 37.4 | 361 | 4.6 | 36.0 | 1,279
29 | 4.3 | 38.7 | 4.6 | 39.0 | 12 | 4.3 | 37.2 | 35 | 4.5 | 38.9 | 116 | 4.7 | 38.1 | 370 | 4.7 | 36.5 | 1,287
30 | 4.4 | 38.4 | 4.4 | 38.9 | 11 | 4.3 | 37.2 | 35 | 4.2 | 38.8 | 108 | 4.5 | 37.9 | 356 | 4.4 | 36.5 | 1,206
31 | 4.5 | 38.8 | 4.7 | 39.2 | 12 | 4.3 | 37.0 | 35 | 4.4 | 38.9 | 113 | 4.7 | 38.2 | 367 | 4.5 | 36.9 | 1,221
32 | 4.8 | 39.4 | 4.6 | 39.2 | 12 | 4.7 | 37.8 | 37 | 4.6 | 39.2 | 117 | 4.8 | 38.9 | 371 | 4.9 | 37.6 | 1,305
33 | 4.8 | 39.8 | 4.8 | 39.5 | 12 | 4.5 | 37.7 | 36 | 4.8 | 39.9 | 120 | 4.8 | 38.8 | 371 | 4.8 | 37.5 | 1,279
34 | 4.8 | 40.8 | 5.2 | 40.5 | 13 | 4.5 | 38.0 | 36 | 4.9 | 40.0 | 123 | 5.0 | 39.3 | 382 | 5.2 | 38.0 | 1,369
35 | 4.9 | 41.4 | 4.8 | 40.3 | 12 | 4.4 | 38.4 | 34 | 4.6 | 40.3 | 114 | 4.9 | 39.5 | 372 | 5.0 | 38.5 | 1,299
36 | 4.5 | 41.1 | 5.0 | 40.7 | 12 | 4.6 | 38.5 | 36 | 4.7 | 40.2 | 117 | 4.9 | 39.9 | 368 | 4.7 | 38.6 | 1,218
37 | 4.9 | 41.8 | 4.7 | 40.5 | 12 | 4.8 | 39.2 | 37 | 4.7 | 40.1 | 117 | 4.9 | 39.9 | 368 | 4.8 | 38.5 | 1,248
38 | 4.9 | 42.2 | 4.8 | 40.3 | 12 | 4.8 | 39.7 | 36 | 4.9 | 40.5 | 121 | 4.9 | 40.1 | 367 | 4.8 | 38.5 | 1,248
39 | 4.6 | 42.3 | 4.6 | 41.1 | 11 | 4.5 | 39.6 | 34 | 4.9 | 40.8 | 120 | 4.5 | 39.6 | 341 | 4.7 | 38.6 | 1,217
40 | 4.5 | 41.8 | 4.9 | 41.2 | 12 | 4.8 | 40.1 | 36 | 4.8 | 41.3 | 116 | 4.9 | 40.6 | 362 | 4.8 | 38.9 | 1,233
Mean for Weeks
1–13 | 4.5 | 26.6 | 4.6 | 26.2 | 18 | 4.5 | 25.8 | 53 | 4.6 | 26.5 | 177 | 4.6 | 26.1 | 537 | 4.8 | 25.5 | 1,922
14–40 | 4.6 | 37.9 | 4.7 | 37.4 | 13 | 4.5 | 36.0 | 37 | 4.5 | 37.5 | 122 | 4.7 | 36.5 | 387 | 4.7 | 35.3 | 1,341

a Grams of feed consumed per animal per day

b Milligrams of senna consumed per kilogram body weight per day