# APPENDIX D CHEMICAL CHARACTERIZATION AND DOSE FORMULATION STUDIES

## Procurement and Characterization of Senna

Senna was obtained from Madaus AG (Köln, Germany) in one lot (1999000) that was used in the 5- and 40-week studies. Identity and purity analyses were conducted by the analytical chemistry laboratory at Research Triangle Institute (Research Triangle Park, NC) and by the study laboratory at Battelle Columbus Operations (Columbus, OH). Reports on analyses performed in support of the senna studies are on file at the National Institute of Environmental Health Sciences.

Lot 1999000 of the chemical, a brown, powdered raw plant material, was identified as senna by the analytical chemistry laboratory using high-performance liquid chromatography with ultraviolet detection (HPLC/UV) by system A (Table D1), and the identity was confirmed by the study laboratory using a similar HPLC/UV system.

The bulk test material was characterized by the analytical chemistry laboratory as a multi-component natural product with a complex mixture of constituents that were confirmed by identifying as many components as possible in methanol:water (50:50) extracts of the raw material. Chromatographic comparisons were made to reference standard solutions in the same solvent of sennosides A and B and sennidins A and B purchased from Indofine Chemical Company, Inc. (Hillsborough, NJ); aloe-emodin, emodin, and rhein from Sigma-Aldrich, Inc. (St. Louis, MO); and aloe-emodin-8-glucoside, chrysophanic acid, and physcione from Madaus AG. In a parallel study conducted by the Natural Products Group of the analytical chemistry laboratory, nine additional reference standards that assisted in identifying constituents in lot 1999000 were isolated and identified in methanol:water (50:50) extracts of RTI lot 10001-86-01 of senna obtained from Frontier Natural Products Co-op (Norway, IA). Forty-seven components with a peak area of at least 0.1% of the total peak area were observed using system A, accounting for 99.6% of the total peak area for the test material extract (Figure D1). Of these 47, 18 were considered major components (≥ 1% each). By comparisons to the chromatographic profiles of the purchased and isolated reference standards, peaks were confirmed in lot 1999000 for sennosides A and B, sennidins A and B, rhein, aloe-emodin, quercetin 3-gentiobioside, kaempferol 3-gentiobioside, torachrysone-8-O-ß-D-glucopyranoside, quercetin, and torachrysone (Figures D2 and D3). Weight percentages of four postulated active components in the test article were estimated to be: 0.7% sennoside A, 1.3% sennoside B, 0.06% sennidin A, and 0.03% sennidin B. The identities of the marker compounds sennoside A and sennoside B in lot 1999000 were confirmed by the study laboratory using resolution standard solutions of these chemicals in methanol:water (50:50).

Lot 1999000 was sterilized by exposure to cobalt-60. The irradiation procedure was performed by Neutron Products, Inc. (Dickerson, MD). Comparison of the irradiated material with the nonirradiated material indicated that all 10 major peaks present in the nonirradiated material were present in the irradiated material at a relative concentration of ≥ 90.7%. Examination of the chromatograms before and after indicated that no new significant peaks appeared after irradiation (Figure D4, Tables D2 and D3).

The water content of lot 1999000 was determined by Covance Laboratories, Inc. (Madison, WI), using weight loss on drying and by the analytical laboratory using Karl Fischer titration. The bulk purity of the test material was determined by the analytical chemistry laboratory using broad gradient HPLC/UV by system B and a system similar to system B that monitored absorbance at 210 nm and utilized mobile phase modifiers that were compatible with low-ultraviolet wavelengths (i.e., phosphoric acid instead of ammonium formate). Broad screening assays for residual volatiles were conducted on dimethylsulfoxide extracts of the test material by the analytical chemistry laboratory using gas chromatography (GC) with flame ionization detection. These assays used a Varian 3800 instrument (Varian, Inc., Santa Clara, CA), a DB-624 (Agilent Technologies, Inc., Santa Clara, CA) or a Rtx^®^-200 (Restex, Bellefonte, PA) 30 m × 0.53 mm column with a 3.0 µm film, a temperature program of 40° C for 20 minutes followed by a 20° C/minute increase to 240° C and then a 20 minute hold, and helium carrier gas flowing at 4.3 to 4.6 mL/minute. Nutritional testing, trace metals screening, nitrosamines assays, and pesticide screening were performed on lot 1999000 by Covance Laboratories, Inc., using standard methods; trace metals were also assayed by the Trace Inorganics Department at the analytical chemistry laboratory.

For lot 1999000, moisture content was determined to be 6.0% (w/w) by weight loss on drying and 5.8% by weight by Karl Fischer titration. Broad gradient HPLC/UV analyses with monitoring at 210 or 270 nm each detected 13 major (≥ 1% of the total peak areas) components accounting for 91% of the total peak areas and 25 minor (< 1%) components. GC for residual volatiles detected methanol and isopropanol, both at levels below their estimated limits of quantitation (0.1% and 0.09% by weight, respectively), and a single unknown. Organochlorine and organophophorus pesticide levels were below the detection limits of 200 and 50 ppb, respectively. Mercury, thallium, and cadmium levels were less than the limits of detection, which were respectively 25, 20, and 500 ppb. Lead and selenium were present at 299 and 690 ppb, respectively. Nitrosamines were not present above the detection limit of 1.0 ppb. Results of the nutritional and contaminant tests were deemed acceptable for use in these studies.

To ensure stability, the bulk chemical was stored at approximately 5° C in a sealed plastic bag inside a 6-gallon metal pail (5-week study) or in amber glass bottles (40-week study). All transferring and handling of the study material was done under yellow lights. Periodic reanalyses of the bulk chemical were performed during the 5- and 40-week studies by the study laboratory using HPLC/UV by system A, and no degradation of the test material was detected.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared by mixing senna with feed (Table D4). A premix was prepared by hand and then blended with additional feed in a Patterson-Kelly twin-shell blender for 15 minutes. Formulations were stored in sealed plastic buckets containing plastic liners at approximately 5° C and used within 42 days.

Homogeneity and stability studies of the 300 and 10,000 ppm dose formulations were performed by the analytical chemistry laboratory using HPLC/UV by system C or a similar system, and the study laboratory performed homogeneity studies of the 625 and 10,000 ppm dose formulations using HPLC/UV by system C. Homogeneity and stability studies of the 100 ppm dose formulation were performed by the study laboratory using HPLC with mass spectrometry (MS) detection by system D; the more sensitive HPLC/MS/MS enabled the quantification of sennoside A in the 100 ppm dose formulation. Homogeneity was confirmed, and stability was confirmed for at least 42 days for dose formulations stored in sealed containers, protected from light, at 5° C, and for at least 7 days under simulated animal room conditions.

Periodic analyses of the dose formulations of senna (quantitating sennoside A as the analytical marker) were conducted by the study laboratory using HPLC/UV by system C (5-week study) or HPLC/MS/MS by system D (40-week study). During the 5-week study, the dose formulations were analyzed once; all five dose formulations were within 10% of the target concentrations (Table D5). Animal room samples of these dose formulations were also analyzed, and four of five were within 10% of the target concentrations. During the 40-week study, the dose formulations were analyzed five times; animal room samples were also analyzed (Table D6). Of the dose formulations analyzed, 33 of 50 were within 10% of the target concentrations; four of 10 animal room samples were within 10% of the target concentrations. Variability of the slope of the standard curve for the analytical assay was determined to account for the discrepancies between observed and expected sample values rather than incorrect formulation preparation or changing formulation concentrations during use.

TABLE D1 High-Performance Liquid Chromatography Systems Used in the Feed Studies of Senna^a^

Detection System | Column | Solvent System
System A
Ultraviolet (270 nm) light | Luna^®^ C18, 150 mm × 4.6 mm, 5 μm particle size (Phenomenex, Torrance, CA) | A) acetonitrile:25 mM aqueous ammonium formate (10:90) and; B) acetonitrile:25 mM aqueous ammonium formate (90:10);; 100% A for 10 minutes, then linear gradient to 96% A:4% B in 5 minutes, held for 10 minutes, then linear gradient to 10% A:90% B in 25 minutes, held for 10 minutes, then linear gradient to 100% A in 10 minutes, held for 5 minutes; flow rate 1.0 mL/minute
System B
Ultraviolet (270 nm) light | Luna^®^ C18, 150 mm × 4.6 mm, 5 μm particle size (Phenomenex) | A) acetonitrile:25 mM aqueous ammonium formate (10:90) and; B) acetonitrile:25 mM aqueous ammonium formate (90:10); 100% A to 100% B in 25 minutes, held at 100% B for 20 minutes, then to 100% A in 10 minutes, held for 5 minutes; flow rate 1.0 mL/minute
System C
Ultraviolet (270 nm) light | Nucleosil^®^ C8, 250 mm × 4.6 mm, 5 μm particle size (Phenomenex or MACHERERY-NAGEL, Inc., Bethlehem, PA) | A) methanol:25 mM aqueous ammonium formate: (10:90) and; B) methanol:25 mM aqueous ammonium formate: (90:10);; linear gradient from 100% A to 60% A:40% B in 20 minutes, held for 10 minutes, then linear gradient to 100% B in 15 minutes, held for 10 minutes, then linear gradient to 100% A in 5 minutes, held for 5 minutes; flow rate 1.0 mL/minute
System D
Mass spectrometry | Gemini^®^ C18, 100 mm × 4.6 mm, 3.0 μm particle size (Phenomenex) | A) 0.1% acetic acid in water and; B) 0.1% acetic acid in methanol; (40% A:60% B), isocratic; flow rate 0.5 mL/minute

a The high-performance liquid chromatographs were manufactured by Waters Corporation (Milford, MA) (systems A, B, and C) or Agilent Technologies, Inc. (Palo Alto, CA) (systems A, C, and D), and the mass spectrometer was manufactured by Micromass, Inc. (Manchester, UK) (system D).

FIGURE D1 High-Performance Liquid Chromatography Profile of an Extracted Senna Sample and a Solvent Blank

FIGURE D2 High-Performance Liquid Chromatography Profile of an Extracted Senna Sample; Component Confirmation for Commercially Acquired Components

FIGURE D3 High-Performance Liquid Chromatography Profile of an Extracted Senna Sample; Component Confirmation for RTI-Isolated Components

FIGURE D4 High Performance Liquid Chromatography Profiles of the Irradiated and Nonirradiated Senna Sample

TABLE D2 Results of Analyses of Irradiated Study Sample in the 5-Week Feed Study of Senna

Peak No. (Identity) | Replicate 1 RRF^a^ | Replicate 2 RRF | Mean RRF | Relative Purity (%)
1 | 3.383 | 3.635 | 3.509 | 95.3
2 | 0.7461 | 0.8072 | 0.7767 | 91.4
3 | 1.014 | 1.064 | 1.039 | 91.8
4 (sennoside B) | 2.519 | 2.690 | 2.605 | 91.5
5 (sennoside A) | 1.581 | 1.696 | 1.639 | 91.2
6 | 1.031 | 1.117 | 1.074 | 92.5
7 (rhein) | 1.093 | 1.177 | 1.135 | 92.4
8 (aloe-emodin) | 0.07147 | 0.08064 | 0.07606 | 90.7
9 (sennidin A) | 0.09410 | 0.10110 | 0.09760 | 92.6
10 (sennidin B) | 0.08326 | 0.09143 | 0.08735 | 91.7

a RRF=relative response factor

b % Relative purity = (mean RRF, study material/mean RRF, comparison material) × 100

TABLE D3 Results of Analyses of Nonirradiated Study Sample in the 5-Week Feed Study of Senna

Peak No. (Identity) | Replicate 1 RRF^a^ | Replicate 2 RRF | Mean RRF
1 | 3.710 | 3.656 | 3.683
2 | 0.8511 | 0.8482 | 0.8497
3 | 1.136 | 1.127 | 1.132
4 (sennoside B) | 2.849 | 2.847 | 2.848
5 (sennoside A) | 1.804 | 1.792 | 1.798
6 | 1.174 | 1.147 | 1.161
7 (rhein) | 1.252 | 1.204 | 1.228
8 (aloe-emodin) | 0.08655 | 0.08118 | 0.08387
9 (sennidin A) | 0.1072 | 0.1036 | 0.1054
10 (sennidin B) | 0.09814 | 0.09246 | 0.09530

a RRF=relative response factor

TABLE D4 Preparation and Storage of Dose Formulations in the Feed Studies of Senna

5-Week Study | 40-Week Study
Preparation
A premix of feed and senna was prepared, then layered into the remaining feed and blended in a Patterson-Kelly twin-shell V-blender for 15 minutes. The dose formulations were prepared once during the study. | Same as 5-week study. The dose formulations were prepared approximately monthly.
Chemical Lot Number
1999000 | 1999000
Maximum Storage Time
42 days | 42 days
Storage Conditions
Stored in sealed plastic buckets lined with plastic liners at approximately 5° C | Stored in sealed plastic buckets lined with plastic liners at approximately 5° C
Study Laboratory
Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH)

TABLE D5 Results of Analyses of Dose Formulations Administered to C57BL/6NTac Mice in the 5-Week Feed Study of Senna

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration^a^ (ppm) | Difference from Target (%)
September 28, 2005 | September 28–30, 2005 | 625 | 642 | +3
| | 1,250 | 1,310 | +5
| | 2,500 | 2,500 | 0
| | 5,000 | 5,160 | +3
| | 10,000 | 10,200 | +2
| November 10–13, 2005^b^ | 625 | 605 | −3
| | 1,250 | 1,260 | +1
| | 2,500 | 2,550 | +2
| | 5,000 | 5,770 | +15
| | 10,000 | 9,340 | −7

a Results of duplicate analyses

b Animal room samples

TABLE D6 Results of Analyses of Dose Formulations Administered to Heterozygous F1 p53^+/−^ Mice in the 40-Week Feed Study of Senna

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration^a^ (ppm) | Difference from Target (%)
June 12, 2007 | June 14–18, 2007 | 100 | 112 ± 1 | +12
| | 100 | 108 ± 3 | +8
| | 300 | 335 ± 15 | +12
| | 300 | 345 ± 16 | +15
| | 1,000 | 1,140 ± 90 | +14
| | 1,000 | 1,140 ± 50 | +14
| | 3,000 | 3,460 ± 270 | +15
| | 3,000 | 3,260 ± 270 | +9
| | 10,000 | 9,550 ± 230 | −5
| | 10,000 | 9,090 ± 70 | −9
| August 5, 2007^b^ | 100 | 106 ± 2 | +6
| | 300 | 349 ± 11 | +16
| | 1,000 | 1,220 ± 10 | +22
| | 3,000 | 3,730 ± 10 | +24
| | 10,000 | 12,100 ± 0 | +21
August 7, 2007 | August 13, 2007 | 100 | 88.0 ± 1.5 | −12
| | 100 | 86.9 ± 3.5 | −13
| | 300 | 311 ± 4 | +4
| | 300 | 312 ± 3 | +4
| | 1,000 | 1,040 ± 20 | +4
| | 1,000 | 1,030 ± 20 | +3
| | 3,000 | 2,970 ± 20 | −1
| | 3,000 | 3,020 ± 10 | +1
| | 10,000 | 10,500 ± 100 | +5
| | 10,000 | 10,400 ± 200 | +4
November 9, 2007 | November 13, 2007 | 100 | 95.7 ± 3.5 | −4
| | 100 | 104 ± 5 | +4
| | 300 | 282 ± 1 | −6
| | 300 | 306 ± 13 | +2
| | 1,000 | 923 ± 45 | −8
| | 1,000 | 940 ± 27 | −6
| | 3,000 | 2,830 ± 70 | −6
| | 3,000 | 3,120 ± 50 | +4
| | 10,000 | 9,970 ± 250 | 0
| | 10,000 | 10,400 ± 300 | +4
January 11, 2008 | January 16, 2008 | 100 | 72.7 ± 7.1^c^ | −27
| | 100 | 73.3 ± 22.0^c^ | −27
| | 300 | 233 ± 29^c^ | −22
| | 300 | 253 ± 24 | −16
| | 1,000 | 1,010 ± 130 | +1
| | 1,000 | 1,120 ± 30 | +12
| | 3,000 | 3,280 ± 20 | +9
| | 3,000 | 3,320 ± 170 | +11
| | 10,000 | 11,100 ± 800 | +11
| | 10,000 | 10,700 ± 100 | +7
| February 22, 2008^b^ | 100 | 99.4 ± 0.6 | −1
| | 300 | 298 ± 6 | −1
| | 1,000 | 869 ± 65 | −13
| | 3,000 | 2,600 ± 160 | −13
| | 10,000 | 9,350 ± 320 | −7
February 19, 2008 | February 29, 2008 | 100 | 118 ± 2 | +18
| | 100 | 101 ± 15 | +1
| | 300 | 329 ± 28 | +10
| | 300 | 295 ± 9 | −2
| | 1,000 | 926 ± 41 | −7
| | 1,000 | 950 ± 53 | −5
| | 3,000 | 2,730 ± 60 | −9
| | 3,000 | 2,590 ± 130 | −14
| | 10,000 | 9,700 ± 590 | −3
| | 10,000 | 10,300 ± 250 | +3

a Results of triplicate analyses (mean ± standard deviation).

b Animal room samples

c Formulation was outside the acceptable range of ± 20% of target concentration, but used at NTP’s direction.