# APPENDIX C ORGAN WEIGHTS AND ORGAN-WEIGHT-TO-BODY-WEIGHT RATIOS

TABLE C1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for C57BL/6NTac Mice in the 5-Week Feed Study of Senna^a^

| 0 ppm | 625 ppm | 1,250 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt | 23.5 ± 0.3 | 23.2 ± 0.3 | 22.6 ± 0.5 | 23.2 ± 0.8 | 23.3 ± 0.3 | 22.5 ± 0.2
Heart
Absolute | 0.15 ± 0.01 | 0.13 ± 0.00^**^ | 0.13 ± 0.01^**^ | 0.13 ± 0.01^**^ | 0.13 ± 0.01^**^ | 0.12 ± 0.00^**^
Relative | 6.559 ± 0.384 | 5.403 ± 0.140^*^ | 5.721 ± 0.251 | 5.662 ± 0.205 | 5.466 ± 0.229^*^ | 5.265 ± 0.199^**^
R. Kidney
Absolute | 0.19 ± 0.01 | 0.19 ± 0.00 | 0.19 ± 0.01 | 0.19 ± 0.01 | 0.20 ± 0.01 | 0.19 ± 0.00
Relative | 8.012 ± 0.253 | 7.980 ± 0.115 | 8.208 ± 0.308 | 8.205 ± 0.217 | 8.442 ± 0.391 | 8.326 ± 0.237
Liver
Absolute | 1.39 ± 0.05 | 1.28 ± 0.03 | 1.31 ± 0.03 | 1.35 ± 0.05 | 1.39 ± 0.02 | 1.29 ± 0.02
Relative | 59.293 ± 1.345 | 55.090 ± 1.226^*^ | 58.075 ± 0.925 | 57.978 ± 0.943 | 59.744 ± 0.834 | 57.344 ± 1.061
Lung
Absolute | 0.20 ± 0.01 | 0.20 ± 0.01 | 0.18 ± 0.01 | 0.19 ± 0.01 | 0.19 ± 0.01 | 0.18 ± 0.01
Relative | 8.487 ± 0.323 | 8.489 ± 0.309 | 8.123 ± 0.234 | 7.962 ± 0.150 | 7.942 ± 0.283 | 8.022 ± 0.319
R. Testis
Absolute | 0.081 ± 0.004 | 0.080 ± 0.004 | 0.084 ± 0.004 | 0.081 ± 0.003 | 0.082 ± 0.003 | 0.078 ± 0.004
Relative | 3.459 ± 0.141 | 3.458 ± 0.115 | 3.714 ± 0.134 | 3.491 ± 0.121 | 3.501 ± 0.108 | 3.461 ± 0.170
Thymus
Absolute | 0.074 ± 0.005 | 0.073 ± 0.004 | 0.064 ± 0.008 | 0.062 ± 0.004 | 0.078 ± 0.007 | 0.063 ± 0.004
Relative | 3.132 ± 0.196 | 3.166 ± 0.174 | 2.826 ± 0.392 | 2.668 ± 0.109 | 3.358 ± 0.284 | 2.807 ± 0.196
Female
Necropsy body wt | 20.3 ± 0.4 | 19.2 ± 0.4 | 20.1 ± 0.3 | 20.2 ± 0.5 | 19.1 ± 0.6 | 19.5 ± 0.5
Heart
Absolute | 0.12 ± 0.00 | 0.12 ± 0.01 | 0.12 ± 0.00 | 0.13 ± 0.01 | 0.13 ± 0.01 | 0.11 ± 0.00
Relative | 5.990 ± 0.114 | 6.037 ± 0.326 | 5.788 ± 0.163 | 6.498 ± 0.440 | 6.885 ± 0.589 | 5.669 ± 0.163
R. Kidney
Absolute | 0.16 ± 0.01 | 0.15 ± 0.01 | 0.16 ± 0.00 | 0.16 ± 0.00 | 0.15 ± 0.00 | 0.16 ± 0.01
Relative | 7.876 ± 0.340 | 8.041 ± 0.297 | 7.740 ± 0.191 | 7.709 ± 0.256 | 7.574 ± 0.193 | 8.092 ± 0.168
Liver
Absolute | 1.18 ± 0.03 | 1.09 ± 0.04 | 1.11 ± 0.02 | 1.16 ± 0.04 | 1.15 ± 0.04 | 1.14 ± 0.05
Relative | 58.099 ± 1.034 | 56.813 ± 1.411 | 55.333 ± 0.719 | 57.069 ± 0.912 | 60.165 ± 3.511 | 58.299 ± 1.831
Lung
Absolute | 0.18 ± 0.01 | 0.17 ± 0.01 | 0.18 ± 0.01 | 0.22 ± 0.03 | 0.21 ± 0.02 | 0.17 ± 0.01
Relative | 9.070 ± 0.353 | 8.840 ± 0.342 | 9.052 ± 0.301 | 10.821 ± 1.240 | 10.902 ± 1.596 | 8.702 ± 0.278
Thymus
Absolute | 0.090 ± 0.005 | 0.084 ± 0.003 | 0.086 ± 0.003 | 0.086 ± 0.003 | 0.074 ± 0.011 | 0.087 ± 0.003
Relative | 4.435 ± 0.182 | 4.348 ± 0.109 | 4.293 ± 0.142 | 4.274 ± 0.212 | 3.815 ± 0.514 | 4.453 ± 0.123

* Significantly different (P≤0.05) from the control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE C2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Heterozygous F1 p53^+/−^ Mice in the 40-Week Feed Study of Senna^a^

| 0 ppm | 100 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
n | 25 | 24 | 25 | 25 | 23 | 24
Necropsy body wt | 50.1 ± 0.7 | 50.4 ± 0.5 | 51.9 ± 0.6 | 49.0 ± 0.9 | 50.7 ± 0.8 | 48.0 ± 0.6
Heart
Absolute | 0.21 ± 0.01 | 0.24 ± 0.01 | 0.24 ± 0.01^*^ | 0.21 ± 0.01 | 0.21 ± 0.01 | 0.20 ± 0.01
Relative | 4.236 ± 0.111 | 4.673 ± 0.142 | 4.589 ± 0.136 | 4.215 ± 0.147 | 4.175 ± 0.115 | 4.237 ± 0.124
R. Kidney
Absolute | 0.41 ± 0.01 | 0.42 ± 0.01 | 0.44 ± 0.01 | 0.39 ± 0.01 | 0.41 ± 0.01 | 0.39 ± 0.01
Relative | 8.151 ± 0.147 | 8.232 ± 0.226 | 8.460 ± 0.151 | 8.021 ± 0.171 | 8.058 ± 0.156 | 8.216 ± 0.133
Liver
Absolute | 2.42 ± 0.08 | 2.36 ± 0.08 | 2.66 ± 0.10 | 2.31 ± 0.10 | 2.40 ± 0.11 | 2.07 ± 0.04^**^
Relative | 48.167 ± 1.188 | 46.553 ± 1.208 | 50.897 ± 1.553 | 46.753 ± 1.485 | 46.940 ± 1.620 | 43.060 ± 0.499^**^
Lung
Absolute | 0.37 ± 0.01 | 0.37 ± 0.01 | 0.40 ± 0.01^b^ | 0.34 ± 0.01 | 0.37 ± 0.02 | 0.36 ± 0.02
Relative | 7.401 ± 0.262 | 7.286 ± 0.278 | 7.669 ± 0.251^b^ | 6.984 ± 0.309 | 7.325 ± 0.255 | 7.521 ± 0.298
R. Testis
Absolute | 0.112 ± 0.001 | 0.111 ± 0.002 | 0.113 ± 0.002 | 0.108 ± 0.001 | 0.111 ± 0.002 | 0.113 ± 0.001
Relative | 2.242 ± 0.044 | 2.201 ± 0.029 | 2.173 ± 0.029 | 2.231 ± 0.048 | 2.206 ± 0.040 | 2.353 ± 0.036
Thymus
Absolute | 0.069 ± 0.005 | 0.064 ± 0.006 | 0.061 ± 0.004 | 0.064 ± 0.006 | 0.062 ± 0.005 | 0.058 ± 0.003
Relative | 1.359 ± 0.098 | 1.271 ± 0.109 | 1.185 ± 0.075 | 1.297 ± 0.116 | 1.207 ± 0.098 | 1.200 ± 0.055
Female
n | 23 | 23 | 23 | 22 | 22 | 24
Necropsy body wt | 42.8 ± 0.9 | 42.3 ± 0.8 | 41.1 ± 0.7 | 42.2 ± 0.9 | 41.8 ± 0.6 | 39.8 ± 0.7^*^
Heart
Absolute | 0.17 ± 0.01 | 0.18 ± 0.01 | 0.17 ± 0.00 | 0.17 ± 0.01 | 0.16 ± 0.00 | 0.17 ± 0.00
Relative | 4.107 ± 0.204 | 4.307 ± 0.207 | 4.249 ± 0.097 | 4.073 ± 0.157 | 3.948 ± 0.100 | 4.326 ± 0.139
R. Kidney
Absolute | 0.24 ± 0.00 | 0.24 ± 0.00 | 0.24 ± 0.00 | 0.24 ± 0.01 | 0.24 ± 0.00 | 0.24 ± 0.01
Relative | 5.670 ± 0.124 | 5.717 ± 0.126 | 5.790 ± 0.120 | 5.726 ± 0.153 | 5.810 ± 0.107 | 6.092 ± 0.135
Liver
Absolute | 1.64 ± 0.03 | 1.70 ± 0.04 | 1.63 ± 0.03 | 1.69 ± 0.03 | 1.70 ± 0.04 | 1.72 ± 0.03
Relative | 38.561 ± 0.870 | 40.364 ± 1.031 | 39.909 ± 0.803 | 40.276 ± 0.901 | 40.711 ± 0.685 | 43.492 ± 0.770^**^
Lung
Absolute | 0.32 ± 0.01 | 0.35 ± 0.01 | 0.33 ± 0.01 | 0.32 ± 0.01 | 0.33 ± 0.01 | 0.32 ± 0.01
Relative | 7.593 ± 0.374 | 8.396 ± 0.318 | 8.138 ± 0.298 | 7.616 ± 0.284 | 7.945 ± 0.276 | 8.175 ± 0.375
Thymus
Absolute | 0.060 ± 0.003^c^ | 0.049 ± 0.003 | 0.055 ± 0.003 | 0.058 ± 0.004 | 0.053 ± 0.003 | 0.052 ± 0.003
Relative | 1.413 ± 0.081^c^ | 1.160 ± 0.070 | 1.348 ± 0.074 | 1.365 ± 0.079 | 1.263 ± 0.081 | 1.300 ± 0.060

* Significantly different (P≤0.05) from the control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

b n=24

c n=22