# APPENDIX B GENETIC TOXICOLOGY

TABLE B1 Mutagenicity of Senna in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | With 30% hamster S9 | With 30% hamster S9 | With 30% hamster S9 | With 30% hamster S9
Assay performed at SRI International (sample one)
TA100 | 0 | 90 ± 1 | 113 ± 14 | 95 ± 10 | 122 ± 4 | 126 ± 7
TA100 | 100 | 94 ± 3 | 95 ± 4
TA100 | 333 | 105 ± 5 | 130 ± 4
TA100 | 1,000 | 90 ± 4 | 119 ± 10 | 103 ± 7 | 131 ± 4 | 111 ± 3
TA100 | 3,333 | 89 ± 9^b^ | 123 ± 12^b^ | 91 ± 3 | 144 ± 6 | 146 ± 8
TA100 | 6,666 | | | 103 ± 5 | 158 ± 5 | 174 ± 12
TA100 | 10,000 | 74 ± 1^b^ | 165 ± 3^b^ | 138 ± 6 | 174 ± 9 | 186 ± 8
TA100 | 16,666 | | | 121 ± 9 | 199 ± 12 | 195 ± 4
| | | | | Weakly | Weakly
Trial summary | | Negative | Equivocal | Equivocal | Positive | Positive
Positive control^c^ | | 1,569 ± 22 | 676 ± 63 | 610 ± 26 | 775 ± 25 | 561 ± 39
| | With 30% rat S9 | With 30% rat S9 | With 30% rat S9 | With 30% rat S9
TA100 (continued) | 0 | 134 ± 10 | 120 ± 7 | 145 ± 2 | 135 ± 10
TA100 (continued) | 100 | 140 ± 9
TA100 (continued) | 333 | 135 ± 2
TA100 (continued) | 1,000 | 134 ± 3 | 121 ± 12 | 151 ± 5 | 145 ± 10
TA100 (continued) | 3,333 | 154 ± 3^b^ | 133 ± 1 | 151 ± 8 | 174 ± 1
TA100 (continued) | 6,666 | | 129 ± 5 | 172 ± 9 | 209 ± 12
TA100 (continued) | 10,000 | 166 ± 9 | 144 ± 7 | 204 ± 8 | 238 ± 12
TA100 (continued) | 16,666 | | 142 ± 4 | 248 ± 18 | 231 ± 18^d^
| | | | Weakly | Weakly
Trial summary | | Negative | Negative | Positive | Positive
Positive control | | 488 ± 9 | 474 ± 17 | 470 ± 12 | 396 ± 13
| | Without S9 | With 30% hamster S9 | With 30% hamster S9 | With 30% hamster S9 | With 30% hamster S9 | With 30% hamster S9
TA98 | 0 | 24 ± 4 | 25 ± 6 | 26 ± 3 | 25 ± 4 | 24 ± 3 | 18 ± 3
TA98 | 100 | 28 ± 2 | 21 ± 4 | 12 ± 3 | 20 ± 2 | 21 ± 3
TA98 | 333 | 25 ± 3 | 24 ± 4 | 18 ± 3 | 20 ± 3 | 16 ± 1
TA98 | 1,000 | 27 ± 2 | 28 ± 5 | 24 ± 4 | 28 ± 1 | 35 ± 4 | 30 ± 1
TA98 | 1,666 | | | | | | 35 ± 2
TA98 | 3,333 | 24 ± 1^b^ | 51 ± 4^b^ | 39 ± 7 | 47 ± 8 | 71 ± 3 | 59 ± 4
TA98 | 6,666 | | | | | | 75 ± 1
TA98 | 10,000 | 26 ± 2^b^ | 70 ± 2^b^ | 50 ± 1 | 101 ± 9 | 137 ± 5 | 117 ± 8
Trial summary | | Negative | Positive | Positive | Positive | Positive | Positive
Positive control | | 557 ± 17 | 308 ± 22 | 529 ± 43 | 417 ± 13 | 354 ± 17 | 272 ± 8
| Dose (Mg/plate) | With 30% rat S9 | With 30% rat S9 | With 30% rat S9 | With 30% rat S9 | With 30% rat S9
TA98 (continued) | 0 | 41 ± 2 | 21 ± 3 | 31 ± 2 | 36 ± 2 | 38 ± 3
TA98 (continued) | 100 | 32 ± 5 | 24 ± 4 | 30 ± 4 | 33 ± 4
TA98 (continued) | 333 | 21 ± 1 | 23 ± 5 | 29 ± 5 | 30 ± 4
TA98 (continued) | 1,000 | 24 ± 3 | 31 ± 1 | 26 ± 1 | 34 ± 3 | 54 ± 2
TA98 (continued) | 1,666 | | | | | 64 ± 12
TA98 (continued) | 3,333 | 82 ± 6^b^ | 34 ± 4 | 69 ± 4 | 107 ± 11 | 121 ± 11
TA98 (continued) | 6,666 | | | | | 150 ± 7
TA98 (continued) | 10,000 | 77 ± 39^e^ | 59 ± 9 | 167 ± 9 | 237 ± 16 | 143 ± 14
Trial summary | | Positive | Positive | Positive | Positive | Positive
Positive control | | 122 ± 13 | 119 ± 6 | 133 ± 9 | 104 ± 10 | 81 ± 3
Assay performed at BioReliance Corporation (sample two)
| | Without S9 | Without S9 | With 10% hamster S9 | With 30% hamster S9 | With 10% rat S9 | With 30% rat S9
TA100 | 0 | 108 ± 3 | 168 ± 4 | 190 ± 17 | 105 ± 2 | 181 ± 4 | 120 ± 1
TA100 | 100 | 110 ± 7^b^ | 198 ± 9^b^ | 173 ± 3^b^ | 109 ± 3^b^ | 216 ± 6^b^ | 109 ± 3^b^
TA100 | 333 | 122 ± 8^b^ | 241± 27^b^ | 201 ± 4^b^ | 116 ± 3^b^ | 216 ± 8^b^ | 114 ± 6^b^
TA100 | 1,000 | 109 ± 1^b^ | 201 ± 10^b^ | 211 ±36^b^ | 114 ± 3^b^ | 230 ± 13^b^ | 111 ± 3^b^
TA100 | 3,333 | 107 ± 2^b^ | 221 ± 9^b^ | 190 ± 4^b^ | 115 ± 6^b^ | 197 ± 11^b^ | 129 ± 10^b^
TA100 | 10,000 | 106 ± 1^b^ | 192 ± 8^b^ | 193 ± 3^b^ | 119 ± 6^b^ | 195 ± 10^b^ | 106 ± 2^b^
Trial summary | | Negative | Equivocal | Negative | Negative | Negative | Negative
Positive control | | 606 ± 3 | 511 ± 19 | 1,291 ± 70 | 842 ± 41 | 915 ± 28 | 632 ± 14
TA1535 | 0 | 10 ± 5^e^ | 12 ± 2 | 9 ± 2 | 13 ± 1 | 15 ± 3 | 16 ± 0
TA1535 | 100 | 17 ± 1^b^ | 11 ± 3^b^ | 11 ± 2^b^ | 15 ± 1^b^ | 8 ± 1^b^ | 17 ± 1^b^
TA1535 | 333 | 16 ± 1^b^ | 10 ± 2^b^ | 12 ± 0^b^ | 14 ± 1^b^ | 10 ± 1^b^ | 17 ± 1^b^
TA1535 | 1,000 | 15 ± 0^b^ | 12 ± 2^b^ | 12 ± 3^b^ | 16 ± 2^b^ | 12 ± 3^b^ | 16 ± 1^b^
TA1535 | 3,333 | 18 ± 1^b^ | 12 ± 1^b^ | 9 ± 0^b^ | 16 ± 0^b^ | 8 ± 0^b^ | 16 ± 0^b^
TA1535 | 10,000 | 16 ± 0^b^ | 14 ± 2^b^ | 11 ± 2^b^ | 17 ± 1^b^ | 13 ± 1^b^ | 16 ± 1^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 655 ± 27 | 244 ± 11 | 145 ± 10 | 494 ± 62 | 70 ± 2 | 79 ± 4
TA97 | 0 | 91 ± 6 | 140 ± 22 | 177 ± 3 | 101 ± 4 | 144 ± 16 | 108 ± 4
TA97 | 100 | 108 ± 5^b^ | 200 ± 2^b^ | 150 ± 5^b^ | 97 ± 4^b^ | 164 ± 6^b^ | 115 ± 7^b^
TA97 | 333 | 111 ± 2^b^ | 198 ± 3^b^ | 163 ± 5^b^ | 101 ± 1^b^ | 180± 10^b^ | 116 ± 7^b^
TA97 | 1,000 | 106 ± 1^b^ | 196 ± 9^b^ | 170 ± 4^b^ | 119 ± 5^b^ | 189 ± 4^b^ | 105 ± 1^b^
TA97 | 3,333 | 111 ± 4^b^ | 189 ± 5^b^ | 166 ± 2^b^ | 121 ± 4^b^ | 191 ± 2^b^ | 119 ± 7^b^
TA97 | 10,000 | 122 ± 8^b^ | 193 ± 4^b^ | 174 ± 4^b^ | 120 ± 9^b^ | 193 ± 6^b^ | 114 ± 3^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 982 ±172 | 714 ± 80 | 1,456 ± 33 | 1,700 ± 34 | 1,741 ± 109 | 534 ± 74
| Dose (μg/plate) | Without S9 | Without S9 | With 10% hamster S9 | With 10% hamster S9 | With 30% hamster S9
TA98 | 0 | 13 ± 0 | 13 ± 1 | 22 ± 2 | 19 ± 2 | 11 ± 1
TA98 | 100 | 13 ± 1^b^ | 13 ± 2^b^ | 18 ± 1^b^ | 24 ± 5^b^ | 11 ± 1^b^
TA98 | 333 | 14 ± 0^b^ | 12 ± 1^b^ | 17 ± 1^b^ | 20 ± 7^b^ | 16 ± 1^b^
TA98 | 1,000 | 14 ± 1^b^ | 17 ± 1^b^ | 31 ± 4^b^ | 21 ± 2^b^ | 13 ± 1^b^
TA98 | 3,333 | 16 ± 1^b^ | 15 ± 1^b^ | 40 ± 2^b^ | 21 ± 3^b^ | 15 ± 1^b^
TA98 | 10,000 | 16 ± 1^b^ | 16 ± 1^b^ | 38 ± 8^b^ | 28 ± 1^b^ | 17 ± 1
Trial summary | | Negative | Negative | Equivocal | Negative | Negative
Positive control | | 118 ± 3 | 115 ± 7 | 1,307 ± 61 | 817 ± 87 | 906 ± 56
| | With 10% rat S9 | With 30% rat S9
TA98 (continued) | 0 | 16 ± 4 | 13 ± 1
TA98 (continued) | 100 | 15 ± 2^b^ | 14 ± 2^b^
TA98 (continued) | 333 | 25 ± 3^b^ | 13 ± 1^b^
TA98 (continued) | 1,000 | 22 ± 5^b^ | 14 ± 0^b^
TA98 (continued) | 3,333 | 22 ± 1^b^ | 18 ± 1^b^
TA98 (continued) | 10,000 | 25 ± 2^b^ | 19 ± 1^b^
Trial summary | | Negative | Negative
Positive control | | 379 ± 12 | 191 ± 13

a Data are presented as revertants/plate (mean ± standard error) from three plates. The detailed protocol is presented by Zeiger et al. (1992). 0 μg/plate was the solvent control.

b Precipitate on plate

c The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535), 9-aminoacridine (TA97), and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.

d Contamination

e Slight toxicity and precipitate on plate

TABLE B2 Mutagenicity of Senna in Bacterial Tester Strains^a^

Strain | Dose (Mg/plate) | Without S9 | Without S9 | With 10% rat S9 | With 10% rat S9 | With 30% rat S9 | With 30% rat S9
Assay performed at SITEK Research Laboratories (sample three)
TA100 | 0 | 99 ± 6 | 83 ± 3 | 63 ± 4 | 60 ± 0
TA100 | 10 | 80 ± 6 | 61 ± 2 | 61 ± 3 | 58 ± 1
TA100 | 25 | 82 ± 2 | 65 ± 8 | 73 ± 5 | 56 ± 3
TA100 | 50 | 71 ± 3 | 61 ± 7 | 77 ± 4 | 62 ± 4
TA100 | 100 | 80 ± 4 | 46 ± 2 | 64 ± 4 | 48 ± 3
TA100 | 250 | 104 ± 5 | 56 ± 5 | 65 ± 1 | 36 ± 5
Trial summary | | Negative | Negative | Negative | Negative
Positive control^b^ | | 274 ± 28 | 556 ± 21 | 498 ± 27 | 936 ± 167
TA98 | 0 | 26 ± 4 | 25 ± 2 | 32 ± 2 | 42 ± 6 | 34 ± 4 | 51 ± 4
TA98 | 10 | 28 ± 4 | 22 ± 2 | 29 ± 1 | 28 ± 4 | 37 ± 5 | 46 ± 10
TA98 | 25 | 24 ± 3 | 25 ± 2 | 23 ± 4 | 22 ± 2 | 26 ± 8 | 62 ± 4
TA98 | 50 | 40 ± 5 | 26 ± 1 | 24 ± 1 | 34 ± 1 | 42 ± 1 | 56 ± 8
TA98 | 100 | 23 ± 5 | 20 ± 1 | 18 ± 1 | 28 ± 4 | 35 ± 7 | 42 ± 8
TA98 | 250 | 28 ± 4 | 18 ± 1 | 17 ± 2 | 22 ± 2 | 29 ± 1 | 39 ± 8
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 432 ± 27 | 431 ± 19 | 1,102 ± 31 | 544 ± 35 | 285 ± 7 | 317 ± 23
Escherichia coli WP2 uvrA/pKM101
| 0 | 160 ± 15 | 166 ± 5 | 219 ± 10 | 206 ± 5
| 10 | 202 ± 7 | 202 ± 7 | 235 ± 12 | 330 ± 12
| 25 | 205 ± 9 | 208 ± 49 | 287 ± 13 | 244 ± 16
| 50 | 163 ± 5 | 116 ± 12 | 206 ± 5 | 186 ± 12
| 100 | 176 ± 9 | 107 ± 4 | 219 ± 5 | 153 ± 3
| 250 | 219 ± 23 | 53 ± 1 | 270 ± 21 | 126 ± 10
Trial summary | | Negative | Negative | Negative | Equivocal
Positive control | | 1,568 ± 66 | 1,734 ± 46 | 824 ± 47 | 906 ± 29
Assay performed at ILS, Inc. (sample four)
TA100 | 0 | 110 ± 9 | 76 ± 6 | 77 ± 9 | 111 ± 7
TA100 | 125 | 108 ± 8 | 87 ± 4 | 89 ± 2 | 97 ± 1
TA100 | 250 | 104 ± 3^c^ | 84 ± 3 | 80 ± 3 | 103 ± 10^c^
TA100 | 500 | 141 ± 6^c^ | 91 ± 11 | 93 ± 4^c^ | 139 ± 3^c^
TA100 | 1,500 | 105 ± 11^c^ | 91 ± 6^c^ | 119 ± 6^c^ | 125 ± 6^c^
TA100 | 3,000 | 130 ± 3^c^ | 95 ± 3^c^ | 132 ± 3^c^ | 161 ± 6^c^
TA100 | 6,000 | 120± 11^c^ | 97 ± 3^c^ | 142 ± 6^c^ | 165 ± 2^c^
| | | | Weakly | Weakly
Trial summary | | Negative | Negative | Positive | Positive
Positive control | | 858 ± 48 | 665 ± 54 | 2,065 ± 90 | 1,889 ± 34
TA98 | 0 | 21 ± 3 | 24 ± 2 | 31 ± 4 | 30 ± 3
TA98 | 125 | 22 ± 2 | 23 ± 2 | 34 ± 1 | 23 ± 3
TA98 | 250 | 22 ± 4^c^ | 25 ± 2 | 35 ± 2 | 44 ± 6^c^
TA98 | 500 | 19 ± 2^c^ | 30 ± 1^c^ | 49 ± 6^c^ | 50 ± 3^c^
TA98 | 1,500 | 22 ± 3^c^ | 36 ± 2^c^ | 64 ± 9^c^ | 48 ± 5^c^
TA98 | 3,000 | 36 ± 3^c^ | 31 ± 3^c^ | 80 ± 9^c^ | 68 ± 14^c^
TA98 | 6,000 | 59 ± 6^c^ | 63 ± 14^c^ | 90 ± 5^c^ | 85 ± 7^c^
| | | Weakly
Trial summary | | Positive | Positive | Positive | Positive
Positive control | | 735 ± 11 | 611 ± 21 | 1,990 ± 168 | 1,456 ± 20
Escherichia coli WP2 uvrA/pKM101
| 0 | 182 ± 6 | 192 ± 18 | 231 ± 3 | 243 ± 16
| 125 | 175 ± 9 | 188 ± 12 | 232 ± 14 | 206 ± 10
| 250 | 161 ± 6 | 172 ± 5 | 204 ± 8 | 222 ± 7
| 500 | 161 ± 10 | 140 ± 9^c^ | 225 ± 19 | 223 ± 4^c^
| 1,500 | 158 ± 11^c^ | 133 ± 14^c^ | 185 ± 44^c^ | 165 ± 7^c^
| 3,000 | 155 ± 9^c^ | 136 ± 4^c^ | 158 ± 17^c^ | 177 ± 8^c^
| 6,000 | 156 ± 10^c^ | 172 ± 20^c^ | 204 ± 6^c^ | 170 ± 9^c^
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 1,302 ± 38 | 1,066 ± 47 | 1,740 ± 17 | 1,552 ± 31

a Assays using two different samples from the same lot of senna that was used in the 40-week study. Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent control.

b The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

c Precipitate on plate

TABLE B3 Mutagenicity of Rhein in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | With 30% hamster S9 | With 30% hamster S9 | With 30% rat S9 | With 30% rat S9
TA100 | 0 | 85 ± 3 | 101 ± 6 | 119 ± 5 | 129 ± 5 | 104 ± 10
TA100 | 3 | 85 ± 3
TA100 | 10 | 94 ± 5 | 134 ± 8 | | 131 ± 6
TA100 | 33 | 94 ± 5 | 122 ± 5 | 100 ± 3 | 120 ± 5 | 116 ± 18
TA100 | 66 | | | 140 ± 3 | | 134 ± 2
TA100 | 100 | 91 ± 4 | 140 ± 6 | 172 ± 14 | 138 ± 7 | 156 ± 4
TA100 | 166 | | | 198 ± 9 | | 191 ± 4
TA100 | 333 | 66 ± 5 | 200 ± 47 | 208 ± 8 | 169 ± 14 | 225 ± 19
TA100 | 666 | | 246 ± 26 | 180 ± 3 | 219 ± 35 | 74 ± 12
Trial summary | | Negative | Positive | Positive | Positive | Positive
Positive control^b^ | | 1,569 ± 22 | 676 ± 63 | 696 ± 31 | 488 ± 9 | 430 ± 20
TA98 | 0 | 19 ± 2 | 33 ± 2 | 21 ± 2 | 45 ± 3 | 26 ± 5
TA98 | 3 | 21 ± 2
TA98 | 10 | 24 ± 3 | 22 ± 2 | | 41 ± 7
TA98 | 33 | 26 ± 3 | 28 ± 0 | 21 ± 3 | 42 ± 6 | 37 ± 2
TA98 | 66 | | | 29 ± 4 | | 48 ± 4
TA98 | 100 | 23 ± 1 | 30 ± 2 | 44 ± 2 | 45 ± 3 | 61 ± 4
TA98 | 166 | | | 57 ± 14 | | 78 ± 9
TA98 | 333 | 27 ± 2 | 94 ± 8 | 68 ± 12 | 72 ± 5 | 111 ± 7
TA98 | 666 | | 124 ± 11 | 98 ± 8 | 143 ± 12 | 73 ± 5
Trial summary | | Negative | Positive | Positive | Positive | Positive
Positive control | | 557 ± 17 | 308 ± 22 | 549 ± 19 | 122 ± 13 | 144 ± 6

a Study was performed at SRI International. Data are presented as revertants/plate (mean ± standard error) from three plates. The detailed protocol is presented by Zeiger et al. (1992). 0 μg/plate was the solvent control.

b The positive controls in the absence of metabolic activation were sodium azide (TA100) and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with both strains was 2-aminoanthracene.

TABLE B4 Mutagenicity of Chrysophanic Acid in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | With 10% hamster S9 | With 10% hamster S9 | With 30% hamster S9 | With 5% hamster S9 | With 5% hamster S9
TA100 | 0 | 111 ± 6 | 86 ± 3 | 118 ± 14 | 107 ± 10 | 98 ± 5 | 121 ± 3
TA100 | 1 | 115 ± 5
TA100 | 3 | 91 ± 6 | | 108 ± 6 | | | 110 ± 11
TA100 | 10 | 94 ± 3 | 105 ± 15 | 126 ± 8 | 134 ± 10 | 104 ± 13 | 144 ± 16
TA100 | 16 | | | 138 ± 1 | | | 133 ± 10
TA100 | 33 | 86 ± 6 | 126 ± 7 | 143 ± 6 | 122 ± 10 | 131 ± 8 | 155 ± 3
TA100 | 66 | | | 148 ± 8 | | | 142 ± 5
TA100 | 100 | 83 ± 3 | 132 ± 5 | 127 ± 4 | 152 ± 1 | 124 ± 5 | 99 ± 13
TA100 | 166 | | | 134 ± 2 | | | 124 ± 7
TA100 | 333 | | 123 ± 8 | 114 ± 8 | 160 ± 11 | 112 ± 7 | 132 ± 9
TA100 | 666 | | 118 ± 6^b^ | | 165 ± 10^b^ | 81 ± 3^b^
| | | | | Weakly
Trial summary | | Negative | Equivocal | Negative | Positive | Negative | Negative
Positive control^c^ | | 1,384 ± 50 | 856 ± 73 | 987 ± 39 | 590 ± 26 | 1,458 ± 109 | 1,058 ± 14
| | With 30% hamster S9 | With 30% hamster S9 | With 10% rat S9 | With 10% rat S9 | With 5% rat S9 | With 5% rat S9
TA100 (continued) | 0 | 125 ± 8 | 132 ± 10 | 99 ± 12 | 114 ± 13 | 95 ± 11 | 105 ± 17
TA100 (continued) | 3 | | 129 ± 10 | | 130 ± 8 | | 131 ± 11
TA100 (continued) | 10 | 102 ± 7 | 147 ± 3 | 126 ± 6 | 134 ± 4 | 94 ± 4 | 158 ± 6
TA100 (continued) | 16 | | 146 ± 4 | | 163 ± 2 | | 157 ± 3
TA100 (continued) | 33 | 125 ± 9 | 151 ± 12 | 145 ± 10 | 157 ± 8 | 135 ± 6 | 147 ± 8
TA100 (continued) | 66 | | 162 ± 9 | | 166 ± 4 | | 142 ± 7
TA100 (continued) | 100 | 145 ± 11 | 156 ± 10 | 169 ± 5 | 163 ± 8 | 148 ± 3 | 124 ± 12
TA100 (continued) | 166 | | 157 ± 2 | | 151 ± 13 | | 134 ± 10
TA100 (continued) | 333 | 154 ± 3 | 123 ± 7 | 148 ± 4 | 137 ± 6 | 107 ± 4 | 109 ± 7
TA100 (continued) | 666 | 142 ± 12^b^ | | 121 ± 4^b^ | | 98 ± 2^b^
| | | | Weakly
Trial summary | | Negative | Negative | Positive | Equivocal | Equivocal | Equivocal
Positive control | | 696 ± 31 | 731 ± 40 | 369 ± 18 | 477 ± 35 | 706 ± 33 | 908 ± 79
| | With 30% rat S9 | With 30% rat S9 | With 30% rat S9
TA100 (continued) | 0 | 135 ± 6 | 134 ± 5 | 119 ± 4
TA100 (continued) | 3 | | | 126 ± 7
TA100 (continued) | 10 | 154 ± 6 | 110 ± 11 | 147 ± 8
TA100 (continued) | 16 | | | 143 ± 4
TA100 (continued) | 33 | 139 ± 15 | 136 ± 5 | 145 ± 11
TA100 (continued) | 66 | | | 182 ± 4
TA100 (continued) | 100 | 189 ± 13 | 154 ± 10 | 178 ± 10
TA100 (continued) | 166 | | | 177 ± 12
TA100 (continued) | 333 | 193 ± 7 | 156 ± 6 | 178 ± 11
TA100 (continued) | 666 | 185 ± 18^b^ | 146 ± 4^b^
| | Weakly
Trial summary | | Positive | Negative | Equivocal
Positive control | | 393 ± 23 | 430 ± 20 | 434 ± 25
| Dose (μg/plate) | Without S9 | With 30% hamster S9 | With 30% rat S9
TA98 | 0 | 20 ± 1 | 21 ± 3 | 40 ± 5
TA98 | 1 | 22 ± 0
TA98 | 3 | 14 ± 3
TA98 | 10 | 10 ± 1 | 20 ± 4 | 32 ± 2
TA98 | 33 | 10 ± 1 | 27 ± 3 | 31 ± 4
TA98 | 100 | 13 ± 0 | 29 ± 1 | 35 ± 2
TA98 | 333 | | 28 ± 3 | 31 ± 2
TA98 | 666 | | 28 ± 2^b^ | 37 ± 6^b^
Trial summary | | Negative | Negative | Negative
Positive control | | 515 ± 29 | 482 ± 30 | 138 ± 13
| | With 10% hamster S9 | With 30% hamster S9 | With 5% hamster S9 | With 10% rat S9 | With 30% rat S9 | With 5% rat S9
TA1535 | 0 | 7 ± 1 | 7 ± 2 | 6 ± 1 | 5 ± 1 | 6 ± 2 | 5 ± 2
TA1535 | 3 | 5 ± 1 | 7 ± 1 | 7 ± 1 | 4 ± 2 | 4 ± 2 | 6 ± 1
TA1535 | 10 | 4 ± 1 | 7 ± 3 | 7 ± 1 | 3 ± 1 | 6 ± 1 | 5 ± 2
TA1535 | 16 | 6 ± 1 | 7 ± 2 | 4 ± 0 | 5 ± 1 | 6 ± 1 | 4 ± 1
TA1535 | 33 | 4 ± 2 | 9 ± 1 | 5 ± 1 | 7 ± 1 | 5 ± 1 | 4 ± 1
TA1535 | 66 | 6 ± 3 | 4 ± 1 | 6 ± 0 | 5 ± 0 | 7 ± 1 | 6 ± 1
TA1535 | 100 | 8 ± 2 | 7 ± 1 | 7 ± 1 | 7 ± 1 | 8 ± 1 | 9 ± 2
TA1535 | 166 | 6 ± 1 | 10 ± 1 | 8 ± 3 | 12 ± 2 | 10 ± 2 | 7 ± 1
TA1535 | 333 | 6 ± 1 | 9 ± 1 | 5 ± 0 | 13 ± 1 | 7 ± 2 | 8 ± 1
Trial summary | | Negative | Negative | Negative | Equivocal | Negative | Negative
Positive control | | 68 ± 6 | 109 ± 16 | 89 ± 9 | 36 ± 2 | 48 ± 4 | 51 ± 3

a Study was performed at ILS, Inc. Data are presented as revertants/plate (mean ± standard error) from three plates. This detailed protocol is presented by Zeiger et al. (1992). 0 μg/plate was the solvent control.

b Precipitate on plate

c The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535) and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.

TABLE B5 Mutagenicity of Sennoside A in Bacterial Tester Strains^a^

Strain | Dose (Mg/plate) | Without S9 | Without S9 | With 10% rat S9 | With 10% rat S9
TA100 | 0 | 94 ± 5 | 121 ± 5 | 112 ± 4 | 113 ± 4
TA100 | 12.5 | 112 ± 7 | 110 ± 3 | 116 ± 6 | 107 ± 7
TA100 | 50 | 87 ± 8 | 104 ± 4 | 119 ± 9 | 119 ± 9
TA100 | 125 | 91 ± 3 | 110 ± 6 | 105 ± 5 | 108 ± 2
TA100 | 500 | 105 ± 8 | 100 ± 9 | 121 ± 6 | 100 ± 4
TA100 | 1,500 | 102 ± 6 | 122 ± 5 | 113 ± 2 | 100 ± 4
TA100 | 6,000 | 85 ± 9 | 91 ± 4 | 109 ± 4 | 107 ± 7
Trial summary | | Negative | Negative | Negative | Negative
Positive control^b^ | | 823 ± 17 | 955 ± 35 | 2,374 ± 146 | 1,608 ± 112
TA98 | 0 | 36 ± 1 | 28 ± 5 | 45 ± 3 | 36 ± 1
TA98 | 12.5 | 28 ± 0 | 26 ± 2 | 43 ± 5 | 43 ± 5
TA98 | 50 | 34 ± 3 | 28 ± 1 | 40 ± 2 | 47 ± 6
TA98 | 125 | 35 ± 8 | 24 ± 5 | 51 ± 3 | 47 ± 6
TA98 | 500 | 29 ± 6 | 37 ± 4 | 41 ± 5 | 38 ± 4
TA98 | 1,500 | 28 ± 4 | 35 ± 12 | 36 ± 2 | 39 ± 5
TA98 | 6,000 | 27 ± 7 | 24 ± 1 | 23 ± 3 | 27 ± 6
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 598 ± 43 | 788 ± 36 | 1,690 ± 127 | 1,768 ± 71
Escherichia coli WP2 uvrA/pKM101
| 0 | 185 ± 9 | 170 ± 12 | 209 ± 10 | 211 ± 4
| 12.5 | 192 ± 6 | 184 ± 5 | 222 ± 3 | 212 ± 3
| 50 | 189 ± 6 | 172 ± 8 | 238 ± 15 | 212 ± 6
| 125 | 181 ± 9 | 190 ± 2 | 229 ± 6 | 234 ± 7
| 500 | 182 ± 9 | 175 ± 5 | 222 ± 13 | 224 ± 17
| 1,500 | 197 ± 11 | 191 ± 4 | 242 ± 3 | 219 ± 9
| 6,000 | 194 ± 5 | 176 ± 14 | 223 ± 9 | 219 ± 6
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 1,336 ± 63 | 1,166 ± 10 | 1,561 ± 26 | 1,654 ± 17

a Study was performed at ILS, Inc. Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent control.

b The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

TABLE B6 Mutagenicity of Sennoside B in Bacterial Tester Strains^a^

Strain | Dose (Mg/plate) | Without S9 | Without S9 | With 10% rat S9 | With 10% rat S9
TA100 | 0 | 104 ± 4 | 104 ± 3 | 105 ± 3 | 110 ± 10
TA100 | 12.5 | 113 ± 6 | 97 ± 9 | 102 ± 3 | 120 ± 1
TA100 | 50 | 105 ± 4 | 91 ± 3 | 101 ± 4 | 104 ± 2
TA100 | 125 | 104 ± 9 | 101 ± 7 | 103 ± 10 | 115 ± 5
TA100 | 500 | 103 ± 6 | 95 ± 5 | 96 ± 8 | 119 ± 15
TA100 | 1,500 | 101 ± 4 | 107 ± 4 | 87 ± 3 | 105 ± 3
TA100 | 6,000 | 96 ± 4 | 103 ± 3 | 85 ± 1 | 114 ± 4
Trial summary | | Negative | Negative | Negative | Negative
Positive control^b^ | | 824 ± 21 | 796 ± 11 | 1,662 ± 139 | 3,046 ± 65
TA98 | 0 | 29 ± 5 | 28 ± 5 | 38 ± 3 | 37 ± 3
TA98 | 12.5 | 21 ± 6 | 24 ± 4 | 48 ± 5 | 27 ± 2
TA98 | 50 | 21 ± 3 | 20 ± 4 | 42 ± 9 | 29 ± 1
TA98 | 125 | 22 ± 4 | 28 ± 3 | 47 ± 4 | 36 ± 3
TA98 | 500 | 22 ± 2 | 24 ± 4 | 37 ± 3 | 36 ± 5
TA98 | 1,500 | 26 ± 3 | 25 ± 1 | 37 ± 3 | 41 ± 5
TA98 | 6,000 | 23 ± 4 | 30 ± 4 | 29 ± 0 | 31 ± 3
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 688 ± 100 | 610 ± 17 | 1,956 ± 62 | 1,550 ± 72
Escherichia coli WP2 uvrA/pKM101
| 0 | 161 ± 7 | 179 ± 5 | 232 ± 14 | 196 ± 8
| 12.5 | 151 ± 10 | 140 ± 4 | 216 ± 9 | 212 ± 4
| 50 | 162 ± 2 | 165 ± 13 | 213 ± 15 | 213 ± 2
| 125 | 157 ± 5 | 192 ± 19 | 216 ± 7 | 194 ± 6
| 500 | 167 ± 4 | 183 ± 13 | 219 ± 5 | 198 ± 4
| 1,500 | 165 ± 3 | 191 ± 0 | 217 ± 9 | 202 ± 8
| 6,000 | 151 ± 9 | 198 ± 11 | 210 ± 14 | 191 ± 10
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 1,066 ± 36 | 1,225 ± 102 | 1,973 ± 111 | 1,629 ± 54

a Study was performed at ILS, Inc. Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent control.

b The positive controls in the absence of metabolic activation were sodium azide (TA100), 4 nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

TABLE B7 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Heterozygous F1 p53^+/−^ Male Mice Following Administration of Senna in Feed for 40 Weeks^a^

| Concentration (ppm) | Number of Mice with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Feed^d^ | 0 | 4 | 3.24 ± 0.17 | | 1.67 ± 0.04 | | 1.961 ± 0.20
Senna | 100 | 4 | 2.98 ± 0.25 | 0.5766 | 1.70 ± 0.09 | 0.5196 | 2.582 ± 0.81 | 1.000
Senna | 300 | 4 | 4.13 ± 0.61 | 0.3897 | 1.64 ± 0.02 | 0.6045 | 2.098 ± 0.35 | 1.000
Senna | 1,000 | 3 | 3.42 ± 0.45 | 0.4383 | 1.65 ± 0.06 | 0.6544 | 1.955 ± 0.07 | 1.000
Senna | 3,000 | 5 | 3.79 ± 0.72 | 0.4127 | 1.72 ± 0.11 | 0.4288 | 1.643 ± 0.22 | 1.000
Senna | 10,000 | 5 | 2.93 ± 0.17 | 0.4202 | 1.84 ± 0.04 | 0.0847 | 2.778 ± 0.76 | 0.442
Senna | | | P=0.825^e^ | | P=0.016^e^ | | P=0.360^e^

a Study was performed at ILS, Inc. The detailed protocol is presented by Dertinger et al. (2004) and Witt et al. (2008). NCE=normochromatic erythrocyte; PCE=polychromatic erythrocyte

b Mean ± standard error

c Pairwise comparison with the control group; exposed group values are significant at P≤0.025 by Williams’ test.

d Control

e Significance tested by linear regression; significant at P≤0.025