# APPENDIX A SUMMARY OF LESIONS IN HETEROZYGOUS F1 p53^+/−^ MICE IN THE 40-WEEK FEED STUDY OF SENNA

TABLE A1 Summary of the Incidence of Neoplasms in Male Heterozygous F1 p53^+/−^ Mice in the 40-Week Feed Study of Senna^a^

| 0 ppm | 100 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Disposition Summary
Animals initially in study | 25 | 25 | 25 | 25 | 25 | 25
Early deaths
Natural deaths | | 1 | | | 2 | 1
Survivors
Terminal sacrifice | 25 | 24 | 25 | 25 | 23 | 24
Animals examined microscopically | 25 | 25 | 25 | 25 | 25 | 25
Alimentary System
Intestine large, cecum | (25) | (25) | (25) | (25) | (23) | (25)
Intestine large, colon | (25) | (25) | (25) | (25) | (24) | (25)
Intestine large, rectum | (24) | (25) | (25) | (25) | (24) | (25)
Intestine small, duodenum | (25) | (25) | (25) | (25) | (23) | (25)
Intestine small, jejunum | (25) | (25) | (25) | (25) | (23) | (24)
Liver | (25) | (25) | (25) | (25) | (25) | (25)
Hemangiosarcoma, metastatic, heart | | 1 (4%)
Hepatocellular adenoma | 1 (4%) | | 5 (20%) | | 1 (4%) | 1 (4%)
Hepatocellular adenoma, multiple | | | | | 1 (4%)
Pancreas | (25) | (25) | (25) | (25) | (25) | (25)
Hemangiosarcoma, metastatic, heart | | 1 (4%)
Stomach, forestomach | (25) | (25) | (25) | (25) | (25) | (25)
Stomach, glandular | (25) | (25) | (25) | (25) | (25) | (25)
Tooth | (1) | (0) | (0) | (0) | (0) | (0)
Cardiovascular System
Blood vessel | (25) | (25) | (25) | (25) | (25) | (25)
Heart | (25) | (25) | (25) | (25) | (25) | (25)
Hemangiosarcoma | | 1 (4%)
Endocrine System
Adrenal cortex | (24) | (25) | (25) | (25) | (25) | (25)
Hemangiosarcoma, metastatic, heart | | 1 (4%)
Adrenal medulla | (24) | (25) | (25) | (25) | (25) | (25)
Hemangiosarcoma, metastatic, heart | | 1 (4%)
General Body System
None
Genital System
Coagulating gland | (2) | (0) | (1) | (0) | (0) | (3)
Epididymis | (25) | (25) | (25) | (25) | (25) | (25)
Preputial gland | (25) | (25) | (25) | (25) | (25) | (23)
Prostate | (25) | (25) | (25) | (25) | (25) | (25)
Seminal vesicle | (25) | (25) | (25) | (25) | (25) | (25)
Hemangiosarcoma, metastatic, heart | | 1 (4%)
Testes | (25) | (25) | (25) | (25) | (25) | (25)
Hemangiosarcoma, metastatic, heart | | 1 (4%)
Hematopoietic System
Bone marrow | (25) | (25) | (25) | (25) | (25) | (25)
Lymph node, mandibular | (25) | (25) | (25) | (25) | (24) | (25)
Lymph node, mesenteric | (24) | (25) | (25) | (25) | (25) | (25)
Spleen | (25) | (25) | (25) | (25) | (23) | (25)
Thymus | (25) | (24) | (25) | (25) | (23) | (25)
Integumentary System
Skin | (25) | (25) | (25) | (25) | (25) | (25)
Hemangioma | | | | | 1 (4%)
Subcutaneous tissue, sarcoma | | | 1 (4%)
Musculoskeletal System
Bone | (25) | (25) | (25) | (25) | (25) | (25)
Femur, osteoma | | | 1 (4%)
Maxilla, osteosarcoma | | | | 3 (12%) | 1 (4%)
Vertebra, osteosarcoma | | | | | 1 (4%)
Nervous System
Brain | (25) | (25) | (25) | (25) | (25) | (25)
Hemangiosarcoma, metastatic, heart | | 1 (4%)
Respiratory System
Lung | (25) | (25) | (25) | (25) | (25) | (25)
Alveolar/bronchiolar adenoma | 1 (4%) | | 1 (4%)
Hemangiosarcoma, metastatic, heart | | 1 (4%)
Nose | (25) | (25) | (25) | (25) | (25) | (25)
Special Senses System
Harderian gland | (0) | (0) | (0) | (0) | (1) | (0)
Carcinoma | | | | | 1 (100%)
Urinary System
Kidney | (25) | (25) | (25) | (25) | (25) | (25)
Hemangiosarcoma, metastatic, heart | | 1 (4%)
Urinary bladder | (25) | (25) | (25) | (25) | (25) | (25)
Systemic Lesions
Multiple organs^b^ | (25) | (25) | (25) | (25) | (25) | (25)
Lymphoma, malignant | 1 (4%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 3 | 1 | 8 | 3 | 5 | 1
Total primary neoplasms | 3 | 1 | 8 | 3 | 6 | 1
Total animals with benign neoplasms | 2 | | 7 | | 3 | 1
Total benign neoplasms | 2 | | 7 | | 3 | 1
Total animals with malignant neoplasms | 1 | 1 | 1 | 3 | 3
Total malignant neoplasms | 1 | 1 | 1 | 3 | 3
Total animals with metastatic neoplasms | | 1
Total metastatic neoplasms | | 9

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A2 Summary of the Incidence of Nonneoplastic Lesions in Male Heterozygous F1 p53^+/−^ Mice in the 40-Week Feed Study of Senna^a^

| 0 ppm | 100 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Disposition Summary
Animals initially in study | 25 | 25 | 25 | 25 | 25 | 25
Early deaths
Natural deaths | | 1 | | | 2 | 1
Survivors
Terminal sacrifice | 25 | 24 | 25 | 25 | 23 | 24
Animals examined microscopically | 25 | 25 | 25 | 25 | 25 | 25
Alimentary System
Intestine large, cecum | (25) | (25) | (25) | (25) | (23) | (25)
Epithelium, hyperplasia | | | | | | 22 (88%)
Intestine large, colon | (25) | (25) | (25) | (25) | (24) | (25)
Epithelium, hyperplasia | | | | | 3 (13%) | 25 (100%)
Intestine large, rectum | (24) | (25) | (25) | (25) | (24) | (25)
Epithelium, hyperplasia | | | | | | 1 (4%)
Intestine small, duodenum | (25) | (25) | (25) | (25) | (23) | (25)
Ectopic tissue | | | | | 1 (4%)
Intestine small, jejunum | (25) | (25) | (25) | (25) | (23) | (24)
Epithelium, hyperplasia | | | 1 (4%)
Liver | (25) | (25) | (25) | (25) | (25) | (25)
Basophilic focus | 2 (8%) | 3 (12%) | 2 (8%) | | | 4 (16%)
Clear cell focus | | | | 1 (4%)
Degeneration, cystic | | | | 1 (4%)
Eosinophilic focus | | 1 (4%) | | | 1 (4%)
Fibrosis | | | | 1 (4%)
Hematopoietic cell proliferation | | 2 (8%)
Inflammation, chronic active | 15 (60%) | 17 (68%) | 19 (76%) | 22 (88%) | 14 (56%) | 10 (40%)
Mixed cell focus | | | 1 (4%) | 1 (4%) | 1 (4%)
Necrosis | 1 (4%) | 1 (4%) | | 1 (4%) | 1 (4%) | 1 (4%)
Tension lipidosis | 1 (4%)
Kupffer cell, hyperplasia, multifocal | | | | | 1 (4%)
Pancreas | (25) | (25) | (25) | (25) | (25) | (25)
Stomach, forestomach | (25) | (25) | (25) | (25) | (25) | (25)
Inflammation | | | | 1 (4%)
Epithelium, hyperplasia | | | | 1 (4%)
Stomach, glandular | (25) | (25) | (25) | (25) | (25) | (25)
Mineralization | | | 1 (4%) | 1 (4%)
Glands, cyst | 2 (8%) | 2 (8%) | 2 (8%) | | 1 (4%)
Tooth | (1) | (0) | (0) | (0) | (0) | (0)
Malformation | 1 (100%)
Cardiovascular System
Blood vessel | (25) | (25) | (25) | (25) | (25) | (25)
Inflammation | | 1 (4%)
Heart | (25) | (25) | (25) | (25) | (25) | (25)
Mineralization | | | | | 1 (4%)
Valve, pigmentation, melanin | 1 (4%)
Endocrine System
Adrenal cortex | (24) | (25) | (25) | (25) | (25) | (25)
Atrophy | | | | 1 (4%)
Embolus bacterial | | | | | 1 (4%)
Hypertrophy | 3 (13%) | 1 (4%) | 2 (8%) | 1 (4%) | 1 (4%) | 4 (16%)
Subcapsular, hyperplasia | 4 (17%) | | | | | 8 (32%)
Adrenal medulla | (24) | (25) | (25) | (25) | (25) | (25)
General Body System
None
Genital System
Coagulating gland | (2) | (0) | (1) | (0) | (0) | (3)
Epithelium, hyperplasia | 2 (100%) | | 1 (100%) | | | 3 (100%)
Epididymis | (25) | (25) | (25) | (25) | (25) | (25)
Inflammation | | | | | | 1 (4%)
Epithelium, karyomegaly | 14 (56%) | | | | 1 (4%) | 14 (56%)
Preputial gland | (25) | (25) | (25) | (25) | (25) | (23)
Ectasia | | | | | | 1 (4%)
Hyperplasia | | | | | 1 (4%)
Duct, ectasia | 4 (16%) | | | | | 2 (9%)
Prostate | (25) | (25) | (25) | (25) | (25) | (25)
Infiltration cellular, mononuclear cell | 1 (4%) | | 2 (8%) | 1 (4%)
Inflammation | | | | | 1 (4%) | 1 (4%)
Seminal vesicle | (25) | (25) | (25) | (25) | (25) | (25)
Testes | (25) | (25) | (25) | (25) | (25) | (25)
Germinal epithelium, degeneration | | | 1 (4%)
Rete testes, cyst | 1 (4%)
Hematopoietic System
Bone marrow | (25) | (25) | (25) | (25) | (25) | (25)
Hyperplasia | | 1 (4%) | | | | 1 (4%)
Lymph node, mandibular | (25) | (25) | (25) | (25) | (24) | (25)
Atrophy | | | | 3 (12%) | 2 (8%)
Hyperplasia, lymphoid | | | 1 (4%) | 2 (8%)
Lymph node, mesenteric | (24) | (25) | (25) | (25) | (25) | (25)
Atrophy | | 2 (8%)
Hyperplasia, lymphoid | | | | 1 (4%)
Spleen | (25) | (25) | (25) | (25) | (23) | (25)
Hematopoietic cell proliferation | | 1 (4%) | 1 (4%)
Infiltration cellular, plasma cell | | | | | | 1 (4%)
Lymphoid follicle, atrophy | | 2 (8%) | | | | 1 (4%)
Lymphoid follicle, hyperplasia | 1 (4%) | 1 (4%) | | | | 1 (4%)
Thymus | (25) | (24) | (25) | (25) | (23) | (25)
Atrophy | | 1 (4%) | | 2 (8%) | | 1 (4%)
Cyst | | 1 (4%) | 1 (4%)
Cortex, hyperplasia, lymphoid | | | | | 1 (4%)
Epithelial cell, hyperplasia | | | | 1 (4%)
Medulla, hyperplasia, lymphoid | | 2 (8%) | 3 (12%) | 2 (8%) | 4 (17%)
Integumentary System
Skin | (25) | (25) | (25) | (25) | (25) | (25)
Musculoskeletal System
Bone | (25) | (25) | (25) | (25) | (25) | (25)
Hyperostosis | | | | | | 1 (4%)
Nervous System
Brain | (25) | (25) | (25) | (25) | (25) | (25)
Respiratory System
Lung | (25) | (25) | (25) | (25) | (25) | (25)
Thrombosis | | | | | 1 (4%)
Alveolar epithelium, hyperplasia | | | | | | 1 (4%)
Nose | (25) | (25) | (25) | (25) | (25) | (25)
Inflammation | 2 (8%) | 1 (4%) | 2 (8%) | | 1 (4%)
Glands, olfactory epithelium, hyperplasia | | | 1 (4%)
Glands, respiratory epithelium, hyperplasia | 1 (4%) | 6 (24%) | 2 (8%) | 2 (8%) | 3 (12%)
Respiratory epithelium, cyst | | | | | 1 (4%)
Respiratory epithelium, hyperplasia | 2 (8%) | | 1 (4%) | 2 (8%) | | 1 (4%)
Septum, hyalinization | 15 (60%) | 1 (4%) | | | 2 (8%) | 16 (64%)
Special Senses System
Harderian gland | (0) | (0) | (0) | (0) | (1) | (0)
Urinary System
Kidney | (25) | (25) | (25) | (25) | (25) | (25)
Infiltration cellular, mononuclear cell | 1 (4%)
Inflammation | | | | | 1 (4%) | 1 (4%)
Mineralization | | 4 (16%) | 1 (4%) | | 1 (4%)
Necrosis | | | | | 1 (4%)
Nephropathy | 7 (28%) | 7 (28%) | 7 (28%) | 7 (28%) | 9 (36%) | 8 (32%)
Cortex, cyst | | | | | 1 (4%)
Papilla, necrosis | | | | | | 1 (4%)
Urinary bladder | (25) | (25) | (25) | (25) | (25) | (25)
Inflammation | | | | | 1 (4%) | 1 (4%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A3 Summary of the Incidence of Neoplasms in Female Heterozygous F1 p53^+/−^ Mice in the 40-Week Feed Study of Senna^a^

| 0 ppm | 100 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Disposition Summary
Animals initially in study | 25 | 25 | 25 | 25 | 25 | 25
Early deaths
Moribund sacrifice | 2 | 2 | 2 | 2 | 2 | 1
Natural deaths | | | | 1 | 1
Survivors
Terminal sacrifice | 23 | 23 | 23 | 22 | 22 | 24
Animals examined microscopically | 25 | 25 | 25 | 25 | 25 | 25
Alimentary System
Gallbladder | (25) | (25) | (25) | (25) | (25) | (25)
Intestine large, cecum | (25) | (25) | (25) | (25) | (25) | (25)
Intestine large, colon | (25) | (25) | (25) | (25) | (25) | (25)
Intestine large, rectum | (25) | (25) | (25) | (25) | (25) | (25)
Intestine small, duodenum | (25) | (25) | (25) | (24) | (25) | (25)
Intestine small, jejunum | (25) | (25) | (25) | (25) | (25) | (25)
Liver | (25) | (25) | (25) | (25) | (25) | (25)
Pancreas | (25) | (25) | (25) | (25) | (25) | (25)
Salivary glands | (25) | (25) | (25) | (25) | (25) | (25)
Stomach, forestomach | (25) | (25) | (25) | (25) | (25) | (25)
Stomach, glandular | (25) | (25) | (25) | (25) | (25) | (25)
Granulosa cell tumor malignant, metastatic, ovary | 1 (4%)
Tooth | (0) | (1) | (0) | (0) | (0) | (0)
Cardiovascular System
Heart | (25) | (25) | (25) | (25) | (25) | (25)
Endocrine System
Adrenal cortex | (25) | (25) | (25) | (25) | (25) | (25)
Adrenal medulla | (25) | (25) | (25) | (25) | (25) | (25)
Pheochromocytoma benign | 1 (4%)
Pituitary gland | (25) | (25) | (25) | (25) | (25) | (25)
Thyroid gland | (25) | (25) | (25) | (25) | (25) | (25)
General Body System
Peritoneum | (1) | (0) | (0) | (0) | (0) | (0)
Granulosa cell tumor malignant, metastatic, ovary | 1 (100%)
Genital System
Ovary | (25) | (25) | (25) | (25) | (25) | (25)
Cystadenoma | 1 (4%)
Granulosa cell tumor malignant | 1 (4%)
Uterus | (25) | (25) | (25) | (25) | (25) | (25)
Polyp, stromal | | | 1 (4%) | | 1 (4%)
Hematopoietic System
Bone marrow | (25) | (25) | (25) | (25) | (25) | (25)
Lymph node | (2) | (1) | (0) | (0) | (0) | (0)
Renal, granulosa cell tumor malignant, metastatic, ovary | 1 (50%)
Lymph node, mandibular | (25) | (25) | (25) | (25) | (25) | (25)
Lymph node, mesenteric | (23) | (25) | (25) | (25) | (25) | (25)
Spleen | (25) | (25) | (25) | (25) | (25) | (25)
Thymus | (24) | (22) | (22) | (22) | (22) | (24)
Integumentary System
Mammary gland | (25) | (25) | (25) | (25) | (25) | (25)
Carcinoma | | | | 1 (4%)
Musculoskeletal System
Bone | (25) | (25) | (25) | (25) | (25) | (25)
Osteosarcoma | | | | | | 1 (4%)
Femur, osteosarcoma | | | | | | 1 (4%)
Maxilla, osteosarcoma | | 1 (4%) | | 1 (4%)
Rib, osteosarcoma | 1 (4%)
Tibia, osteosarcoma | | 1 (4%)
Vertebra, osteosarcoma | 1 (4%) | | 1 (4%) | 2 (8%)
Nervous System
Brain | (25) | (25) | (25) | (25) | (25) | (25)
Olfactory neuroblastoma, metastatic, nose | | | | | | 1 (4%)
Peripheral nerve | (1) | (0) | (1) | (1) | (1) | (0)
Spinal cord | (1) | (0) | (2) | (2) | (1) | (1)
Respiratory System
Lung | (25) | (25) | (25) | (25) | (25) | (25)
Osteosarcoma, metastatic, bone | | 1 (4%) | | | | 1 (4%)
Nose | (25) | (25) | (25) | (25) | (25) | (25)
Olfactory epithelium, meuroblastoma malignant | | | | | | 1 (4%)
Special Senses System
None
Urinary System
Kidney | (25) | (25) | (25) | (25) | (25) | (25)
Granulosa cell tumor malignant, metastatic, ovary | 1 (4%)
Urinary bladder | (25) | (25) | (25) | (25) | (25) | (25)
Systemic Lesions
Multiple organs^b^ | (25) | (25) | (25) | (25) | (25) | (25)
Histiocytic sarcoma | | 1 (4%)
Lymphoma malignant | 1 (4%) | | 1 (4%) | | 1 (4%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 6 | 3 | 3 | 4 | 2 | 3
Total primary neoplasms | 6 | 3 | 3 | 4 | 2 | 3
Total animals with benign neoplasms | 2 | | 1 | | 1
Total benign neoplasms | 2 | | 1 | | 1
Total animals with malignant neoplasms | 4 | 3 | 2 | 4 | 1 | 3
Total malignant neoplasms | 4 | 3 | 2 | 4 | 1 | 3
Total animals with metastatic neoplasms | 1 | 1 | | | | 2
Total metastatic neoplasms | 4 | 1 | | | | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A4 Summary of the Incidence of Nonneoplastic Lesions in Female Heterozygous F1 p53^+/−^ Mice in the 40-Week Feed Study of Senna^a^

| 0 ppm | 100 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Disposition Summary
Animals initially in study | 25 | 25 | 25 | 25 | 25 | 25
Early deaths
Moribund sacrifice | 2 | 2 | 2 | 2 | 2 | 1
Natural deaths | | | | 1 | 1
Survivors
Terminal sacrifice | 23 | 23 | 23 | 22 | 22 | 24
Animals examined microscopically | 25 | 25 | 25 | 25 | 25 | 25
Alimentary System
Gallbladder | (25) | (25) | (25) | (25) | (25) | (25)
Inflammation | | | | | | 1 (4%)
Intestine large, cecum | (25) | (25) | (25) | (25) | (25) | (25)
Epithelium, hyperplasia | | | | | | 19 (76%)
Intestine large, colon | (25) | (25) | (25) | (25) | (25) | (25)
Epithelium, hyperplasia | | | | | 7 (28%) | 25 (100%)
Intestine large, rectum | (25) | (25) | (25) | (25) | (25) | (25)
Epithelium, hyperplasia | | | | | | 1 (4%)
Intestine small, duodenum | (25) | (25) | (25) | (24) | (25) | (25)
Intestine small, jejunum | (25) | (25) | (25) | (25) | (25) | (25)
Diverticulum | | | 1 (4%) | 1 (4%)
Liver | (25) | (25) | (25) | (25) | (25) | (25)
Basophilic focus | | | | | | 1 (4%)
Clear cell focus | | | | | | 1 (4%)
Hematopoietic cell proliferation | 1 (4%) | | | | 1 (4%) | 1 (4%)
Infiltration cellular, mixed cell | | | | 2 (8%)
Inflammation, chronic active | 13 (52%) | 2 (8%) | 1 (4%) | 5 (20%) | 6 (24%) | 9 (36%)
Mixed cell focus | 1 (4%)
Necrosis | | | | | 1 (4%)
Necrosis, focal | 1 (4%)
Tension lipidosis | | | | 1 (4%)
Pancreas | (25) | (25) | (25) | (25) | (25) | (25)
Atrophy | | | | | 1 (4%)
Salivary glands | (25) | (25) | (25) | (25) | (25) | (25)
Hyperplasia, lymphoid | 1 (4%) | | | 1 (4%) | | 1 (4%)
Stomach, forestomach | (25) | (25) | (25) | (25) | (25) | (25)
Inflammation | | | 1 (4%)
Epithelium, hyperplasia | | | 1 (4%)
Stomach, glandular | (25) | (25) | (25) | (25) | (25) | (25)
Epithelium, metaplasia, squamous | | | | 1 (4%) | 1 (4%)
Glands, cyst | 1 (4%) | 4 (16%) | 3 (12%) | 2 (8%) | 1 (4%)
Tooth | (0) | (1) | (0) | (0) | (0) | (0)
Cardiovascular System
Heart | (25) | (25) | (25) | (25) | (25) | (25)
Cardiomyopathy | | | | | 2 (8%) | 1 (4%)
Embolus tumor | | 1 (4%)
Infiltration cellular, lymphocyte | | | | | 1 (4%)
Epicardium, inflammation | | | | | 1 (4%)
Valve, thrombosis | | | | 1 (4%)
Endocrine System
Adrenal cortex | (25) | (25) | (25) | (25) | (25) | (25)
Hypertrophy | | | 1 (4%)
Subcapsular, hyperplasia | 16 (64%) | 2 (8%) | 1 (4%) | 2 (8%) | 1 (4%) | 16 (64%)
Adrenal medulla | (25) | (25) | (25) | (25) | (25) | (25)
Pituitary gland | (25) | (25) | (25) | (25) | (25) | (25)
Pars distalis, hyperplasia | | | 1 (4%)
Thyroid gland | (25) | (25) | (25) | (25) | (25) | (25)
Cyst | | 1 (4%)
General Body System
Peritoneum | (1) | (0) | (0) | (0) | (0) | (0)
Genital System
Ovary | (25) | (25) | (25) | (25) | (25) | (25)
Angiectasis | | 1 (4%)
Atrophy | 3 (12%) | 3 (12%) | 2 (8%) | 3 (12%) | 2 (8%) | 4 (16%)
Cyst | 1 (4%) | 2 (8%) | | 3 (12%) | 1 (4%) | 1 (4%)
Mineralization | | | 1 (4%)
Pigmentation, hemosiderin | | | 1 (4%)
Uterus | (25) | (25) | (25) | (25) | (25) | (25)
Endometrium, hyperplasia, cystic | 15 (60%) | 7 (28%) | 3 (12%) | 5 (20%) | 6 (24%) | 14 (56%)
Hematopoietic System
Bone marrow | (25) | (25) | (25) | (25) | (25) | (25)
Hyperplasia | 1 (4%) | 1 (4%) | | 1 (4%) | | 1 (4%)
Inflammation | | 1 (4%)
Necrosis | | | | | 1 (4%)
Lymph node | (2) | (1) | (0) | (0) | (0) | (0)
Lymph node, mandibular | (25) | (25) | (25) | (25) | (25) | (25)
Atrophy | | | 1 (4%) | 2 (8%) | 1 (4%) | 1 (4%)
Hyperplasia, lymphoid | 1 (4%)
Infiltration cellular, mast cell | | 1 (4%)
Lymph node, mesenteric | (23) | (25) | (25) | (25) | (25) | (25)
Atrophy | 1 (4%) | 1 (4%) | 2 (8%) | 2 (8%) | 2 (8%)
Hyperplasia, lymphoid | | | | | | 1 (4%)
Inflammation, suppurative | | | | 1 (4%)
Spleen | (25) | (25) | (25) | (25) | (25) | (25)
Hematopoietic cell proliferation | 1 (4%) | 1 (4%) | | 1 (4%) | 1 (4%)
Lymphoid follicle, atrophy | 1 (4%) | 1 (4%)
Lymphoid follicle, hyperplasia | | 1 (4%) | | 2 (8%)
Thymus | (24) | (22) | (22) | (22) | (22) | (24)
Atrophy | 3 (13%) | 1 (5%) | 1 (5%) | 1 (5%) | 1 (5%) | 2 (8%)
Hyperplasia, lymphoid | 1 (4%)
Medulla, hyperplasia, lymphoid | 4 (17%) | 3 (14%) | 3 (14%) | 6 (27%) | 5 (23%) | 4 (17%)
Integumentary System
Mammary gland | (25) | (25) | (25) | (25) | (25) | (25)
Duct, ectasia | 1 (14%) | | | | 1 (4%) | 1 (4%)
Musculoskeletal System
Bone | (25) | (25) | (25) | (25) | (25) | (25)
Callus | 1 (4%)
Fibro-osseous lesion | | 2 (8%) | | 2 (8%) | 1 (4%) | 1 (4%)
Nervous System
Brain | (25) | (25) | (25) | (25) | (25) | (25)
Peripheral nerve | (1) | (0) | (1) | (1) | (1) | (0)
Degeneration | 1 (100%)
Spinal cord | (1) | (0) | (2) | (2) | (1) | (1)
Degeneration | | | 2 (100%) | 2 (100%) | | 1 (100%)
Nerve, degeneration | 1 (100%)
Respiratory System
Lung | (25) | (25) | (25) | (25) | (25) | (25)
Alveolar epithelium, hyperplasia | 1 (4%)
Artery, infiltration cellular, mixed cell | | 1 (4%)
Serosa, inflammation | | | | | 1 (4%)
Nose | (25) | (25) | (25) | (25) | (25) | (25)
Inflammation | 1 (4%) | 1 (4%) | 1 (4%) | 2 (8%)
Inflammation, suppurative | | | | 1 (4%)
Glands, olfactory epithelium, dilatation | | | 1 (4%)
Glands, respiratory epithelium, hyperplasia | 1 (4%) | 6 (24%) | 4 (16%) | 4 (16%) | 4 (16%)
Olfactory epithelium, degeneration | | | | | | 1 (4%)
Septum, hyalinization | 17 (68%) | 2 (8%) | 3 (12%) | 2 (8%) | 3 (12%) | 15 (60%)
Special Senses System
None
Urinary System
Kidney | (25) | (25) | (25) | (25) | (25) | (25)
Hyperplasia, lymphoid | | | | | | 1 (4%)
Mineralization | 1 (4%) | | 1 (4%)
Nephropathy | 3 (12%) | 6 (24%) | 5 (20%) | 4 (16%) | 9 (36%) | 2 (8%)
Urinary bladder | (25) | (25) | (25) | (25) | (25) | (25)
Infiltration, cellular, lymphocyte | | 1 (4%) | 3 (12%) | 2 (8%)
Inflammation | | | 1 (4%)
Transitional epithelium, vacuolization cytoplasmic | | | | | 1 (4%)

a Number of animals examined microscopically at the site and the number of animals with lesion