# REFERENCES

Anderson, L.M. (2004). Predictive values of traditional animal bioassay studies for human perinatal carcinogenesis risk determination. Toxicol. Appl. Pharmacol. 199, 162–174.15313588
Anonymous (1987). Zidovudine approved by FDA for treatment of AIDS. Clin. Pharm. 6, 431–435.3319360
Anonymous (2007) FDA notifications. FDA approves generic AZT. AIDS Alert 22, 79.
Antiretroviral Pregnancy Registry (2003). <www.apregistry.com>, Accessed December 2, 2011.
Arnaudo, E., Dalakas, M.C., Shanske, S., Moraes, C.T., DiMauro, S., and Schon, E.A. (1991). Depletion of muscle mitochondrial DNA in AIDS patients with zidovudine-induced myopathy. Lancet 337, 508–510.1671889
Artandi, S.E., Chang, S., Lee, S.L., Alson, S., Gottlieb, G.J., Chin, L., and DePinho, R.A. (2000). Telomere dysfunction promotes non-reciprocal translocations and epithelial cancers in mice. Nature 406, 641–645.10949306
Avramis, V.I., Markson, W., Jackson, R.L., and Gomperts, E. (1989). Biochemical pharmacology of zidovudine in human T-lymphoblastoid cells (CEM). AIDS 3, 417–422.2504244
Ayers, K.M. (1988). Preclinical toxicology of zidovudine. Am. J. Med. 85 (Suppl. 2A), 186–188.3044084
Ayers, K.M., Clive, D., Tucker, W.E., Jr., Hajian, G., and de Miranda, P. (1996a). Nonclinical toxicology studies with zidovudine: Genetic toxicity tests and carcinogenicity bioassays in mice and rats. Fundam. Appl. Toxicol. 32, 148–158.8921318
Ayers, K.M., Tucker, W.E., Hajian, G., and de Miranda, P. (1996b). Nonclinical toxicology studies with zidovudine; acute, subacute, and chronic toxicity in rodents, dogs, and monkeys. Fundam. Appl. Toxicol. 32, 129–139.8921316
Ayers, K.M., Torrey, C.E., and Reynolds, D.J. (1997). A transplacental carcinogenicity bioassay in CD-1 mice with zidovudine. Fundam. Appl. Toxicol. 38, 195–198.9299194
Bailer, A.J., and Portier, C.J. (1988). Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics 44, 417–431.3390507
Balzarini, J. (1994). Metabolism and mechanism of antiretroviral action of purine and pyrimidine derivatives. Pharm. World Sci. 16, 113–126.8032337
Bieler, G.S., and Williams, R.L. (1993). Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics 49, 793–801.8241374
Binder, D.A. (1992). Fitting Cox’s proportional hazards models from survey data. Biometrika 79, 139–147.
Bishop, J.B., Tani, Y., Witt, K., Johnson, J.A., Peddada, S., Dunnick, J., and Nyska, A. (2004a). Mitochondrial damage revealed by morphometric and semiquantitative analysis of mouse pup cardiomyocytes following in utero and postnatal exposure to zidovudine and lamivudine. Toxicol. Sci. 81, 512–517.15229369
Bishop, J.B., Witt, K.L., Tice, R.R., and Wolfe, G.W. (2004b). Genetic damage detected in CD-1 mouse pups exposed to 3′-azido-3′-deoxythymidine and dideoxyinosine via maternal dosing, nursing, and direct gavage. Environ. Mol. Mutagen. 43, 3–9.14743340
Boorman, G.A., Montgomery, C.A., Jr., Eustis, S.L., Wolfe, M.J., McConnell, E.E., and Hardisty, J.F. (1985). Quality assurance in pathology for rodent carcinogenicity studies. In Handbook of Carcinogen Testing (H.A. Milman and E.K. Weisburger, Eds.), pp. 345–357. Noyes Publications, Park Ridge, NJ.
Bradshaw, P.C., Li, J., and Samuels, D.C. (2005). A computational model of mitochondrial AZT metabolism. Biochem. J. 392, 363–373.16060859
Brinkman, K., Smeitink, J.A., Romijn, J.A., and Reiss, P. (1999). Mitochondrial toxicity induced by nucleoside-analogue reverse-transcriptase inhibitors is a key factor in the pathogenesis of antiretroviral-therapy-related lipodystrophy. Lancet 354, 1112–1115.10509516
Brook, I. (1987). Approval of zidovudine (AZT) for acquired immunodeficiency syndrome. A challenge to the medical and pharmaceutical communities. JAMA 258, 1517.3306004
Bull, R.J., Sanchez, I.M., Nelson, M.A., Larson, J.L., and Lansing, A.J. (1990). Liver tumor induction in B6C3F1 mice by dichloroacetate and trichloroacetate. Toxicology 63, 341–359.2219130
Chan, S.S., Santos, J.H., Meyer, J.N., Mandavilli, B.S., Cook, D.L., Jr., McCash, C.L., Kissling, G.E., Nyska, A., Foley, J.F., van Houten, B., Copeland, W.C., Walker, V.E., Witt, K.L., and Bishop, J.B. (2007). Mitochondrial toxicity in hearts of CD-1 mice following perinatal exposure to AZT, 3TC, or AZT/3TC in combination. Environ. Mol. Mutagen. 48, 190–200.16395692
Child, S., Montaner, J., Tsoukas, C., Fanning, M., Le, T., Wall, R.A., and Ruedy, J. (1991). Canadian multicenter azidothymidine trial: AZT pharmacokinetics. J. Acquir. Immune Defic. Syndr. 4, 865–870.1895207
Cleveland, W.S. (1979). Robust locally weighted regression and smoothing scatterplots. J. Am. Stat. Assoc. 74, 829–836.
Cleveland, W.S., Devlin, S.J., and Grosse, E. (1988). Regression by local fitting. J. Econ. 37, 87–114.
Code of Federal Regulations (CFR) 21, Part 58.
Comstock, K.E., Johnson, K.J., Rifenbery, D., and Henner, W.D. (1993). Isolation and analysis of the gene and cDNA for a human Mu class glutathione S-transferase, GSTM4. J. Biol. Chem. 268, 16,958–16,965.
Connor, E.M., Sperling, R.S., Gelber, R., Kiselev, P., Scott, G., O’Sullivan, M.J., VanDyke, R., Bey, M., Shearer, W., Jacobson, R.L., Jimenez, E., O’Neill, E., Bazin, B., Delfraissy, J-F., Culnane, M., Coombs, R., Elkins, M., Moye, J., Stratton, P., and Balsley, J. (1994). Reduction of maternal-infant transmission of human immunodeficiency virus type 1 with zidovudine treatment. Pediatric AIDS Clinical Trials Group Protocol 076 Study Group. N. Engl. J. Med. 331, 1173–1180.7935654
Corcuera Pindado, M.T., Lopez Bravo, A., Martinez-Rodriguez, R., Picazo Talavera, A., Gomez Aguado, F., Roldan Contreras, M., Perez Alvarez, M.J., Fernandez Garcia, A., and Alonso Martin, M.J. (1994). Histochemical and ultrastructural changes induced by zidovudine in mitochondria of rat cardiac muscle. Eur. J. Histochem. 38, 311–318.7535128
Cox, D.R. (1972). Regression models and life-tables. J. R. Stat. Soc. B34, 187–220.
Cretton, E.M., Schinazi, R.F., McClure, H.M., Anderson, D.C., and Sommadossi, J.-P. (1991). Pharmacokinetics of 3′-azido-3′-deoxythymidine and its catabolites and interactions with probenecid in rhesus monkeys. Antimicrob. Agents Chemother. 35, 801–807.1854160
Dainiak, N., Worthington, M., Riordan, M.A., Kreczko, S., and Goldman, L. (1988). 3′-Azido-3′-deoxythymidine (AZT) inhibits proliferation in vitro of human haematopoietic progenitor cells. Br. J. Haematol. 69, 299–304.3261597
Dalakas, M.C., Illa, I., Pezeshkpour, G.H., Laukaitis, J.P., Cohen, B., and Griffin, J.L. (1990). Mitochondrial myopathy caused by long-term zidovudine therapy. N. Engl. J. Med. 322, 1098–1105.2320079
DeAngelo, A.B., Daniel, F.B., Most, B.M., and Olson, G.R. (1996). The carcinogenicity of dichloroacetic acid in the male Fischer 344 rat. Toxicology 114, 207–221.8980710
de Miranda, P., Burnette, T.C., and Good, S.S. (1990). Tissue distribution and metabolic disposition of zidovudine in rats. Drug Metab. Dispos. 18, 315–320.1974192
Dertinger, S.D., Torous, D.K., and Tometsko, K.R. (1996). Induction of micronuclei by low doses of azidothymidine (AZT). Mutat. Res. 368, 301–307.8692236
Dertinger, S.D., Bishop, M.E., McNamee, J.P., Hayashi, M., Suzuki, T., Asano, N., Nakajima, M., Saito J., Moore, M., Torous, D.K., and Macgregor, J.T. (2006). Flow cytometric analysis of micronuclei in peripheral blood reticulocytes: I. Intra- and interlaboratory comparison with microscopic scoring. Toxicol. Sci. 94, 83–91.16888078
Deveaud, C., Beauvoit, B., Reynaud, A., and Bonnet, J. (2007). Site-specific reduction of oxidative and lipid metabolism in adipose tissue of 3′-azido-3′-deoxythymidine-treated rats. Antimicrob. Agents Chemother. 51, 583–590.17158934
Department of Health and Human Services (DHHS) (2008a). Panel on Antiretroviral Guidelines for Adults and Adolescents. Guidelines for the use of antiretroviral agents in HIV-1-infected adults and adolescents. DHHS, Washington, DC.
Department of Health and Human Services (DHHS) (2008b). Working Group on Antiretroviral Therapy and Medical Management of HIV-Infected Children. Guidelines for the Use of Antiretroviral Agents in Pediatric HIV Infection. DHHS, Washington, DC.
Department of Health and Human Services (DHHS) (2009). AIDS Information and guidelines. <http://aidsinfo.nih.gov/guidelines/>
Divi, R.L., Leonard, S.L., Kuo, M.M., Nagashima, K., Thamire, C., St. Claire, M.C., Wade, N.A., Walker, V.E., and Poirier, M.C. (2007). Transplacentally exposed human and monkey newborn infants show similar evidence of nucleoside reverse transcriptase inhibitor-induced mitochondrial toxicity. Environ. Mol. Mutagen. 48, 201–209.16538687
Diwan, B.A., Riggs, C.W., Logsdon, D., Haines, D.C., Olivero, O.A., Rice, J.M., Yuspa, S.H., Poirier, M.C., and Anderson, L.M. (1999). Multiorgan transplacental and neonatal carcinogenicity of 3′-azido-3′-deoxythymidine in mice. Toxicol. Appl. Pharmacol. 161, 82–99.10558926
Diwan, B.A., Olivero, O.A., and Poirier, M.C. (2000). Absence of structural or functional alterations in male and female reproductive organs of F_1_ and F_2_ generations derived from female mice exposed to 3′-azido-3′-deoxythymidine during pregnancy. Toxicol. Lett. 115, 9–15.10817626
Dobrovolsky, V.N., Shaddock, J.G., Mittelstaedt, R.A., Bishop, M.E., Lewis, S.M., Lee, F.W., Aidoo, A., Leakey, J.E., Dunnick, J.K., and Heflich, R.H. (2007). Frequency of Hprt mutant lymphocytes and micronucleated erythrocytes in p53-haplodeficient mice treated perinatally with AZT and AZT in combination with 3TC. Environ. Mol. Mutagen. 48, 270–282.17358030
Donehower, L.A., Harvey, M., Slagle, B.L., McArthur, M.J., Montgomery, C.A., Jr., Butel, J.S., and Bradley, A. (1992). Mice deficient for p53 are developmentally normal but susceptible to spontaneous tumours. Nature 356, 215–221.1552940
Donehower, L.A., Harvey, M., Vogle, H., McArthur, M.J., Montgomery, C.A., Jr., Park, S.H., Thompson, T., Ford, R.J., and Bradley, A. (1995). Effects of genetic background on tumorigenesis in p53-deficient mice. Mol. Carcinog. 14, 16–22.7546219
Doshi, K.J., Gallo, J.M., Boudinot, F.D., Schinazi, R.F., and Chu, C.K. (1989). Comparative pharmacokinetics of 3′-azido-3′-deoxythymidine (AZT) and 3′-azido-2′,3′-dideoxyuridine (AZddU) in mice. Drug Metab. Dispos. 17, 590–594.2575492
Dunnett, C.W. (1955). A multiple comparison procedure for comparing several treatments with a control. J. Am. Stat. Assoc. 50, 1096–1121.
Dunnick, J.K., Hardisty, J.F., Herbert, R.A., Seeley, J.C., Furedi-Machacek, E.M., Foley, J.F., Lacks, G.D., Stasiewicz, S., and French, J.E. (1997). Phenolphthalein induces thymic lymphomas accompanied by loss of the p53 wild type allele in heterozygous p53-deficient (±) mice. Toxicol. Pathol. 25, 533–540.9437796
Efron, B. (1977). The efficiency of Cox’s likelihood function for censored data. J. Am. Stat. Assoc. 72, 557–565.
Ewings, E.L., Gerschenson, M., St. Claire, M.C., Nagashima, K., Skopets, B., Harbaugh, S.W., Harbaugh, J.W., and Poirier, M.C. (2000). Genotoxic and functional consequences of transplacental zidovudine exposure in fetal monkey brain mitochondria. J. Acquir. Immune Defic. Syndr. 24, 100–105.10935684
Fischl, M.A. (1989). State of antiretroviral therapy with zidovudine. AIDS 3 (Suppl. 1), S137–S143.2514732
Fowler, D.A., Weidner, D.A., and Sommadossi, J.-P. (1995). Effects of 3′-azido-3′-deoxythymidine on erythroid inducible gene expression in human K-562 leukemia cells. Toxicol. Lett. 80, 139–146.7482581
Freireich, E.J., Gehan, E.A., Rall, D.P., Schmidt, L.H., and Skipper, H.E. (1966). Quantitative comparison of toxicity of anticancer agents in mouse, rat, hamster, dog, monkey, and man. Cancer Chemother. Rep. 50, 219–244.4957125
French, J.E. (2004). Identification and characterization of potential human carcinogens using B6.129tm1Trp53 heterozygous null mice and loss of heterozygosity at the Trp53 locus. IARC Sci. Publ. 157, 271–287.
French, J.E., Lacks, G.D., Trempus, C., Dunnick, J.K., Foley, J., Mahler, J., Tice, R.R., and Tennant, R.W. (2001a). Loss of heterozygosity frequency at the Trp53 locus in p53-deficient (+/−) mouse tumors is carcinogen- and tissue dependent. Carcinogenesis 22, 99–106.11159747
French, J.E., Storer, R.D., and Donehower, L.A. (2001b). The nature of the heterozygous Trp53 knockout model for identification of mutagenic carcinogens. Toxicol. Pathol. 29, 24–29.11695559
Furman, P.A., Fyfe, J.A., St. Clair, M.H., Weinhold, K., Rideout, J.L., Freeman, G.A., Lehrman, S.N., Bolognesi, D.P., Broder, S., Mitsuya, H., and Barry, D.W. (1986). Phosphorylation of 3′-azido-3′-deoxythymidine and selective interaction of the 5′-triphosphate with human immunodeficiency virus reverse transcriptase. Proc. Natl. Acad. Sci. U.S.A. 83, 8333–8337.2430286
Gallicchio, V.S., Doukas, M.A., Hulette, B.C., Hughes, N.K., and Gass, C. (1989). Protection of 3′-azido-3′-deoxythymidine induced toxicity to murine hematopoietic progenitors (CFU-GM, BFU-E and CFU-MEG) with interleukin-1. Proc. Soc. Exp. Biol. Med. 192, 201–204.2813453
Gerschenson, M., Erhart, S.W., Paik, C.Y., St. Claire, M.C., Nagashima, K., Skopets, B., Harbaugh, S.W., Harbaugh, J.W., Quan, W., and Poirier, M.C. (2000). Fetal mitochondrial heart and skeletal muscle damage in Erythrocebus patas monkeys exposed in utero to 3′-azido-3′-deoxythymidine. AIDS Res. Hum. Retroviruses 16, 635–644.10791874
Gonzalez Cid, M., and Larripa, I. (1994). Genotoxic activity of azidothymidine (AZT) in in vitro systems. Mutat. Res. 321, 113–118.7510839
Good, S.S., Koble, C.S., Crouch, R., Johnson, R.L., Rideout, J.L., and de Miranda, P. (1990). Isolation and characterization of an ether glucuronide of zidovudine, a major metabolite in monkeys and humans. Drug Metab. Dispos. 18, 321–326.1974193
Greene, J.A., Ayers, K.M., Tucker, W.E., Jr., and de Miranda, P. (1996). Nonclinical toxicology studies with zidovudine: Reproductive toxicity studies in rats and rabbits. Fundam. Appl. Toxicol. 32, 140–147.8921317
Horowitz, J.P., Chua, J., and Noel, M. (1964). Nucleosides. V. The monomesylates of 1′-(2′-deoxy-β-D-lyxofuranosyl)thymine. J. Org. Chem. 29, 2076–2078.
Huang, P., Farquhar, D., and Plunkett, W. (1990). Selective action of 3′-azido-3′-deoxythymidine 5′-triphosphate on viral reverse transcriptases and human DNA polymerases. J. Biol. Chem. 265, 11,914–11,918.
Jonckheere, A.R. (1954). A distribution-free k-sample test against ordered alternatives. Biometrika 41, 133–145.
Kakuda, T.N., Brundage, R.C., Anderson, P.L., and Fletcher, C.V. (1999). Nucleoside reverse transcriptase inhibitor-induced mitochondrial toxicity as an aetiology for lipodystrophy. AIDS 13, 2311–2312.10563722
Kaplan, E.L., and Meier, P. (1958). Nonparametric estimation from incomplete observations. J. Am. Stat. Assoc. 53, 457–481.
Kirk, G.D., Merlo, C., O’Driscoll, P., Mehta, S.H., Galai, N., Vlahov, D., Samet, J., and Engels, E.A. (2007). HIV infection is associated with an increased risk for lung cancer, independent of smoking. Clin. Infect. Dis. 45, 103–110.17554710
Lamperth, L., Dalakas, M.C., Dagani, F., Anderson, J., and Ferrari, R. (1991). Abnormal skeletal and cardiac muscle mitochondria induced by zidovudine (AZT) in human muscle in vitro and in an animal model. Lab. Invest. 65, 742–751.1753716
Lewis, S.M., Lee, F.W., Ali, A.A., Allaben, W.T., Weis, C.C., and Leakey, J.E.A (2010). Modifying a displacement pump for oral gavage dosing of solution and suspension preparations to adult and neonatal mice. Lab Anim. 39, 149–154
Lewis, W., Papoian, T., Gonzales, B., Louie, H., Kelly, D.P., Payne, R.M., and Grody, W.W. (1991). Mitochondrial ultrastructural and molecular changes induced by zidovudine in rat hearts. Lab. Invest. 65, 228–236.1715447
Lewis, W., Gonzales, B., Chomyn, A., and Papoian, T. (1992). Zidovudine induces molecular, biochemical, and ultrastructural changes in rat skeletal muscle mitochondria. J. Clin. Invest. 89, 1354–1360.1556193
Lewis, W., Simpson, J.F., and Meyer, R.R. (1994). Cardiac mitochondrial DNA polymerase-γ is inhibited competitively and noncompetitively by phosphorylated zidovudine. Circ. Res. 74, 344–348.8293572
Lewis, W., Grupp, I.L., Grupp, G., Hoit, B., Morris, R., Samarel, A.M., Bruggeman, L., and Klotman, P. (2000). Cardiac dysfunction in the HIV-1 transgenic mouse treated with zidovudine. Lab. Invest. 80, 187–197.10701688
Liang, K.Y., and Zeger, S.L. (1986). Longitudinal data analysis using generalized linear models. Biometrika 73, 13–22.
Lim, S.E., and Copeland, W.C. (2001). Differential incorporation and removal of antiviral deoxynucleotides by human DNA polymerase γ. J. Biol. Chem. 276, 23,616–23,623.
Lin, D.Y., and Wei, L.J. (1989). The robust inference for the Cox proportional hazards model. J. Am. Stat. Assoc. 84, 1074–1078.
Lin, D.Y., Wei, L.J., and Ying, Z. (1993). Checking the Cox model with cumulative sums of martingale-based residuals. Biometrika 80, 557–572.
Lynx, M.D., and McKee, E.E. (2006). 3′-Azido-3′-deoxythymidine (AZT) is a competitive inhibitor of thymidine phosphorylation in isolated rat heart and liver mitochondria. Biochem. Pharmacol. 72, 239–243.16720018
Lynx, M.D., Bentley, A.T., and McKee, E.E. (2006). 3′-Azido-3′-deoxythymidine (AZT) inhibits thymidine phosphorylation in isolated rat liver mitochondria: A possible mechanism of AZT hepatotoxicity. Biochem. Pharmacol. 71, 1342–1348.16472780
McConnell, E.E., Solleveld, H.A., Swenberg, J.A., and Boorman, G.A. (1986). Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. JNCI 76, 283–289.3456066
McCullagh, P., and Nelder, J.A. (1989). Generalized Linear Models, 2nd ed. Chapman and Hall, London.
Mallal, S.A., John, M., Moore, C.B., James, I.R., and McKinnon, E.J. (2000). Contribution of nucleoside analogue reverse transcriptase inhibitors to subcutaneous fat wasting in patients with HIV infection. AIDS 14, 1309–1316.10930144
Maronpot, R.R., and Boorman, G.A. (1982). Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol. Pathol. 10, 71–80.28094716
Mays, D.C., Dixon, K.F., Balboa, A., Pawluk, L.J., Bauer, M.R., Nawoot, S., and Gerber, N. (1991). A nonprimate animal model applicable to zidovudine pharmacokinetics in humans: Inhibition of glucuronidation and renal excretion of zidovudine by probenecid in rats. J. Pharmacol. Exp. Ther. 259, 1261–1270.1762074
Meng, Q., Grosovsky, A.J., Shi, X., and Walker, V.E. (2000a). Mutagenicity and loss of heterozygosity at the APRT locus in human lymphoblastoid cells exposed to 3′-azido-3′-deoxythymidine. Mutagenesis 15, 405–410.10970446
Meng, Q., Su, T., Olivero, O.A., Poirier, M.C., Shi, X., Ding, X., and Walker, V.E. (2000b). Relationships between DNA incorporation, mutant frequency, and loss of heterozygosity at the TK locus in human lymphoblastoid cells exposed to 3′-azido-3′-deoxythymidine. Toxicol. Sci. 54, 322–329.10774814
Meng, Q., Walker, D.M., Olivero, O.A., Shi, X., Antiochos, B.B., Poirier, M.C., and Walker, V.E. (2000c). Zidovudine-didanosine coexposure potentiates DNA incorporation of zidovudine and mutagenesis in human cells. Proc. Natl. Acad. Sci. U.S.A. 97, 12,667–12,671.10618362
Meng, Q., Su, T., O’Neill, J.P., and Walker, V.E. (2002). Molecular analysis of mutations at the HPRT and TK loci of human lymphoblastoid cells after combined treatments with 3′-azido-3′-deoxythymidine and 2′,3′-dideoxyinosine. Environ. Mol. Mutagen. 39, 282–295.12112380
The Merck Index (2006). 14th ed. (M.J. O’Neil, Ed.), p. 1746. Merck and Company, Inc., Whitehouse Station, NJ.
Mitsuya, H., Weinhold, K.J., Furman, P.A., St. Clair, M.H., Lehrman, S.N., Gallo, R.C., Bolognesi, D., Barry, D.W., and Broder, S. (1985). 3′-Azido-3′-deoxythymidine (BW A509U): An antiviral agent that inhibits the infectivity and cytopathic effect of human T-lymphotrophic virus type III/lymphadenopathy-associated virus in vitro. Proc. Natl. Acad. Sci. U.S.A. 82, 7096–7100.2413459
Motimaya, A.M., Subramanya, K.S., Curry, P.T., and Kitchin, R.M. (1994). Lack of induction of micronuclei by azidothymidine (AZT) in vivo in mouse bone marrow cells. Environ. Mol. Mutagen. 23, 74–76.7802748
National Toxicology Program (NTP) (1999). Toxicology and Carcinogenesis Studies of AZT (CAS No. 30516-87-1) and AZT/α-Interferon A/D in B6C3F_1_ Mice (Gavage Studies). Technical Report Series No. 469. NIH Publication No. 99-3959. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (2005a). Toxicology Studies of Aspartame (CAS No. 22839-47-0) in Genetically Modified (FVB Tg.AC Hemizygous) and B6.129-Cdkn2a^tm1Rdp^ (N2) Deficient Mice and Carcinogenicity Studies of Aspartame in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Feed Studies). Genetically Modified Model Report No. 1. NIH Publication No. 06-4459. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2005b). Toxicology Studies of Acesulfame Potassium (CAS No. 55589-62-3) in Genetically Modified (FVB Tg.AC Hemizygous) Mice and Carcinogenicity Studies of Acesulfame Potassium in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Feed Studies). Genetically Modified Model Report No. 2. NIH Publication No. 06-4460. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2006). Toxicology and Carcinogenesis Studies of Transplacental AZT (CAS No. 30516-87-1) in Swiss (CD-1^®^) Mice (In Utero Studies). Technical Report Series No. 522. NIH Publication No. 06-4458. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007a). Toxicology Studies of Bromodichloromethane (CAS No. 75-27-4) in Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal, Drinking Water, and Gavage Studies) and Carcinogenicity Studies of Bromodichloromethane in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Drinking Water and Gavage Studies). Genetically Modified Model Report No. 5. NIH Publication No. 07-4422. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007b). Toxicology Studies of Sodium Bromate (CAS No. 7789-38-0) in Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal and Drinking Water Studies) and Carcinogenicity Studies of Sodium Bromate in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Drinking Water Studies). Genetically Modified Model Report No. 6. NIH Publication No. 07-4423. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007c). Toxicology Studies of Dicyclohexylcarbodiimide (CAS No. 538-75-0) in F344/N Rats, B6C3F_1_ Mice, and Genetically Modified (FVB Tg.AC Hemizygous) Mice and Carcinogenicity Study of Dicyclohexylcarbodiimide in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Dermal Studies). Genetically Modified Model Report No. 9. NIH Publication No. 07-4426. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007d). Toxicology Study of Diisopropylcarbodiimide (CAS No. 693-13-0) in Genetically Modified (FVB Tg.AC Hemizygous) Mice and Carcinogenicity Study of Diisopropylcarbodiimide in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Dermal Studies). Genetically Modified Model Report No. 10. NIH Publication No. 07-4427. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007e). Toxicology Studies of Dichloroacetic Acid (CAS No. 79-43-6) in Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal and Drinking Water Studies) and Carcinogenicity Studies of Dichloroacetic Acid in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Drinking Water Studies). Genetically Modified Model Report No. 11. NIH Publication No. 07-4428. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2008). Toxicology Studies of Allyl Bromide (CAS No. 106-95-6) in Genetically Modified (FVB Tg.AC Hemizygous) Mice and Carcinogenicity Studies of Allyl Bromide in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Dermal and Gavage Studies). Genetically Modified Model Report No. 7 NIH Publication No. 08-4424. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2012). Toxicology Study Of Senna (CAS No. 8013-11-4) in C57BL/6NTac Mice and Toxicology and Carcinogenesis Study of Senna in Genetically Modified C3B6.129F1−Trp53^tm1Brd^ N12 Haploinsufficient Mice (Feed Studies). Genetically Modified Model Report No. 15. NIH Publication No. 12-5968. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2013). Toxicology and Carcinogenesis Studies of Mixtures of 3′-Azido-3′-Deoxythymidine (AZT), Lamivudine (3TC), Nevirapine (NVP), and Nelfinavir Mesylate (NFV) (CAS Nos. 30516-87-1, 134678-17-4, 129618-40-2, 159989-65-8) in B6C3F1 Mice (Transplacental Exposure Studies). Technical Report Series No. 569. NIH Publication No. 13-5911. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
Olin, B.R., and Kastrup, E.K., Eds. (1995). Drug Facts and Comparisons, p. 404c. Facts and Comparisons, Inc., St. Louis, MO.
Olivero, O.A. (2007). Mechanisms of genotoxicity of nucleoside reverse transcriptase inhibitors. Environ. Mol. Mutagen. 48, 215–223.16395695
Olivero, O.A. (2008). Relevance of experimental models for investigation of genotoxicity induced by antiretroviral therapy during human pregnancy. Mutat. Res. 658, 184–190.18295533
Olivero, O.A., Anderson, L.M., Diwan, B.A., Haines, D.C., Harbaugh, S.W., Moskal, T.J., Jones, A.B., Rice, J.M., Riggs, C.W., Logsdon, D., Yuspa, S.H., and Poirier, M.C. (1997). Transplacental effects of 3′-azido-2′,3′-dideoxythymidine (AZT): Tumorigenicity in mice and genotoxicity in mice and monkeys. J. Natl. Cancer Inst. 89, 1602–1608.9362158
Olivero, O.A., Parikka, R., Poirier, M.C., and Vahakangas, K. (1999). 3′-Azido-3′-deoxythymidine (AZT) transplacental perfusion kinetics and DNA incorporation in normal human placentas perfused with AZT. Mutat. Res. 428, 41–47.10517977
Olivero, O.A., Shearer, G.M., Chougnet, C.A., Kovacs, A.A., Baker, R., Stek, A.M., Khoury, M.M., and Poirier, M.C. (2000). Incorporation of zidovudine into cord blood DNA of infants and peripheral blood DNA of their HIV-1-positive mothers. Ann. N.Y. Acad. Sci. 918, 262–268.11131712
Olivero, O.A., Reddy, M.K., Pietras, S.M., and Poirier, M.C. (2001). Plasma drug levels compared with DNA incorporation of 3′-azido-3′-deoxythymidine (AZT) in adult cynomolgus (macaca fascicularis) monkeys. Exp. Biol. Med. 226, 446–449.
Parker, W.B., White, E.L., Shaddix, S.C., Ross, L.J., Buckheit, R.W., Jr., Germany, J.M., Secrist, J.A., III, Vince, R., and Shannon, W.M. (1991). Mechanism of inhibition of human immunodeficiency virus type I reverse transcriptase and human DNA polymerases α, β, and γ by the 5′-triphosphates of carbovir, 3′-azido-3′-deoxythymidine, 2′,3′-dideoxyguanosine, and 3′-deoxythymidine. A novel RNA template for the evaluation of antiretroviral drugs. J. Biol. Chem. 266, 1754–1762.1703154
Patel, B.A., Chu, C.K., and Boudinot, F.D. (1989). Pharmacokinetics and saturable renal tubular secretion of zidovudine in rats. J. Pharm. Sci. 78, 530–534.2778651
Pérez-Pérez, M.J., Hernandez, A.I., Priego, E.M., Rodríguez-Barrios, F., Gago, F., Camarasa, M.J., and Balzarini, J. (2005). Mitochondrial thymidine kinase inhibitors. Curr. Top. Med. Chem. 5, 1205–1219.16305527
Phillips, M.D., Nascimbeni, B., Tice, R.R., and Shelby, M.D. (1991). Induction of micronuclei in mouse bone marrow cells: An evaluation of nucleoside analogues used in the treatment of AIDS. Environ. Mol. Mutagen. 18, 168–183.1915312
Piegorsch, W.W., and Bailer, A.J. (1997). Statistics for Environmental Biology and Toxicology, Section 6.3.2. Chapman and Hall, London.
Pluda, J.M., Mitsuya, H., and Yarchoan, R. (1991). Hematologic effects of AIDS therapies. Hematol. Oncol. Clin. North Am. 5, 229–248.1708759
Poirier, M.C., Patterson, T.A., Slikker, W., and Olivero, O.A. (1999). Incorporation of 3′-azido-3′-deoxythymidine (AZT) into fetal DNA and fetal tissue distribution of drug after infusion of pregnant late-term rhesus macaques with a human-equivalent AZT dose. J. Acquir. Immune Defic. Syndr. 22, 477–483.10961609
Portier, C.J., and Bailer, A.J. (1989). Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam. Appl. Toxicol. 12, 731–737.2744275
Pritchard, J.B., French, J.E., Davis, B.J., and Haseman, J.K. (2003). The role of transgenic mouse models in carcinogen identification. Environ. Health. Perspect. 111, 444–454.12676597
Public Health Service (PHS) Task Force (2008). Recommendations for use of antiretroviral drugs in pregnant HIV-infected women for maternal health and interventions to reduce perinatal HIV transmission in the United States. U.S. Department of Health and Human Services, Washington, DC.
Raidel, S.M., Haase, C.P., Jansen, N.R., Russ, R.B., Sutliff, R.L., Velsor, L.W., Day, B.J., Hoit, B.D., Samarel, A.M., and Lewis, W. (2002). Targeted myocardial transgenic expression of HIV Tat causes cardiomyopathy and mitochondrial damage. Am. J. Physiol. Heart Circ. Physiol. 282, H1672–H1678.11959630
Rice, J.M. (1973). An overview of transplacental chemical carcinogenesis. Teratology 8, 113–126.
Samuels, D.C. (2006). Mitochondrial AZT metabolism. IUBMB Life 58, 403–408.16801215
Senda, S., Blanche, S., Costagliola, D., Cibert, C., Nigon, F., Firtion, G., Floch, C., Parat, S., and Viegas-Péquignot, E. (2007). Altered heterochromatin organization after perinatal exposure to zidovudine. Antivir. Ther. 12, 179–187.17503660
Shafik, H.M., Nokta, M.A., and Pollard, R.B. (1991). Recombinant human interferon beta ser protects against zidovudine-induced genetic damage in AIDS patients. Antiviral Res. 16, 205–212.1799278
Shirley, E. (1977). A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics 33, 386–389.884197
Simpson, M.V., Chin, C.D., Keilbaugh, S.A., Lin, T.S., and Prusoff, W.H. (1989). Studies on the inhibition of mitochondrial DNA replication by 3′-azido-3′-deoxythymidine and other dideoxynucleoside analogs which inhibit HIV-1 replication. Biochem. Pharmacol. 38, 1033–1036.2706007
Singlas, E., Poiger, J.C., Taburet, A.M., Colaneri, S., and Fillastre, J.P. (1989). Comparative pharmacokinetics of zidovudine (AZT) in healthy subjects and HIV seropositive patients. Eur. J. Clin. Pharmacol. 36, 639–640.2776824
Sommadossi, J.-P., and Carlisle, R. (1987). Toxicity of 3′-azido-3′-deoxythymidine and 9-(1,3-dihydroxy-2-propoxymethyl)guanine for normal human hematopoietic progenitor cells in vitro. Antimicrob. Agents Chemother. 31, 452–454.3495235
Sommadossi, J.-P., Carlisle, R., and Zhou, Z. (1989). Cellular pharmacology of 3′-azido-3′-deoxythymidine with evidence of incorporation into DNA of human bone marrow cells. Mol. Pharmacol. 36, 9–14.2747633
Sperling, R.S., Shapiro, D.E., McSherry, G.D., Britto, P., Cunningham, B.E., Culnane, M., Coombs, R.W., Scott, G., Van Dyke, R.B., Shearer, W.T., Jimenez, E., Diaz, C., Harrison, D.D., and Delfraissy, J.F., for the Pediatric AIDS Clinical Trials Group Protocol 076 Study Group (1998). Safety of the maternal-infant zidovudine regimen utilized in the Pediatric AIDS Clinical Trial Group 076 study. AIDS 12, 1805–1813.9792381
Stagg, M.P., Cretton, E.M., Kidd, L., Diasio, R.B., and Sommadossi, J.-P. (1992). Clinical pharmacokinetics of 3′-azido-3′-deoxythymidine (zidovudine) and catabolites with formation of a toxic catabolite, 3′-amino-3′-deoxythymidine Clin. Pharmacol. Ther. 51, 668–676.1611806
Steinbrook, R. (2004). The AIDS epidemic in 2004. N. Engl. J. Med. 351, 115–117.15247349
Storer, R.D., French, J.E., Haseman, J., Hajian, G., LeGrand, E.K., Long, G.G., Mixson, L.A., Ochoa, R., Sagartz, J.E., and Soper, K.A. (2001). P53^(+/−)^ hemizygous knockout mouse: Overview of available data. Toxicol. Pathol. 29, 30–50.11695560
Susan-Resiga, D., Bentley, A.T., Lynx, M.D., LaClair, D.D., and McKee, E.E. (2007). Zidovudine inhibits thymidine phosphorylation in the isolated perfused rat heart. Antimicrob. Agents Chemother. 51, 1142–1149.17220403
Sussman, H.E., Olivero, O.A., Meng, Q., Pietras, S.M., Poirier, M.C., O’Neill, J.P., Finette, B.A., Bauer, M.J., and Walker, V.E. (1999). Genotoxicity of 3′-azido-3′-deoxythymidine in the human lymphoblastoid cell line, TK6: Relationships between DNA incorporation, mutant frequency, and spectrum of deletion mutations in HPRT. Mutat. Res. 429, 249–259.10526209
Taburet, A.-M., Naveau, S., Zorza, G., Colin, J.-N., Delfraissy, J.-F., Chaput, J.-C., and Singlas, E. (1990). Pharmacokinetics of zidovudine in patients with liver cirrhosis. Clin. Pharmacol. Ther. 47, 731–739.2357867
Tennant, R.W., French, J.E., and Spalding, J.W. (1995). Identifying chemical carcinogens and assessing potential risk in short-term bioassays using transgenic mouse models. Environ. Health Perspect. 103, 942–950.8529591
Terpstra, T.J. (1952). The asymptotic normality and consistency of Kendall’s test against trend, when ties are present in one ranking. Indagat. Mathemat. 14, 327–333.
Thompson, M.B., Dunnick, J.K., Sutphin, M.E., Giles, H.D., Irwin, R.D., and Prejean, J.D. (1991). Hematologic toxicity of AZT and ddC administered as single agents and in combination to rats and mice. Fundam. Appl. Toxicol. 17, 159–176.1655546
Toltzis, P., Marx, C.M., Kleinman, N., Levine, E.M., and Schmidt, E.V. (1991). Zidovudine-associated embryonic toxicity in mice. J. Infect. Dis. 163, 1212–1218.2037787
Törnevik, Y., Ullman, B., Balzarini, J., Wahren, B., and Eriksson, S. (1995). Cytotoxicity of 3′-azido-3′-deoxythymidine correlates with 3′-azidothymidine-5′-monophosphate (AZTMP) levels, whereas anti-human immunodeficiency virus (HIV) activity correlates with 3′-azidothymidine-5′-triphosphate (AZTTP) levels in cultured CEM T-lymphoblastoid cells. Biochem. Pharmacol. 49, 829–837.7702641
Trang, J.M., Prejean, J.D., James, R.H., Irwin, R.D., Goehl, T.J., and Page, J.G. (1993). Zidovudine bioavailability and linear pharmacokinetics in female B6C3F1 mice. Drug Metab. Dispos. 21, 189–193.8095218
UNAIDS (2008). 2008 Report on the Global AIDS Epidemic. Joint United Nations Programme on HIV/AIDS, New York.
Von Tungeln, L.S., Hamilton, L.P., Dobrovolski, V.N., Bishop, M.E., Shaddock, J.G., Heflich, R.H., and Beland, F.A. (2002). Frequency of Tk and Hprt lymphocyte mutants and bone marrow micronuclei in B6C3F1/Tk^+/−^ mice treated neonatally with zidovudine and lamivudine. Carcinogenesis 23, 1427–1432.12189183
Walker, D.M., Poirier, M.C., Campen, M.J., Cook, D.L., Jr., Divi, R.L., Nagashima, K., Lund, A.K., Cossey, P.Y., Hahn, F.F., and Walker, V.E. (2004). Persistence of mitochondrial toxicity in hearts of female B6C3F1 mice exposed in utero to 3′-azido-3′-deoxythymidine. Cardiovasc. Toxicol. 4, 133–153.15371630
Walker, D.M., Malarkey, D.E., Seilkop, S.K., Ruecker, F.A., Funk, K.A., Wolfe, M.J., Treanor, C.P., Foley, J.F., Hahn, F.F., Hardisty, J.F., and Walker, V.E. (2007). Transplacental carcinogenicity of 3′-azido-3′-deoxythymidine in B6C3F1 mice and F344 rats. Environ. Mol. Mutagen. 48, 283–298.17358026
Weidner, D.A., and Sommadossi, J.-P. (1990). 3′-Azido-3′-deoxythymidine inhibits globin gene transcription in butyric acid-induced K-562 human leukemia cells. Mol. Pharmacol. 38, 797–804.2174502
Williams, D.A. (1986). A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics 42, 183–186.3719054
Williams, L.D., Von Tungeln, L.S., Beland, F.A., and Doerge, D.R. (2003). Liquid chromatographic-mass spectrometric determination of the metabolism and disposition of the anti-retroviral nucleoside analogs zidovudine and lamivudine in C57BL/6N and B6C3F1 mice. J. Chromatogr. B Analyt. Technol. Biomed. Life Sci. 798, 55–62.
Witt, K.L., Tice, R.R., Wolfe, G.W., and Bishop, J.B. (2004). Genetic damage detected in CD-1 mouse pups exposed perinatally to 3′-azido-3′-deoxythymidine or dideoxyinosine via maternal dosing, nursing, and direct gavage: II. Effects of the individual agents compared to combination treatment. Environ. Mol. Mutagen. 44, 321–328.15476197
Witt, K.L., Cunningham, C.K., Patterson, K.B., Kissling, G.E., Dertinger, S.D., Livingston, E., and Bishop, J.B. (2007). Elevated frequencies of micronucleated erythrocytes in infants exposed to zidovudine in utero and postpartum to prevent mother-to-child transmission of HIV. Environ. Mol. Mutagen. 48, 322–329.17358032
World Health Organization Report (WHO) (2004). Report 2004: Changing History. World Health Organization, Geneva.
Yarchoan, R., Weinhold, K.J., Lyerly, H.K., Gelmann, E., Blum, R.M., Shearer, G.M., Mitsuya, H., Collins, J.M., Myers, C.E., Klecker, R.W., Markham, P.D., Durack, D.T., Nusinoff Lehrman, S., Barry, D.W., Fischl, M.A., Gallo, R.C., Bolognesi, D.P., and Broder, S. (1986). Administration of 3′-azido-3′-deoxythymidine, an inhibitor of HTLV-III/LAV replication, to patients with AIDS or AIDS-related complex. Lancet 1 (March 15), 575–580.2869302
Zimmerman, T.P., Mahoney, W.B., and Prus, K.L. (1987). 3′-Azido-3′-deoxythymidine. J. Biol. Chem. 262, 5748–5754.3471758