# NATIONAL TOXICOLOGY PROGRAM TECHNICAL REPORTS PEER REVIEW PANEL

The members of the Peer Review Panel who evaluated the draft NTP Report on 3′-azido-3′-deoxythymidine on February 9, 2012, are listed below. Panel members serve as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, panel members have five major responsibilities in reviewing the NTP studies:

- to ascertain that all relevant literature data have been adequately cited and interpreted,
- to determine if the design and conditions of the NTP studies were appropriate,
- to ensure that the Technical Report presents the experimental results and conclusions fully and clearly,
- to judge the significance of the experimental results by scientific criteria, and
- to assess the evaluation of the evidence of carcinogenic activity and other observed toxic responses.

- Stephen M. Roberts, Ph.D., Chairperson
  College of Veterinary Medicine
  University of Florida
  Gainesville, FL
- Jane Alcorn, D.V.M., Ph.D.
  University of Saskatchewan
  Saskatchewan, Canada
- Lucy M. Anderson, Ph.D., Consultant
  Catonsville, MD
- Hillary M. Carpenter, III, Ph.D.
  Minnesota Department of Health
  St. Paul, MN
- Russell C. Cattley, V.M.D., Ph.D.
  College of Veterinary Medicine
  Auburn University
  Auburn, AL
- Michael R. Elwell, D.V.M., Ph.D., Primary Reviewer
  Covance Laboratories, Inc.
  Chantilly, VA
- Jon C. Mirsalis, Ph.D.
  SRI International
  Menlo Park, CA
- Ofelia A. Olivero, Ph.D., Primary Reviewer
  National Cancer Institute
  Bethesda, MD
- Lisa A. Peterson, Ph.D.
  University of Minnesota
  Minneapolis, MN
- Michael V. Pino, D.V.M., Ph.D.
  Sanofi
  Bridgewater, NJ
- Keith A. Soper, Ph.D., Primary Reviewer
  Merck Research Laboratories
  West Point, PA