# DISCUSSION AND CONCLUSIONS

While the advent of Highly Active Antiretroviral Therapy (HAART) has dramatically decreased rates of morbidity and mortality in people infected with the human immunodeficiency virus (HIV), the long-term toxico-logical consequences of such therapy are unknown (PHS, 2008). 3′-Azido-3′-deoxythymidine (AZT) is a key component of HAART, and while it has been previously studied in cancer bioassays, it has not been studied in combination with other antiretroviral drugs. A major objective of the current studies was to develop and evaluate an animal model that could be used for investigating the potential carcinogenicity of AIDS drug combinations, and the studies utilized the heterozygous F1 p53^+/−^ mouse model for the first time in an NTP study.

This genetically modified mouse used in this study was designed to produce a p53 haploinsufficiency on a genetic background that was similar to the B6C3F1 mouse. However, the parental strains were reversed relative to the B6C3F1 mouse to take advantage of the readily available B6.129-Trp53^tmlBrd(–/–)^ (N12) mouse to supply p53 haploinsufficiency from the paternal side so that healthy wild-type female mice would be exposed to AZT during pregnancy. Unlike many other strains, C3H female mice show excellent tolerance to the handling of their pups during dosing. The observed incidences of hepatocellular adenoma in the male heterozygous F1 p53^+/−^ mice used in this study suggest that these genetically modified mice do express a tumor profile that is similar to the B6C3F1 mouse.

The genetically modified model studies are designed to provide rapid screens for potent carcinogens because the genetic modifications generally decrease the time to tumor manifestation. They are not designed to screen for rare tumors, which requires a larger sample size and extensive historical control data. Increased incidences of both malignant lymphoma and hepatocellular adenoma were observed following exposure to AZT in the current heterozygous F1 p53^+/−^ mouse studies despite the lack of increased incidences of vaginal epithelial tumors which have been reported to occur in rodents exposed to AZT in 2-year evaluations (Ayers et al., 1996a; NTP, 1999). The B6.129-Trp53^tmlBrd(+/–)^ (N12) p53 haploinsufficient mouse model, which was used in previous NTP GMM studies, exhibited a very low incidence of liver neoplasms and was unresponsive to exposure to dichloroacetate (NTP, 2007e), a chemical that has been shown to be hepatocarcinogenic in both B6C3F1 mice and Fischer 344 rats (Bull et al., 1990; DeAngelo et al., 1996).

In the 45-week study, the incidences of hepatocellular adenoma occurred with a positive trend in male heterozygous F1 p53^+/−^ mice and the incidence in the 240/120/240 mg/kg group was significantly increased. In addition, the male mice in the 45-week stop-study, exposed to AZT by maternal gavage from gestational day (GD) 12 through 18 and by direct gavage from postnatal day (PND) 1 through 8, exhibited increased incidences of hepatocellular adenoma and hepato-cellular adenoma or carcinoma (combined), but not at a level that reached statistical significance within the study design. However, these increased incidences of hepatocellular neoplasms should also be considered to be related to AZT administration. While incidences of hepatocellular neoplasms were not increased in female heterozygous F1 p53^+/−^ mice, there was a positive trend in the incidences of malignant lymphoma. Thus, this mouse model appears to show sensitivity comparable to that of the B6C3F1 mouse that has recently been reported to develop increased incidences of hepatocellular carcinoma when exposed to high concentrations of AZT during gestation (Walker et al., 2007). This heterozygous F1 p53^+/−^ mouse is therefore superior to the B6.129-Trp53^tmlBrd(+/–)^ (N12) p53 haploinsufficient mouse for use in GMM studies designed to evaluate potentially hepatocarcinogenic chemicals.

The increased incidences of malignant lymphoma in male heterozygous F1 p53^+/−^ mice continuously exposed to AZT for 30 weeks (Table 5) and in female heterozygous F1 p53^+/−^ mice continuously exposed to AZT for 45 weeks (Table 8) could also be treatment related. Historical incidences for malignant lymphoma in 40-and 45-week studies are 3/101 and 3/102 for male and female heterozygous F1 p53^+/−^ mice, respectively (Appendix I). Conversely, in a previous study, prenatal exposure to AZT reduced the incidence of malignant lymphoma in female CD-1 mice (Diwan et al., 1999). This suggests that postnatal and adult exposure to AZT is required to increase the incidence of malignant lymphoma in mice. Low incidences of malignant neoplasms of the bone (osteosarcoma) and nervous tissue (neuroblastoma, astrocytoma) were also observed in male or female heterozygous F1 p53^+/−^ mice. Incidences were not significantly increased by AZT exposure. These neoplasms are rare in B6C3F1 mice and may arise as a consequence of p53 haploinsufficiency or be related to treatment. The NTP historical control incidences for osteosarcoma are 5/101 and 3/102 for male and female heterozygous F1 p53^+/−^ mice, respectively (Appendix I).

AZT exposure has been linked to development of macrocytic anemia and lactic acidosis in both experimental animals and human AIDS patients (Ayers et al., 1996b). While significant elevations of mean cell hemoglobin and mean cell volume were observed in the heterozygous F1 p53^+/−^ mice continuously exposed to 240/120/240 mg/kg for 30 weeks (terminal evaluation) and/or 160 days, the elevated values remained within the normal ranges, suggesting that the highest doses of AZT used in these studies were below the threshold required to produce macrocytic anemia in this strain of mouse.

While early rodent cancer bioassays of AZT using low doses (20 and 40 mg AZT/kg per day) did not report significant carcinogenic activity (Ayers 1988; Ayers et al., 1997), NTP studies have reported carcinogenic activity when higher doses have been used. For example, B6C3F1/N mice exposed to 60 or 120 mg AZT/kg body weight by gavage for 2 years exhibited increased incidences of vaginal squamous cell carcinoma (females) and Harderian gland adenomas (males) (NTP, 1999). While no increases in the incidences of hepato-cellular neoplasms were reported in that study, data interpretation was complicated by high background liver neoplasm incidences associated with active Helicobacter hepaticus infection. In a followup study using Swiss CD-1^®^ mice exposed to AZT throughout gestation via maternal gavage (NTP, 2006), male F_1_ mice exposed to 200 or 300 mg/kg exhibited increased incidences of lung neoplasms [alveolar/bronchiolar carcinoma and alveolar/bronchiolar adenoma or carcinoma (combined)] at 2-years of age. A study by Walker et al. (2007) reported increased incidences of hepatocellular carcinoma in 2-year-old male B6C3F1 mice exposed during gestation to either 240 or 480 mg/kg AZT.

The mechanisms for the carcinogenic effects of AZT in rodents may be related to how AZT is metabolized. AZT is metabolized by three pathways: glucuroni-dation, which accounts for up to 75% of the human urinary product; mixed-function oxidase-mediated reactions, giving 3′-amino-3′-deoxythymidine, a minor urinary metabolite; and phosphorylation, which occurs throughout the tissues. Phosphorylation is fundamental to the antiviral activity of AZT but accounts for only about 1% of its total disposition. Unchanged AZT constitutes about 20% of the human urinary products. In contrast, the unchanged drug in rats and mice accounts for up to 90% of the drug recovered in the urine (Doshi et al., 1989; Patel et al., 1989; de Miranda et al., 1990). It has been argued that the increased incidence of neoplasms of the vaginal epithelium observed in rodent bioassays may be due to chronic local exposure to unconjugated AZT via urine, which would not occur in humans (Ayers et al., 1996a). While lack of conjugation could also influence AZT concentrations in liver and lung tissues following oral AZT exposure, tissue concentrations have not been directly compared between humans and rodents. However, despite low rates of glucuronidation, oral doses of AZT are rapidly eliminated in mice. For example, the serum half-life of AZT in adult female C57BL/6N mice treated orally with 400 mg AZT/kg was reported to be 44 minutes (Williams et al., 2003).

AZT has a relatively high rate of incorporation into nuclear and mitochondrial DNA of liver and lung tissue after transplacental exposure (Olivero et al., 1997), and this may explain why these tissues are targets for transplacental and neonatal carcinogenicity of AZT. AZT exposure has been reported to evoke a wide range of genotoxic effects in both in vitro and in vivo test systems (Olivero, 2007, 2008). In genotoxicity studies run in conjunction with this bioassay, reticulocyte micronucleus frequency was increased 5.6-, 12.1-, and 19.1-fold in 1-day-old heterozygous F1 p53^+/−^ mice given 80, 160, or 240 mg AZT/kg per day, respectively, during gestation, and increased 9.1-, 24.7-, and 13.3-fold in 10-day-old heterozygous F1 p53^+/−^ mice neonatally exposed to 40, 80, or 120 mg AZT/kg per day, respectively.

While there have been no reports of AZT causing cancer in humans, a recent epidemiology study reported that patients with HIV infection or acquired immunodeficiency syndrome (AIDS) have increased risk of developing lung cancer (Kirk et al., 2007). Since the increased risk was not significantly correlated with either HAART or low CD4^+^ cell count, it is not yet known whether AZT exposure contributes to this increased cancer risk. Cancer takes time to develop, and further follow-up of patients is required to determine any association between AZT (and other retroviral drugs) and long-term adverse effects, including cancer. While the benefits of HAART clearly outweigh the potential short-term risks of AZT and other AIDS therapeutics for individuals exposed to HIV, more information is needed on the long-term consequences of HAART so that the therapeutic regimes can be optimized for long-term health. The heterozygous F1 p53^+/−^ mouse model provides a useful tool for further evaluating the hepatocarcinogenic potential of AZT when used alone or in combination with other therapeutic agents. It has the advantage of providing data within 12 months of study initiation and if sufficient animal numbers are used to provide statistical power, it promises high sen sitivity for detecting hepatocarcinogenicity and possibly other neoplasia.

## Conclusions

Under the conditions of these gavage studies, there was clear evidence of carcinogenic activity^*^ of AZT in male heterozygous F1 p53^+/−^ mice based on the occurrence of hepatocellular neoplasms (predominantly adenomas) after 45 weeks of administration. The occurrence of malignant lymphoma may have been related to AZT administration for 30 weeks. There was equivocal evidence of carcinogenic activity of AZT in female heterozygous F1 p53^+/−^ mice based on the occurrence of malignant lymphoma after 45 weeks of administration.

* Explanation of Levels of Evidence of Carcinogenic Activity is on page 10. A summary of the Peer Review Panel comments and the public discussion on this Report appears on page 12.