# RESULTS

## Litter Success and Pup Survival

As shown in Table 3, AZT at the doses used was relatively nontoxic to both the pregnant dams and neonatal heterozygous F1 p53^+/−^ mouse pups. There were no apparent treatment-related effects on both litter success and pup survival to postnatal day (PND) 28, which was greater than 90% in all dose groups.

## 30-Week Study

### Survival

Estimates of 30-week survival probabilities for male and female mice are shown in Table 4 and Figure 3. Survival of males in the 240/120/240 mg/kg group was significantly less than that of the 0/0/0 mg/kg group.

TABLE 3 Litter Parameters and Pup Survival for Mouse Pups in the In Utero/Postnatal Gavage Studies of AZT

| 0/0/0 (0/0) mg/kg^a^ | 80/40/80 mg/kg | 160/80/160 mg/kg | 240/120/240 (240/40) mg/kg^a^
Total dams pregnant | 50 | 22 | 19 | 53
Dams which did not litter | 4 | 4 | 3 | 3
Total litters | 46 | 18 | 16 | 50
Total pups born | 314 | 141 | 105 | 351
Average born per litter | 6.8 | 7.8 | 6.8 | 7.0
Number of males born^b^ | 152 (48.4) | 69 (48.9) | 56 (53.3) | 174 (49.6)
Sex ratio^c^ | 1:0.97 | 1:1.01 | 1:0.88 | 1:0.94
Pups born dead (%) | 14 (4.5) | 2(1.4) | 0 (0) | 13 (3.7)
% Survival PND 1 – PND 10^d^ | 92.8 | 98.1 | 97.8 | 95.3
% Survival PND 11 – PND 28^d^ | 96.7 | 91.1 | 98.9 | 93.8

a Litters dosed to provide stop-study pups are included in the litter and pup birth data but are excluded from the pup survival estimates. Postnatal survival for stop-study pups was 98.6% and 96.5% between PND 1 and PND 10 for the 0/0 mg/kg group and 240/40 mg/kg groups, respectively, and 98.6% and 100% between PND 11 and PND 28 for the 0/0 mg/kg group and 240/40 mg/kg groups, respectively.

b Excludes pups born dead, percent of total live pups given in parentheses

c Male:female

d Excludes pups culled on PND 1 and stop-study litters

TABLE 4 Survival of Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT

| 0/0/0 mg/kg | 240/120/240 mg/kg
Male
Animals initially in study | 27 | 26
Number of litters/group | 22 | 21
Moribund | 0 | 4
Natural deaths | 0 | 1
Mice surviving to study termination | 27 | 21
Percent probability of survival to end of study^a^ | 100.0 | 80.8
Mean survival (days) | 229.3 | 214.5
Survival analysis^b^ | | P=0.034
Female
Animals initially in study | 27 | 26
Number of litters/group | 22 | 23
Moribund | 2 | 0
Natural death | 1 | 0
Mice surviving to study termination | 24 | 26
Percent probability of survival to end of study | 88.9 | 100.0
Mean survival (days) | 217.4 | 228.7
Survival analysis | | P=0.258N

a Kaplan-Meier determinations

b Results of the life table pairwise comparisons (Cox, 1972) with the 0/0/0 mg/kg group. A lower mortality in a dosed group is indicated by N.

FIGURE 3 Kaplan-Meier Survival Curves for Mice Administered AZT by Gavage in the 30-Week In Utero/Postnatal Study of AZT

### Body Weights, Organ Weights, and Clinical Pathology

Growth curves for male and female mice are shown in Figure 4. For male body weights, dose, time, and the interaction of dose and time were significant effects (Table D1). Males administered AZT had significantly lower body weights compared to the 0/0/0 mg/kg group during the duration of the study (Tables D2 and D3). For females, there were significant dose and time effects; however the interaction of dose and time was not significant. Throughout the study, females administered AZT had significantly lower body weights compared to those of the 0/0/0 mg/kg group.

Absolute kidney weights were significantly less in 240/120/240 mg/kg males and females compared to the 0/0/0 mg/kg groups, but the relative kidney weights were similar (Table E1). Mean cell volume and mean cell hemoglobin in dosed females and mean cell volume in dosed males were significantly increased at the end of the study (Table C1); when severe, these changes are characteristic of macrocytic anemia. However, these increases were within normal physiological ranges for mice, suggesting minimal macrocytosis rather than pathologic macrocytic anemia.

FIGURE 4 Growth Curves for Mice Administered AZT by Gavage in the 30-Week In Utero/Postnatal Study of AZT

### Pathology and Statistical Analysis

This section describes the statistically significant or biologically noteworthy changes in the incidences of malignant lymphoma and neoplasms of the bone and brain. Significant changes in the incidences of nonneoplastic lesions included lymphocytic cellular infiltration of the kidney and lymphocytic cellular infiltration of the salivary gland, which were both reduced in male and female mice administered 240/120/240 mg/kg relative to the incidences in the 0/0/0 mg/kg groups. Summaries of the incidences of neoplasms and nonneoplastic lesions and statistical analysis of selected primary neoplasms are presented in Appendix A (Tables A1 through A6).

Malignant Lymphoma: In male mice administered 240/120/240 mg/kg, the incidence of malignant lymphoma was increased compared to that in the 0/0/0 mg/kg group and this contributed to the increased mortality in treated male mice. Although the increased incidence of malignant lymphoma was not statistically significant when evaluated with a standard Poly-3 analysis, it was significant (P=0.005) when adjustments for litter correlations were made (Tables 5, A1, A2, and G6).

Other Findings: The AZT-treated male mice exhibited low incidences of bone and brain neoplasms; these lesions did not occur in the 0/0/0 mg/kg males (Tables 5, A1, and A2).

Litter Correlation Analysis: When statistical analysis incorporating correlation of influence among littermates was used to compute incidences of neoplasms (Appendix G), statistical significance generally increased (i.e., P values decreased) suggesting that there was no positive correlation between tumor incidence and litter. While in most cases these changes were insufficient to decrease P values for the incidences of neoplasms below the 5% definition of significance, the significance of the incidence of malignant lymphoma was altered by this analysis (Tables 5 and G6).

TABLE 5 Incidences of Malignant Neoplasms in Male Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT

| 0/0/0 mg/kg | 240/120/240 mg/kg
Femur^a^ | 27 | 26
Osteosarcoma^b^ | 0 | 1
Cerebrum | 27 | 26
Astrocytoma Malignant | 0 | 1
Olfactory Lobe, Neuroblastoma | 0 | 1
All Organs
Malignant Lymphoma
Overall rate^c^ | 0/27 (0.0%) | 3/26 (11.5%)
Adjusted rate^d^ | 0.0% | 11.9%
Terminal rate^e^ | 0/27 (0.0%) | 0/21 (0.0%)
First incidence (days) | —^g^ | 84
Poly-3 test^f^ | | P=0.102
Litter-adjusted Poly-3 rate | 0.0% | 14.4%
Litter-adjusted Poly-3 test | | P=0.005

a Number of animals with tissue examined microscopically

b Number of animals with neoplasm

c Number of animals with malignant lymphoma per number of animals examined microscopically

d Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

e Observed incidence at terminal kill

f Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg group and the 240/120/240 mg/kg group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

g Not applicable; no neoplasms in animal group

## 45-Week Study

### Survival

Estimates of 45-week survival probabilities for male and female mice are shown in Table 6 and Figure 5. Compared to the 0/0/0 mg/kg groups, there was no significant difference in survival across AZT dose groups in either males or females.

### Body Weights, Organ Weights, and Hematology

Growth curves for male and female mice are shown in Figure 6. Exposure to AZT caused small decreases in body weight relative to vehicle control mice. These decreases were not statistically significant for any dose group in either males or females when compared for each week of the study (Table D6). However, the overall comparison was significant for dose (P=0.002 and P=0.014 for males and females respectively, Table D4). In addition, there were significant negative linear trends with dose, such that for each increment in AZT dose there was, on average, a 6.3 and 4.2 g decrease in body weight for male and female mice, respectively (Table D5).

Absolute brain weights were significantly less in 240/120/240 mg/kg males and in all three dosed groups of females compared to those in the 0/0/0 mg/kg groups, but relative brain weights were not significantly different (Table E2). Mean cell volume and mean cell hemoglobin evaluated at 160 days were significantly increased in 240/120/240 mg/kg males and females (Table C2), which is characteristic of macrocytic anemia; however, as with the mice evaluated at 30 weeks, these increases were within the normal physiological ranges for mice, suggesting minimal macrocytosis rather than pathologic macrocytic anemia.

TABLE 6 Survival of Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT

| 0/0/0 mg/kg | 80/40/80 mg/kg | 160/80/160 mg/kg | 240/120/240 mg/kg
Male
Animals initially in the study | 27 | 27 | 27 | 27
Number of litters/group | 24 | 14 | 15 | 25
Moribund | 2 | 4 | 0 | 2
Natural deaths | 1 | 2 | 0 | 3
Animals surviving to study termination | 24 | 21 | 27 | 22
Percent probability of survival to end of study^a^ | 88.9 | 77.8 | 100.0 | 81.5
Mean survival (days) | 316.7 | 298.4 | 335.5 | 311.3
Survival analysis^b^ | | P=0.241 | P=0.184N | P=0.458
Female
Animals initially in the study | 26 | 27 | 27 | 27
Number of litters/group | 23 | 13 | 15 | 25
Moribund | 2 | 2 | 1 | 3
Natural deaths | 1 | 2 | 2 | 3
Animals surviving to study termination | 23 | 23 | 24 | 21
Percent probability of survival to end of study | 88.5 | 85.2 | 88.9 | 77.8
Mean survival (days) | 326.7 | 316.7 | 323.9 | 316.2
Survival analysis | | P=0.701 | P=0.928N | P=0.334

a Kaplan-Meier determinations

b Results of the life table pairwise comparisons (Cox, 1972) with the 0/0/0 mg/kg group. A lower mortality in a dosed group is indicated by N.

FIGURE 5 Kaplan-Meier Survival Curves for Mice Administered AZT by Gavage in the 45-Week In Utero/Postnatal Study of AZT

FIGURE 6 Growth Curves for Mice Administered AZT by Gavage in the 45-Week In Utero/Postnatal Study of AZT

### Pathology and Statistical Analysis

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms of the liver in male mice, of malignant lymphoma and other malignant neoplasms in females, and nonneoplastic lesions of the preputial gland in male mice and of the pancreas and bone marrow in females. Summaries of the incidences of neoplasms and nonneoplastic lesions and statistical analysis of selected primary neoplasms are presented in Appendix A (Tables A7 through A12). Historical control incidences for neoplasms in heterozygous F1 p53^+/−^ mice are shown in Appendix I.

Liver: The incidences of hepatocellular adenoma in males occurred with a positive trend, and the incidence in the 240/120/240 mg/kg group was significantly greater than that in the 0/0/0 mg/kg group (Tables 7, A7, and A8). A single hepatocellular carcinoma occurred in the 80/40/80 mg/kg group.

TABLE 7 Incidences of Hepatocellular Neoplasms in Male Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT

| 0/0/0 mg/kg | 80/40/80 mg/kg | 160/80/160 mg/kg | 240/120/240 mg/kg
Hepatocellular Adenoma^a^
Overall rate^b^ | 3/26 (11.5%) | 2/27 (7.4%) | 6/27 (22.2%) | 9/27 (33.3%)
Adjusted rate^c^ | 12.3% | 8.8% | 22.2% | 36.5%
Terminal rate^d^ | 3/24 (12.5%) | 2/21 (9.5%) | 6/27 (22.2%) | 7/22 (31.8%)
First incidence (days) | 321 (T) | 319 (T) | 320 (T) | 228
Poly-3 test^e^ | P=0.013 | P=0.531N | P=0.288 | P=0.048
Hepatocellular Adenoma or Carcinoma
Overall rate | 3/26 (11.5%) | 3/27 (11.1%) | 6/27 (22.2%) | 9/27 (33.3%)
Adjusted rate | 12.3% | 13.2% | 22.2% | 36.5%
Terminal rate | 3/24 (12.5%) | 3/21 (14.3%) | 6/27 (22.2%) | 7/22 (31.8%)
First incidence (days) | 321 (T) | 319 (T) | 320 (T) | 228
Poly-3 test | P=0.019 | P=0.634 | P=0.288 | P=0.048

(T)Terminal kill

a Historical incidence for control groups in 40- and 45-week heterozygous F1 p53^+/−^ mouse studies: 8/100, range 4.0%-12.5%

b Number of animals with neoplasm per number of animals with liver examined microscopically

c Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

d Observed incidence at terminal kill

e Beneath the 0/0/0 mg/kg group incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg group and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in a dosed group is indicated by N.

Malignant Lymphoma: A significant positive trend occurred in the incidences of malignant lymphoma in female mice; this neoplasm occurred in the 160/80/160 and 240/120/240 mg/kg groups, but not in the 0/0/0 mg/kg group. When analyzed with the standard Poly-3 test, no significant differences in incidences were found between the treated groups and the 0/0/0 mg/kg group (Tables 8 and A11).

Other Malignant Neoplasms: Both male and female heterozygous F1 p53^+/−^ mice exhibited low incidences of several malignant neoplasms, which appear to be characteristic of this strain. In females, some of these neoplasms, including osteosarcoma and mammary gland adenocarcinoma exhibited higher incidences in treated groups than in the 0/0/0 mg/kg group (Tables A10 and A11). These contributed to increases (not significant) in the overall incidences of malignant neoplasms in 160/80/160 and 240/120/240 mg/kg females (Table A11). There were no incidences of vaginal epithelial neoplasms in any dose group (Table A10). Complete lists of all neoplastic lesions observed in each male or female mouse used in the study are shown in Tables G1 and G2.

Nonneoplastic lesions: Incidences of several nonneoplastic lesions were increased in dosed groups relative to the 0/0/0 mg/kg groups. In males, preputial gland degeneration was observed only in the 240/120/240 mg/kg group (0/0/0 mg/kg, 0/27; 80/40/80 mg/kg, 0/26; 160/80/160 mg/kg, 0/27; 240/120/240 mg/kg, 3/26; Table A9), and in females, incidences of lymphocytic cellular infiltration of the pancreas (0/26, 0/27, 1/27, 3/26, Table A12) and myeloid cell hyperplasia of bone marrow (0/26, 0/26, 4/26, 1/26, Table A12) showed dose-related increases.

Litter Correlation Analysis: When statistical analysis incorporating correlation of influence among littermates was used to compute incidences of neoplasms (Appendix G), statistical significance generally increased (i.e., P values decreased) suggesting that there was no positive correlation between tumor incidence and litter. In most cases, this did not decrease P values below the 5% definition of significance. However, in the case of malignant lymphoma in female mice, significance of the 3/27 incidence in the 240/120/240 mg/kg group relative to the 0/0/0 mg/kg group incidence (0/26) increased from P=0.115 for the non-litter-adjusted Poly-3 test to P=0.033 for the litter-adjusted Poly-3 test (Tables 8 and G10). Incidences of preputial gland degeneration in males (Table G13), and lymphocytic cellular infiltration of the pancreas and myeloid cell hyperplasia of the bone marrow in females (Table G16) exhibited statistically significant increases when litter-adjusted evaluations were performed, but not when the naive Poly-3 evaluations were performed (Tables A9 and A12).

TABLE 8 Incidences of Malignant Lymphoma in Female Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT

| 0/0/0 mg/kg | 80/40/80 mg/kg | 160/80/160 mg/kg | 240/120/240 mg/kg
Malignant Lymphoma^a^
Overall rate^b^ | 0/26 (0.0%) | 0/27 (0.0%) | 1/27 (3.7%) | 3/27 (11.1%)
Adjusted rate^c^ | 0.0% | 0.0% | 4.0% | 12.2%
Terminal rate^d^ | 0/23 (0.0%) | 0/23 (0.0%) | 1/24 (4.2%) | 2/21 (9.5%)
First incidence (days) | —^f^ | — | 322 (T) | 241
Poly-3 test^e^ | P=0.020 | —^g^ | P=0.505 | P=0.115
Litter-adjusted Poly-3 rate | 0.0% | 0.0% | 4.0% | 12.2%
Litter-adjusted Poly-3 test | P=0.023 | — | P=0.148 | P=0.033

(T)Terminal kill

a Historical incidence for control groups in 40- and 45-week heterozygous F1 p53^+/−^ mouse studies: 3/102, range 0.0%–8.0%

b Number of animals with malignant lymphoma per number of animals examined microscopically

c Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

d Observed incidence at terminal kill

e Beneath the 0/0/0 mg/kg group incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg group and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

f Not applicable; no neoplasms in animal group

g Value of statistic cannot be computed.

## 45-Week Stop-Study

### Survival

Estimates of 45-week survival probabilities for male and female mice are shown in Table 9 and Figure 7. There was no effect of AZT administration on survival in males or females.

### Body Weights and Organ Weights

Growth curves for male and female mice are shown in Figure 8. There were significant dose and time effects on body weight in males and a significant time effect in females (Table D7). Dosed male mice had significantly lower body weights compared to the 0/0 mg/kg group (Tables D8 and D9). Absolute brain weights of dosed groups of males and females were significantly less than those of the 0/0 mg/kg group, though relative brain weights were not significantly altered (Table E3).

TABLE 9 Survival of Mice in the 45-Week In Utero/Postnatal Gavage Stop-Study of AZT

| 0/0 mg/kg | 240/40 mg/kg
Male
Animals initially in study | 24 | 25
Number of litters/group | 13 | 14
Moribund | 1 | 2
Natural death | 0 | 1
Mice surviving to study termination | 23 | 22
Percent probability of survival to end of study^a^ | 92.0 | 88.0
Mean survival (days) | 330.9 | 320.2
Survival analysis^b^ | | P=0.276
Female
Animals initially in study | 26 | 26
Number of litters/group | 13 | 14
Moribund | 0 | 3
Natural death | 1 | 0
Mice surviving to study termination | 25 | 23
Percent probability of survival to end of study | 96.2 | 88.5
Mean survival (days) | 331.5 | 326.6
Survival analysis | | P=0.261

a Kaplan-Meier determinations

b Results of the life table pairwise comparisons (Cox, 1972) with the 0/0 mg/kg group

FIGURE 7 Kaplan-Meier Survival Curves for Mice Administered AZT by Gavage in the 45-Week In Utero/Postnatal Stop-Study of AZT

FIGURE 8 Growth Curves for Mice Administered AZT by Gavage in the 45-Week In Utero/Postnatal Stop-Study of AZT

### Pathology and Statistical Analyses

Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Appendix A (Tables A13 through A18). There were no significant changes in the incidences of neoplasms in male or female mice in the 45-week stop-study.

Liver: The incidences of hepatocellular adenoma and hepatocellular adenoma or carcinoma (combined) were slightly increased in 240/40 mg/kg males [hepatocellular adenoma: 0/0 mg/kg, 3/24; 240/40 mg/kg, 5/25; hepatocellular adenoma or carcinoma (combined): 3/24, 7/25; Table A14]. These increases occurred despite a significant decrease in body weight, suggesting that if a larger sample size had been used, a significant increase in the incidences of hepatocellular neoplasms might have been observed.

Litter Correlation Analysis: When statistical analysis incorporating correlation of influence among littermates was used to compute incidences of neoplasms (Appendix G), statistical significance generally increased (i.e., P values decreased) suggesting that there was no positive correlation between tumor incidence and litter. However, these changes were insufficient to decrease P values for the incidences of neoplasms below the 5% definition of significance.

## Genetic Toxicology

In pups that were evaluated on PND 1, having been exposed to AZT transplacentally from GD 12 through GD 18, there was a significant decrease in the percentage of reticulocytes in the red blood cell population in the 160 and 240 mg/kg groups of male pups and in all three exposed groups of female pups (Table B1). In both sexes, this was associated with a significant negative dose trend. AZT exposure did not significantly alter the percentage of reticulocytes in the red blood cell population at the later evaluation time points (Tables B2, B3, and B4). Both the percentage of micronucleated normochromatic erythrocytes (NCEs) and the percentage of micronucleated reticulocytes (RETs) were significantly increased relative to the corresponding 0, 0/0, or 0/0/0 mg/kg group values in 1-day-old pups exposed to 160 or 240 mg/kg (except percent micronucleated NCEs in 160 mg/kg females); in 10-day-old pups administered 80/40, 160/80, or 240/120 mg/kg (except percent micronucleated RETs in 80/40 mg/kg females); in 28-day-old pups administered 80/40/80, 160/80/160, or 240/120/240 mg/kg (except percent micronucleated NCEs in 80/40/80 mg/kg females); and in 30-week-old mice administered 240/120/240 mg/kg.