# APPENDIX G LITTER EFFECTS ON SURVIVAL, BODY WEIGHT, AND PATHOLOGY

## Background

The study design consisted of three different dosing regimens: (1) 30-week continuous dosing consisting of two dose groups (0/0/0 and 240/120/240 mg AZT/kg body weight per day); (2) 45-week continuous dosing consisting of four dose groups (0/0/0, 80/40/80, 160/80/160 and 240/120/240 mg/kg per day); and (3) 45-week stop-study (0/0 and 240/40 mg/kg per day). There were 24 to 27 animals per sex per dose group.

Female C3H/HeNTac wild-type mice were mated with male homozygous, p53-null C57BL/6(N12)Trp53^(−/−)^ mice in order to produce heterozygous F1 p53^+/−^ offspring. Each male was mated consecutively with up to six females. The pregnant females were randomized to the treatment groups and heterozygous F1 p53^+/−^ mice were bred into the study. The mice were dosed by gavage. The pregnant females were dosed daily from gestational day (GD) 12 through GD 18. On postnatal day (PND) 1, heterozygous F1 p53^+/−^ mice were culled to six pups (three males and three females where possible) and postnatal dosing was initiated. The pups were dosed with half the adult dose in half the dosing volume, except in the 45-week stop-study where pups received one-sixth of the maternal dose in half the dose volume. Pups from the same litters could be utilized for the 30- and 45-week continuous dosing studies, because they used the same dosing regimen. Different litters were used for the 45-week stop-study. Pups were weighed and dosed as a litter (i.e. each pup received a dose calculated from the total weight of the litter divided by the number of surviving pups in that litter) from PND 1 through PND 10 for the 30-week and 45-week continuous dosing studies and from PND 1 through PND 8 (with either vehicle or 40 mg/kg) for the 45-week stop-study. For the continuous dosing studies, the pups were individually weighed and administered the same adult dose as their mother from PND 11 onwards. Pups used for the 45-week stop-study were not dosed after PND 8.

The heterozygous F1 p53^+/−^ mice were weaned on PND 21 and assigned to either stay on study or to be culled on PND 28 for genotoxicity evaluations (see Appendix B). In general, either one or two mice of each sex from the same litter were assigned to each study; however, in certain cases three or four pups had to be assigned in order to provide sufficient mice to complete the dose group. The litter and sire assignments of all pups assigned to the three studies are shown in Tables G1 and G2. The primary experimental unit in this study was the heterozygous F1 p53^+/−^ pup. However, because the male C57BL/6(N12)Trp53^(−/−)^ mice used in these studies sired multiple litters and more than one pup per litter was loaded into the studies, two potential clustering factors existed: common litter origin and common sire. While all pups within a litter received the same treatment (i.e. litter implies treatment group), pups from the same sire were not restricted to the same litter (i.e. sire does not imply treatment group).

Additional analyses were performed as outlined below to determine whether these clustering factors had any significant influence on the outcome of the survival, body weight, and pathology evaluations in the three studies.

## Methods

### Survival

A proportional hazards model (Cox, 1972) was run by Sex and Group using Days-On-Study, the censor flag, and AZT dose as the predictor. For the 45-week continuous dosing study, a linear trend estimate was formed using contrasts.

The proportional hazards assumption was checked using the method of Lin et al. (1993). The litter or sire effect clustering was adjusted for by using the aggregated sandwich estimate of variance (Lin and Wei, 1989; Binder, 1992). Ties were handled by Efron’s (1977) method.

All tests of interest were single degree-of-freedom tests and were transformed into estimate ± standard error and given a Z-score testing against zero and a single-sided P value following NTP convention of appending an “N” for negative dose effects.

Three sex × group × dose combinations had no dead/moribund events: 0/0/0 mg/kg males in the 30-week study, 240/120/240 mg/kg females in the 30-week study, and 160/80/160 mg/kg males in the 45-week study. To facilitate convergence for the analyses involving these combinations, an augmented dataset was created by adding a dummy event at the study termination time for each combination and weighting the observation as one-tenth of an observation. Actual observations were weighted as a full observation.

### Body Weight

A repeated measures model with a heterogeneous autoregressive covariance structure was used for the analyses of body weight unadjusted for litter or sire (Appendix D). The repeated measures model refers to the fact that multiple observations were taken on the same animal over time and that the observations for this animal are likely to be more alike than those between two different animals. The design within dosing regimen and sex was a one-way repeated measures model with AZT dose as the fixed effect and time as the repeated measures variable. Testing for an overall linear or quadratic dose trend was accomplished using contrasts. Dunnett’s tests (Dunnett, 1955) on AZT dose were computed for each time point. These tests compared each dosed group with the vehicle control group and made an adjustment for the fact that several comparisons were being carried out concurrently. Summary statistics for the animals’ body weights (in grams) are presented by sex, time (in weeks), and AZT dose (in order to compare dose effects) for each dosing regimen.

The body weight data for each animal were rasterized to evenly-spaced time points (every week) via locally weighted scatterplot smoothing scoring (Cleveland, 1979; Cleveland et al., 1988). This process reduces the number of time points for the mixed-effects model, reduces the effects of outliers, and creates a grid of regularly spaced time points. The scored data were then treated as primary data for the mixed-effects model.

This study needed to correct for possible correlation among littermates and it was long enough to demonstrate variance heterogeneity over time. Therefore, a choice was necessary because of the difficulty in simultaneously adjusting for litters and for variance heterogeneity. The analysis opted to keep litter-adjustments and to estimate the model at each time point. These models were run separately for each sex. The model treated body weight as a function of treatment group. Observations within each litter (dam- or sire-determined) were presumed to be correlated at a given time point. Since separate analyses were performed at each time point, the variance was allowed to change.

In order to better summarize the results, a two-stage analysis was also conducted for each sex × study duration combination on two aspects of the growth curves: early growth rate (slope between 2 and 5 weeks for all studies) and late growth rate (slope between 38 and 44 weeks for the 45-week studies and slope between 23 and 29 weeks for the 30-week study). These analyses determined whether there were any treatment-related effects on early growth or late growth.

Dunnett’s method was used to compare dose levels to control within each drug combination at each age. A polynomial contrast was used to test for linear trend with dose at each age. Contrasts were used to compare drug combinations within dose levels at each age.

### Pathology

For neoplastic lesions, the Poly-k method of Bailer and Portier (1988) as modified by Bieler and Williams (1993) and NIEHS (continuity correction) was used to analyze age-adjusted incidence. For liver neoplasms in male mice, a k=5 analysis was run in addition to the standard k=3 analysis because comparison between the neoplasm incidences at 30 weeks and 45 weeks suggested a steeper tumor progression curve for heterozygous F1 p53^+/−^ mice than for B6C3F1 mice that are used in 2-year carcinogenicity studies.

Bieler and Williams (1993), in the derivation of their variance correction, used the fact that the Cochran-Armitage test can be envisioned as a binomial-weighted regression. Beginning with a regression paradigm with binomial weights, this framework can be generalized and the Cochran-Armitage test can be viewed as a generalized linear model (GLIM) with binomial variation and an identity link function. If this analysis is performed with Poly-k weights, the resulting analysis can be used with more complex designs, including litter correlations and factorial effects as well as alternative link functions.

Correlation among littermates (litter adjusted) was achieved by using the GLIM described above with estimation using generalized estimating equations (GEE) (Liang and Zeger, 1986) and an exchangeable correlation among littermates. Sire-adjusted analyses were generated in the same manner differing only in the specification of the correlation group variable.

It should be noted that the implementation details of this method are different from the Bieler and Williams variance-adjusted Poly-k test (Bieler and Williams, 1993). Particularly, the variance is not quantal adjusted and all comparisons are estimated within a single analysis of variance model rather than multiple regression models. Suitable contrasts were used to test the relevant hypotheses. One-sided results were generated and, per NTP custom, an “N” was appended to indicate negative trends. Since the variance structure is group specific rather than estimated from the null hypothesis, uniform treatment groups were dealt with by adding an uncorrelated dummy lesion observation to all groups (if necessary for any group) with value=0.005 and Poly-3 weight=0.005.

The presented results include the usual unadjusted Bieler and Williams’ quantal-adjusted Poly-3, Poly-3 weighted binomial/identity-link GLIM with litter-adjusted GEE correlation, and Poly-3 weighted binomial/identity-link GLIM with sire-adjusted GEE correlation.

For nonneoplastic lesions, the Poly-k method was used with k=3 to analyze age-adjusted incidences and the nonzero severity score averages were computed. The cluster-adjusted models were used here, also. In addition, to incorporate lesion severity scores, the distribution-free (but unadjusted for age) method of Jonckheere (1954) and Terpstra (1952) was used to compute monotonic trend tests, and the method of Shirley (1977) as modified by Williams (1986) was used to compute comparisons to the vehicle controls (JT/SW). No attempt was made to adjust JT/SW for correlation among clusters.

## Results

### Survival

In the 30-week study, dosed male mice exhibited significantly greater hazard compared to the 0/0/0 mg/kg group, indicated by five early deaths or moribund animals in the 240/120/240 mg/kg group relative to no early deaths or moribund animals in the 0/0/0 mg/kg group. Malignant lymphoma was present in three of the five early removals. Cluster analyses for litter or sire effects did not alter the empirical variance or its significance (Table G3).

There is no indication that AZT significantly increased the hazard in female mice dosed continuously with 240/120/240 mg/kg until 30 weeks, in male or female mice dosed continuously with 80/40/80, 160/80/160, or 240/120/240 mg/kg until 45 weeks, or in male or female mice dosed with 240/40 mg/kg until PND 8 and killed at 45 weeks. Cluster analyses for litter or sire effects did not alter the empirical variance or significance of any of these dose groups (Tables G3, G4, and G5).

Two AZT dose groups demonstrated significantly smaller hazard than the vehicle control group: 30-week study females administered 240/120/240 mg/kg (Table G3) and 45-week study males administered 160/80/160 mg/kg (Table G4). As before, this was due to the lack of failures in these AZT-dosed groups in this study and not to any other distinction. It seems unlikely that AZT serves any protective function and the result is more likely due to chance.

The linear trend tests performed for the 45-week study males were significant (Table G4). This was due to the zero failures in the 160/80/160 mg/kg males; if this cell is ignored then no significant trends are apparent. For the 45-week stop-study, there was no significant dose effect on survival in either male or female mice with or without adjustment for litter or sire clustering (Table G5).

The results tend to indicate that intralitter correlation with regards to survival is either not present or is negative. In any case, merely using the empirical variance estimator caused far more impact than the actual aggregation over dams (litters) or sires.

### Body Weight

The unadjusted body weight tables are shown in Appendix D. The two adjusted analyses (data not shown) were generally identical to the unadjusted analysis (Appendix D).

### Pathology

The following results refer to the litter-adjusted analyses unless otherwise stated. Liver hepatocellular adenoma was the only non-systemic neoplasm found to occur within male mice in sufficient quantity to justify analysis. Hepatocellular carcinoma was also found in males (although in insufficient numbers to justify its own analysis). Therefore, the hepatocellular adenoma or carcinoma pool was also analyzed. The only neoplasm found within female mice in sufficient quantity to justify analysis was the systemic lesion malignant lymphoma.

#### Neoplasms

Generally, the adverse dose-response effects in males were not very notable with the exception of incidences of hepatocellular adenoma.

For males in the 45-week study, significant positive trends occurred in the incidences of hepatocellular adenoma and hepatocellular adenoma or carcinoma (combined), and the incidences of these lesions in the 240/120/240 mg/kg group were significantly increased relative to the 0/0/0 mg/kg group (Table G7). Using k=5 rather than k=3 for the Poly-k survival adjustment did not alter the significance of the tumor incidence increases. Incidences of benign neoplasms (in all organs) showed a significant positive dose trend but no individual dose group incidence differed significantly from that in the 0/0/0 mg/kg group. Adjusting the data for intralitter correlation did not substantially change the conclusions, and in these tumor pools, the estimated correlation was negative or nearly zero. P values were decreased slightly for the litter-adjusted and sire-adjusted Poly-3 tests relative to those of the naive Poly-3 test.

In the 30-week study, incidences (in all organs) of malignant lymphoma, malignant neoplasms, and benign and malignant neoplasms (combined) were significantly increased in 240/120/240 mg/kg males compared to those in the 0/0/0 mg/kg group (Table G6). The naive analysis did not find the incidence of malignant lymphoma to be significantly increased.

No significant dose effects were found in 45-week stop-study males (Table G8).

Generally, the adverse dose-response effects in females were not very notable. For females in the 45-week study, significant positive trends occurred in the incidences (in all organs) of malignant lymphoma and malignant neoplasms found (Table G10), and the incidence of malignant lymphoma in the 240/120/240 mg/kg group was significantly increased compared to that in the 0/0/0 mg/kg group. Using the naive analysis, there was no significant trend in the incidences of malignant neoplasms and, although there was a positive trend in the incidences of malignant lymphoma, the incidence in the 240/120/240 mg/kg group did not differ from that in the 0/0/0 mg/kg group.

No significant dose effects were found in females in the 30-week study (Table G9) or 45-week stop-study (Table G11).

#### Nonneoplastic Lesions

In general, AZT administration significantly increased the incidence or severity of few nonneoplastic lesions when analyzed by naive Poly-3 tests not adjusting for litter or sire correlation. Adjusting for either litter or sire increased the number of significantly increased nonneoplastic lesion incidences.

In males, positive dose effects were found in the 45-week study in the incidences of preputial gland degeneration and hyperplasia of the cecum when adjusted for litter or sire effects but not with the naive Poly-3 analysis (Table G13). The sire-adjusted analysis also showed the incidence of cellular infiltration of the kidney in 45-week 80/40/80 mg/kg males to be significantly increased, although this result was inconsistent with the (nonsignificant) dose trend in this study and with the significantly decreased incidence in the 30-week study (Table G12). There were several other decreases in the incidences of nonneoplastic lesions, which differed in significance between the naive and adjusted evaluations; details appear in Tables G12 through G14. Generally, the adverse dose responses were not very notable.

In females, the only positive dose effects found were in the 45-week study, including increased incidences of cerebral mineralization, myeloid cell bone marrow hyperplasia, cellular infiltration of the pancreas, and tension lipidosis of the liver (Table G16). These increases were significant when adjusted for litter or sire effects but not with the naive Poly-3 analysis. The only notable positive dose effect seen in 30-week study females was a significant increase in the litter-adjusted incidence of cecum hyperplasia (Table G15). There were several other decreases in the incidences of nonneoplastic lesions, which differed in significance between the naive and adjusted evaluations; details appear in Tables G15 through G17. Generally, the adverse dose responses were not very notable.

## Conclusions

The use of common sires and more than one pup per litter to populate dose groups did not confound the sensitivity of these studies. There appeared to be a slightly negative, rather than positive, correlation between littermates and pathologic endpoints. This suggests that in these mice, which are derived from inbred parent strains, the epigenetic effects of intrauterine position override genetic differences between litters.

TABLE G1 Distribution of Male Heterozygous F1 p53^+/−^ Mouse Pups in the In Utero/Postnatal Gavage Studies of AZT

Animal Number | Dam UIN^a^ | Sire UIN^b^ | Litter UIN^b^ | Lesion^c^ | Duration^d^ | Dose^e^
426 | 7F000000316 | 7E000000019 | 7G000001650 | Pc | 1 | 0/0
578 | 7F000000316 | 7E000000019 | 7G000001650 | L | 1 | 0/0
598 | 7F000000315 | 7E000000019 | 7G000001700 | LgA | 1 | 0/0
597 | 7F000000315 | 7E000000019 | 7G000001700 | | 1 | 0/0
625 | 7F000000346 | 7E000000019 | 7G000001782 | | 1 | 0/0
618 | 7F000000346 | 7E000000019 | 7G000001782 | | 1 | 0/0
575 | 7F000000309 | 7E000000033 | 7G000001635 | | 1 | 0/0
574 | 7F000000309 | 7E000000033 | 7G000001635 | | 1 | 0/0
599 | 7F000000310 | 7E000000033 | 7G000001721 | L | 1 | 0/0
600 | 7F000000310 | 7E000000033 | 7G000001721 | | 1 | 0/0
629 | 7F000000351 | 7E000000033 | 7G000001818 | | 1 | 0/0
628 | 7F000000351 | 7E000000033 | 7G000001818 | | 1 | 0/0
587 | 7F000000327 | 7E000000034 | 7G000001666 | | 1 | 0/0
588 | 7F000000327 | 7E000000034 | 7G000001666 | LgA | 1 | 0/0
576 | 7F000000320 | 7E000000037 | 7G000001642 | | 1 | 0/0
577 | 7F000000320 | 7E000000037 | 7G000001642 | | 1 | 0/0
626 | 7F000000326 | 7E000000046 | 7G000001796 | | 1 | 0/0
585 | 7F000000325 | 7E000000049 | 7G000001659 | L | 1 | 0/0
586 | 7F000000325 | 7E000000049 | 7G000001659 | | 1 | 0/0
635 | 7F000000345 | 7E000000052 | 7G000001849 | | 1 | 0/0
647 | 7F000000322 | 7E000000053 | 7G000001856 | | 1 | 0/0
648 | 7F000000322 | 7E000000053 | 7G000001856 | | 1 | 0/0
652 | 7F000000360 | 7E000000055 | 7G000001880 | | 1 | 0/0
653 | 7F000000360 | 7E000000055 | 7G000001880 | HA | 1 | 0/0
611 | 7F000000324 | 7E000000019 | 7G000001738 | | 1 | 240/40
612 | 7F000000324 | 7E000000019 | 7G000001738 | | 1 | 240/40
646 | 7F000000336 | 7E000000019 | 7G000001871 | | 1 | 240/40
645 | 7F000000336 | 7E000000019 | 7G000001871 | L | 1 | 240/40
488 | 7F000000199 | 7E000000022 | 7G000001393 | | 1 | 240/40
565 | 7F000000323 | 7E000000028 | 7G000001673 | L | 1 | 240/40
564 | 7F000000323 | 7E000000028 | 7G000001673 | | 1 | 240/40
593 | 7F000000306 | 7E000000031 | 7G000001707 | L | 1 | 240/40
634 | 7F000000352 | 7E000000033 | 7G000001852 | Lym | 1 | 240/40
643 | 7F000000352 | 7E000000033 | 7G000001852 | Lym | 1 | 240/40
566 | 7F000000319 | 7E000000037 | 7G000001679 | | 1 | 240/40
567 | 7F000000319 | 7E000000037 | 7G000001679 | | 1 | 240/40
581 | 7F000000312 | 7E000000039 | 7G000001695 | | 1 | 240/40
582 | 7F000000312 | 7E000000039 | 7G000001695 | | 1 | 240/40
568 | 7F000000321 | 7E000000041 | 7G000001686 | Lc | 1 | 240/40
580 | 7F000000321 | 7E000000041 | 7G000001686 | Lc | 1 | 240/40
605 | 7F000000317 | 7E000000048 | 7G000001728 | L | 1 | 240/40
549 | 7F000000317 | 7E000000048 | 7G000001728 | S | 1 | 240/40
644 | 7F000000341 | 7E000000052 | 7G000001865 | | 1 | 240/40
656 | 7F000000356 | 7E000000053 | 7G000001893 | L | 1 | 240/40
657 | 7F000000356 | 7E000000053 | 7G000001893 | | 1 | 240/40
651 | 7F000000357 | 7E000000056 | 7G000001886 | | 1 | 240/40
655 | 7F000000357 | 7E000000056 | 7G000001886 | | 1 | 240/40
664 | 7F000000338 | 7E000000056 | 7G000001899 | | 1 | 240/40
665 | 7F000000338 | 7E000000056 | 7G000001899 | | 1 | 240/40
269 | 7F000000194 | 7E000000017 | 7G000001150 | | 2 | 0/0/0
432 | 7F000000194 | 7E000000017 | 7G000001150 | | 3 | 0/0/0
517 | 7F000000177 | 7E000000017 | 7G000001446 | | 3 | 0/0/0
516 | 7F000000177 | 7E000000017 | 7G000001446 | | 3 | 0/0/0
295 | 7F000000116 | 7E000000019 | 7G000000539 | | 3 | 0/0/0
394 | 7F000000347 | 7E000000019 | 7G000001752 | | 2 | 0/0/0
393 | 7F000000347 | 7E000000019 | 7G000001752 | | 2 | 0/0/0
332 | 7F000000161 | 7E000000022 | 7G000000609 | | 3 | 0/0/0
210 | 7F000000123 | 7E000000023 | 7G000000478 | | 2 | 0/0/0
493 | 7F000000123 | 7E000000023 | 7G000000478 | | 3 | 0/0/0
294 | 7F000000125 | 7E000000024 | 7G000000522 | OS | 3 | 0/0/0
212 | 7F000000125 | 7E000000024 | 7G000000522 | | 2 | 0/0/0
279 | 7F000000231 | 7E000000025 | 7G000001563 | | 2 | 0/0/0
515 | 7F000000171 | 7E000000026 | 7G000001461 | HA | 3 | 0/0/0
514 | 7F000000171 | 7E000000026 | 7G000001461 | L | 3 | 0/0/0
469 | 7F000000135 | 7E000000029 | 7G000000542 | Lym | 3 | 0/0/0
213 | 7F000000135 | 7E000000029 | 7G000000542 | | 2 | 0/0/0
348 | 7F000000225 | 7E000000029 | 7G000000636 | | 3 | 0/0/0
230 | 7F000000225 | 7E000000029 | 7G000000636 | | 2 | 0/0/0
293 | 7F000000144 | 7E000000033 | 7G000000484 | | 3 | 0/0/0
211 | 7F000000144 | 7E000000033 | 7G000000484 | | 2 | 0/0/0
395 | 7F000000350 | 7E000000033 | 7G000001765 | | 2 | 0/0/0
396 | 7F000000350 | 7E000000033 | 7G000001765 | | 2 | 0/0/0
350 | 7F000000120 | 7E000000036 | 7G000000672 | | 3 | 0/0/0
386 | 7F000000197 | 7E000000037 | 7G000000791 | | 3 | 0/0/0
256 | 7F000000197 | 7E000000037 | 7G000000791 | | 2 | 0/0/0
349 | 7F000000132 | 7E000000038 | 7G000000642 | | 3 | 0/0/0
231 | 7F000000132 | 7E000000038 | 7G000000642 | | 2 | 0/0/0
415 | 7F000000261 | 7E000000038 | 7G000000796 | OS | 3 | 0/0/0
355 | 7F000000142 | 7E000000041 | 7G000000680 | | 3 | 0/0/0
232 | 7F000000142 | 7E000000041 | 7G000000680 | L | 2 | 0/0/0
278 | 7F000000229 | 7E000000041 | 7G000001546 | | 2 | 0/0/0
539 | 7F000000229 | 7E000000041 | 7G000001546 | | 3 | 0/0/0
277 | 7F000000229 | 7E000000041 | 7G000001546 | | 2 | 0/0/0
254 | 7F000000147 | 7E000000042 | 7G000000768 | | 2 | 0/0/0
375 | 7F000000147 | 7E000000042 | 7G000000768 | S | 3 | 0/0/0
284 | 7F000000223 | 7E000000042 | 7G000001571 | | 2 | 0/0/0
280 | 7F000000223 | 7E000000042 | 7G000001571 | | 2 | 0/0/0
457 | 7F000000152 | 7E000000044 | 7G000000627 | | 3 | 0/0/0
226 | 7F000000152 | 7E000000044 | 7G000000627 | L I | 2 | 0/0/0
374 | 7F000000153 | 7E000000045 | 7G000000731 | | 3 | 0/0/0
255 | 7F000000153 | 7E000000045 | 7G000000731 | | 2 | 0/0/0
417 | 7F000000170 | 7E000000045 | 7G000000853 | | 3 | 0/0/0
263 | 7F000000170 | 7E000000045 | 7G000000853 | | 2 | 0/0/0
356 | 7F000000156 | 7E000000046 | 7G000000694 | Lf | 3 | 0/0/0
233 | 7F000000156 | 7E000000046 | 7G000000694 | | 2 | 0/0/0
416 | 7F000000146 | 7E000000047 | 7G000000804 | | 3 | 0/0/0
257 | 7F000000146 | 7E000000047 | 7G000000804 | | 2 | 0/0/0
357 | 7F000000166 | 7E000000049 | 7G000000701 | | 3 | 0/0/0
234 | 7F000000166 | 7E000000049 | 7G000000701 | | 2 | 0/0/0
630 | 7F000000339 | 7E000000053 | 7G000001745 | L | 3 | 0/0/0
631 | 7F000000339 | 7E000000053 | 7G000001745 | | 3 | 0/0/0
557 | 7F000000364 | 7E000000056 | 7G000001945 | | 2 | 0/0/0
558 | 7F000000364 | 7E000000056 | 7G000001945 | | 2 | 0/0/0
323 | 7F000000158 | 7E000000019 | 7G000000587 | | 3 | 80/40/80
324 | 7F000000158 | 7E000000019 | 7G000000587 | | 3 | 80/40/80
547 | 7F000000208 | 7E000000019 | 7G000001556 | L | 3 | 80/40/80
306 | 7F000000118 | 7E000000020 | 7G000000490 | | 3 | 80/40/80
305 | 7F000000118 | 7E000000020 | 7G000000490 | | 3 | 80/40/80
494 | 7F000000149 | 7E000000022 | 7G000001198 | | 3 | 80/40/80
428 | 7F000000149 | 7E000000022 | 7G000001198 | Lf | 3 | 80/40/80
427 | 7F000000149 | 7E000000022 | 7G000001198 | Lc | 3 | 80/40/80
316 | 7F000000126 | 7E000000024 | 7G000000566 | | 3 | 80/40/80
309 | 7F000000126 | 7E000000024 | 7G000000566 | | 3 | 80/40/80
307 | 7F000000127 | 7E000000025 | 7G000000529 | | 3 | 80/40/80
308 | 7F000000127 | 7E000000025 | 7G000000529 | | 3 | 80/40/80
543 | 7F000000205 | 7E000000034 | 7G000001518 | | 3 | 80/40/80
480 | 7F000000205 | 7E000000034 | 7G000001518 | | 3 | 80/40/80
402 | 7F000000244 | 7E000000035 | 7G000000812 | | 3 | 80/40/80
401 | 7F000000244 | 7E000000035 | 7G000000812 | | 3 | 80/40/80
450 | 7F000000201 | 7E000000038 | 7G000001579 | Lym | 3 | 80/40/80
362 | 7F000000137 | 7E000000039 | 7G000000777 | LgA | 3 | 80/40/80
361 | 7F000000137 | 7E000000039 | 7G000000777 | | 3 | 80/40/80
171 | 7F000000243 | 7E000000041 | 7G000001512 | | 3 | 80/40/80
541 | 7F000000196 | 7E000000042 | 7G000001498 | | 3 | 80/40/80
542 | 7F000000196 | 7E000000042 | 7G000001498 | | 3 | 80/40/80
511 | 7F000000220 | 7E000000043 | 7G000001476 | | 3 | 80/40/80
512 | 7F000000220 | 7E000000043 | 7G000001476 | | 3 | 80/40/80
510 | 7F000000220 | 7E000000043 | 7G000001476 | StA | 3 | 80/40/80
444 | 7F000000246 | 7E000000048 | 7G000001437 | Nb | 3 | 80/40/80
509 | 7F000000246 | 7E000000048 | 7G000001437 | L Lym | 3 | 80/40/80
328 | 7F000000157 | 7E000000019 | 7G000000595 | L | 3 | 160/80/160
330 | 7F000000157 | 7E000000019 | 7G000000595 | | 3 | 160/80/160
320 | 7F000000145 | 7E000000020 | 7G000000572 | | 3 | 160/80/160
321 | 7F000000145 | 7E000000020 | 7G000000572 | | 3 | 160/80/160
298 | 7F000000121 | 7E000000022 | 7G000000498 | L | 3 | 160/80/160
299 | 7F000000121 | 7E000000022 | 7G000000498 | | 3 | 160/80/160
410 | 7F000000232 | 7E000000022 | 7G000000836 | L | 3 | 160/80/160
409 | 7F000000232 | 7E000000022 | 7G000000836 | | 3 | 160/80/160
412 | 7F000000210 | 7E000000025 | 7G000000848 | | 3 | 160/80/160
411 | 7F000000210 | 7E000000025 | 7G000000848 | | 3 | 160/80/160
379 | 7F000000224 | 7E000000028 | 7G000000752 | | 3 | 160/80/160
380 | 7F000000224 | 7E000000028 | 7G000000752 | | 3 | 160/80/160
551 | 7F000000200 | 7E000000028 | 7G000001595 | | 3 | 160/80/160
358 | 7F000000190 | 7E000000029 | 7G000000666 | Lym | 3 | 160/80/160
337 | 7F000000190 | 7E000000029 | 7G000000666 | L | 3 | 160/80/160
531 | 7F000000215 | 7E000000036 | 7G000001454 | | 3 | 160/80/160
530 | 7F000000215 | 7E000000036 | 7G000001454 | | 3 | 160/80/160
433 | 7F000000233 | 7E000000039 | 7G000001158 | L | 3 | 160/80/160
434 | 7F000000233 | 7E000000039 | 7G000001158 | | 3 | 160/80/160
335 | 7F000000162 | 7E000000047 | 7G000000653 | | 3 | 160/80/160
334 | 7F000000162 | 7E000000047 | 7G000000653 | | 3 | 160/80/160
381 | 7F000000164 | 7E000000048 | 7G000000740 | | 3 | 160/80/160
382 | 7F000000164 | 7E000000048 | 7G000000740 | | 3 | 160/80/160
424 | 7F000000173 | 7E000000048 | 7G000000862 | | 3 | 160/80/160
413 | 7F000000173 | 7E000000048 | 7G000000862 | L | 3 | 160/80/160
336 | 7F000000165 | 7E000000049 | 7G000000664 | | 3 | 160/80/160
633 | 7F000000343 | 7E000000055 | 7G000001810 | | 3 | 160/80/160
344 | 7F000000216 | 7E000000019 | 7G000000689 | L | 3 | 240/120/120
314 | 7F000000117 | 7E000000020 | 7G000000554 | L | 3 | 240/120/120
219 | 7F000000117 | 7E000000020 | 7G000000554 | OS \| | 2 | \| 240/120/120
482 | 7F000000160 | 7E000000020 | 7G000000602 | | 3 | 240/120/120
223 | 7F000000160 | 7E000000020 | 7G000000602 | | 2 | \| 240/120/120
675 | 7F000000218 | 7E000000022 | 7G000000658 | | 3 | 240/120/120
342 | 7F000000184 | 7E000000023 | 7G000000616 | | 3 | 240/120/120
227 | 7F000000184 | 7E000000023 | 7G000000616 | | 2 | 240/120/120
241 | 7F000000185 | 7E000000024 | 7G000000784 | | 2 | 240/120/120
389 | 7F000000185 | 7E000000024 | 7G000000784 | | 3 | 240/120/120
322 | 7F000000167 | 7E000000025 | 7G000000581 | | 3 | 240/120/120
368 | 7F000000186 | 7E000000025 | 7G000000746 | | 3 | 240/120/120
315 | 7F000000130 | 7E000000026 | 7G000000557 | | 3 | 240/120/120
220 | 7F000000130 | 7E000000026 | 7G000000557 | | 2 | 240/120/120
343 | 7F000000222 | 7E000000026 | 7G000000619 | L | 3 | 240/120/120
240 | 7F000000222 | 7E000000026 | 7G000000619 | | 2 | 240/120/120
262 | 7F000000203 | 7E000000026 | 7G000000820 | | 2 | 240/120/120
421 | 7F000000203 | 7E000000026 | 7G000000820 | Lf | 3 | 240/120/120
313 | 7F000000134 | 7E000000028 | 7G000000514 | SfS | 3 | 240/120/120
218 | 7F000000134 | 7E000000028 | 7G000000514 | | 2 | 240/120/120
312 | 7F000000136 | 7E000000029 | 7G000000505 | | 3 | 240/120/120
285 | 7F000000193 | 7E000000033 | 7G000001613 | Nb | 2 | 240/120/120
243 | 7F000000112 | 7E000000034 | 7G000000717 | Ac | 2 | 240/120/120
365 | 7F000000112 | 7E000000034 | 7G000000717 | | 3 | 240/120/120
367 | 7F000000113 | 7E000000035 | 7G000000773 | | 3 | 240/120/120
463 | 7F000000211 | 7E000000035 | 7G000000843 | Lym | 2 | 240/120/120
422 | 7F000000211 | 7E000000035 | 7G000000843 | L | 3 | 240/120/120
366 | 7F000000119 | 7E000000036 | 7G000000706 | Nb | 3 | 240/120/120
481 | 7F000000119 | 7E000000036 | 7G000000706 | Lym | 2 | 240/120/120
456 | 7F000000122 | 7E000000037 | 7G000000723 | L | 3 | 240/120/120
242 | 7F000000122 | 7E000000037 | 7G000000723 | | 2 | 240/120/120
271 | 7F000000175 | 7E000000037 | 7G000001470 | | 2 | 240/120/120
272 | 7F000000175 | 7E000000037 | 7G000001470 | | 2 | 240/120/120
465 | 7F000000175 | 7E000000037 | 7G000001470 | Lym | 2 | 240/120/120
273 | 7F000000175 | 7E000000037 | 7G000001470 | | 2 | 240/120/120
524 | 7F000000139 | 7E000000038 | 7G000001421 | | 3 | 240/120/120
523 | 7F000000139 | 7E000000038 | 7G000001421 | | 3 | 240/120/120
270 | 7F000000236 | 7E000000039 | 7G000001428 | | 2 | 240/120/120
522 | 7F000000236 | 7E000000039 | 7G000001428 | L | 3 | 240/120/120
521 | 7F000000236 | 7E000000039 | 7G000001428 | | 3 | 240/120/120
288 | 7F000000245 | 7E000000039 | 7G000001618 | L | 2 | 240/120/120
553 | 7F000000245 | 7E000000039 | 7G000001618 | L | 3 | 240/120/120
476 | 7F000000150 | 7E000000043 | 7G000000765 | Lym | 3 | 240/120/120
265 | 7F000000179 | 7E000000043 | 7G000000829 | | 2 | 240/120/120
423 | 7F000000179 | 7E000000043 | 7G000000829 | L | 3 | 240/120/120
504 | 7F000000230 | 7E000000043 | 7G000001625 | L | 3 | 240/120/120
261 | 7F000000151 | 7E000000044 | 7G000000758 | | 2 | 240/120/120
388 | 7F000000151 | 7E000000044 | 7G000000758 | | 3 | 240/120/120
441 | 7F000000340 | 7E000000053 | 7G000001834 | | 2 | 240/120/120
442 | 7F000000340 | 7E000000053 | 7G000001834 | | 2 | 240/120/120
439 | 7F000000342 | 7E000000055 | 7G000001825 | | 2 | 240/120/120
452 | 7F000000342 | 7E000000055 | 7G000001825 | | 2 | 240/120/120
501 | 7F000000354 | 7E000000056 | 7G000001841 | | 2 | 240/120/120

a UIN = unique identification number

b Adjacent cells within a column with the same shading share the same UIN number.

c Ac = Astrocytoma; HA = Harderian gland adenoma; L = Liver, hepatocellular adenoma; Lc = Liver, hepatocellular carcinoma; LgA = Lung, adenoma; Lf = Liver, basophilic focus; Lym = Malignant lymphoma; L Lym= Liver, hepatocellular adenoma + Malignant lymphoma; Nb = Neuroblastoma; OS = Osteosarcoma; Pc = Pancreas, carcinoma; S = Sarcoma; SfS = Skin, fibrosarcoma; StA = Stomach, adenocarcinoma

d Duration 1, 2, and 3, designate the 45-week stop-study, 30-week study, and 45-week study, respectively; shading highlights nonconsecutive durations

e AZT dose is presented as mg/kg body weight per day

TABLE G2 Distribution of Female Heterozygous F1 p53^+/−^ Mouse Pups in the In Utero/Postnatal Gavage Studies of AZT

Animal Number | Dam UIN | Sire UIN | Litter UIN^b^ | Lesion^c^ | Duration^d^ | Dose^e^
569 | 7F000000316 | 7E000000019 | 7G000001650 | | 1 | 0/0
570 | 7F000000316 | 7E000000019 | 7G000001650 | | 1 | 0/0
571 | 7F000000315 | 7E000000019 | 7G000001700 | Up | 1 | 0/0
572 | 7F000000315 | 7E000000019 | 7G000001700 | OTm | 1 | 0/0
573 | 7F000000346 | 7E000000019 | 7G000001782 | | 1 | 0/0
579 | 7F000000346 | 7E000000019 | 7G000001782 | | 1 | 0/0
589 | 7F000000309 | 7E000000033 | 7G000001635 | | 1 | 0/0
590 | 7F000000309 | 7E000000033 | 7G000001635 | | 1 | 0/0
591 | 7F000000310 | 7E000000033 | 7G000001721 | | 1 | 0/0
592 | 7F000000310 | 7E000000033 | 7G000001721 | | 1 | 0/0
601 | 7F000000351 | 7E000000033 | 7G000001818 | | 1 | 0/0
602 | 7F000000351 | 7E000000033 | 7G000001818 | | 1 | 0/0
603 | 7F000000327 | 7E000000034 | 7G000001666 | | 1 | 0/0
604 | 7F000000327 | 7E000000034 | 7G000001666 | | 1 | 0/0
608 | 7F000000320 | 7E000000037 | 7G000001642 | Oc | 1 | 0/0
619 | 7F000000320 | 7E000000037 | 7G000001642 | | 1 | 0/0
620 | 7F000000326 | 7E000000046 | 7G000001796 | MA | 1 | 0/0
621 | 7F000000326 | 7E000000046 | 7G000001796 | | 1 | 0/0
622 | 7F000000326 | 7E000000046 | 7G000001796 | | 1 | 0/0
623 | 7F000000325 | 7E000000049 | 7G000001659 | | 1 | 0/0
624 | 7F000000325 | 7E000000049 | 7G000001659 | | 1 | 0/0
627 | 7F000000345 | 7E000000052 | 7G000001849 | | 1 | 0/0
636 | 7F000000345 | 7E000000052 | 7G000001849 | | 1 | 0/0
637 | 7F000000322 | 7E000000053 | 7G000001856 | | 1 | 0/0
649 | 7F000000360 | 7E000000055 | 7G000001880 | | 1 | 0/0
654 | 7F000000360 | 7E000000055 | 7G000001880 | | 1 | 0/0
390 | 7F000000324 | 7E000000019 | 7G000001738 | | 1 | 240/40
556 | 7F000000324 | 7E000000019 | 7G000001738 | | 1 | 240/40
559 | 7F000000336 | 7E000000019 | 7G000001871 | | 1 | 240/40
560 | 7F000000336 | 7E000000019 | 7G000001871 | | 1 | 240/40
561 | 7F000000323 | 7E000000028 | 7G000001673 | | 1 | 240/40
562 | 7F000000323 | 7E000000028 | 7G000001673 | | 1 | 240/40
563 | 7F000000306 | 7E000000031 | 7G000001707 | | 1 | 240/40
583 | 7F000000306 | 7E000000031 | 7G000001707 | | 1 | 240/40
584 | 7F000000306 | 7E000000031 | 7G000001707 | Lk | 1 | 240/40
594 | 7F000000352 | 7E000000033 | 7G000001852 | | 1 | 240/40
595 | 7F000000319 | 7E000000037 | 7G000001679 | | 1 | 240/40
596 | 7F000000319 | 7E000000037 | 7G000001679 | | 1 | 240/40
606 | 7F000000308 | 7E000000038 | 7G000001714 | Up | 1 | 240/40
607 | 7F000000308 | 7E000000038 | 7G000001714 | US | 1 | 240/40
610 | 7F000000312 | 7E000000039 | 7G000001695 | Ac | 1 | 240/40
613 | 7F000000321 | 7E000000041 | 7G000001686 | | 1 | 240/40
638 | 7F000000321 | 7E000000041 | 7G000001686 | | 1 | 240/40
639 | 7F000000317 | 7E000000048 | 7G000001728 | | 1 | 240/40
640 | 7F000000341 | 7E000000052 | 7G000001865 | | 1 | 240/40
641 | 7F000000341 | 7E000000052 | 7G000001865 | | 1 | 240/40
642 | 7F000000356 | 7E000000053 | 7G000001893 | | 1 | 240/40
650 | 7F000000356 | 7E000000053 | 7G000001893 | | 1 | 240/40
658 | 7F000000357 | 7E000000056 | 7G000001886 | | 1 | 240/40
659 | 7F000000357 | 7E000000056 | 7G000001886 | | 1 | 240/40
666 | 7F000000338 | 7E000000056 | 7G000001899 | | 1 | 240/40
667 | 7F000000338 | 7E000000056 | 7G000001899 | | 1 | 240/40
173 | 7F000000194 | 7E000000017 | 7G000001150 | | 2 | 0/0/0
209 | 7F000000194 | 7E000000017 | 7G000001150 | S | 3 | 0/0/0
289 | 7F000000177 | 7E000000017 | 7G000001446 | | 3 | 0/0/0
290 | 7F000000177 | 7E000000017 | 7G000001446 | | 3 | 0/0/0
291 | 7F000000116 | 7E000000019 | 7G000000539 | | 3 | 0/0/0
215 | 7F000000347 | 7E000000019 | 7G000001752 | | 2 | 0/0/0
214 | 7F000000347 | 7E000000019 | 7G000001752 | | 2 | 0/0/0
216 | 7F000000161 | 7E000000022 | 7G000000609 | | 2 | 0/0/0
292 | 7F000000161 | 7E000000022 | 7G000000609 | | 3 | 0/0/0
333 | 7F000000123 | 7E000000023 | 7G000000478 | | 3 | 0/0/0
217 | 7F000000123 | 7E000000023 | 7G000000478 | | 2 | 0/0/0
351 | 7F000000125 | 7E000000024 | 7G000000522 | | 3 | 0/0/0
222 | 7F000000125 | 7E000000024 | 7G000000522 | | 2 | 0/0/0
235 | 7F000000128 | 7E000000025 | 7G000000548 | | 2 | 0/0/0
236 | 7F000000231 | 7E000000025 | 7G000001563 | | 2 | 0/0/0
238 | 7F000000231 | 7E000000025 | 7G000001563 | | 2 | 0/0/0
237 | 7F000000231 | 7E000000025 | 7G000001563 | | 2 | 0/0/0
353 | 7F000000171 | 7E000000026 | 7G000001461 | | 3 | 0/0/0
352 | 7F000000171 | 7E000000026 | 7G000001461 | | 3 | 0/0/0
354 | 7F000000225 | 7E000000029 | 7G000000636 | | 3 | 0/0/0
239 | 7F000000144 | 7E000000033 | 7G000000484 | | 2 | 0/0/0
360 | 7F000000144 | 7E000000033 | 7G000000484 | | 3 | 0/0/0
249 | 7F000000350 | 7E000000033 | 7G000001765 | | 2 | 0/0/0
376 | 7F000000120 | 7E000000036 | 7G000000672 | OL | 3 | 0/0/0
250 | 7F000000120 | 7E000000036 | 7G000000672 | | 2 | 0/0/0
377 | 7F000000197 | 7E000000037 | 7G000000791 | | 3 | 0/0/0
251 | 7F000000197 | 7E000000037 | 7G000000791 | Usp | 2 | 0/0/0
252 | 7F000000261 | 7E000000038 | 7G000000796 | | 2 | 0/0/0
378 | 7F000000261 | 7E000000038 | 7G000000796 | | 3 | 0/0/0
253 | 7F000000142 | 7E000000041 | 7G000000680 | | 2 | 0/0/0
400 | 7F000000142 | 7E000000041 | 7G000000680 | | 3 | 0/0/0
414 | 7F000000229 | 7E000000041 | 7G000001546 | | 3 | 0/0/0
268 | 7F000000229 | 7E000000041 | 7G000001546 | | 2 | 0/0/0
266 | 7F000000229 | 7E000000041 | 7G000001546 | | 2 | 0/0/0
431 | 7F000000147 | 7E000000042 | 7G000000768 | | 3 | 0/0/0
274 | 7F000000147 | 7E000000042 | 7G000000768 | | 2 | 0/0/0
446 | 7F000000192 | 7E000000042 | 7G000001497 | Mth | 3 | 0/0/0
276 | 7F000000223 | 7E000000042 | 7G000001571 | | 2 | 0/0/0
275 | 7F000000223 | 7E000000042 | 7G000001571 | MA | 2 | 0/0/0
281 | 7F000000152 | 7E000000044 | 7G000000627 | | 2 | 0/0/0
513 | 7F000000152 | 7E000000044 | 7G000000627 | | 3 | 0/0/0
282 | 7F000000153 | 7E000000045 | 7G000000731 | | 2 | 0/0/0
518 | 7F000000153 | 7E000000045 | 7G000000731 | | 3 | 0/0/0
519 | 7F000000170 | 7E000000045 | 7G000000853 | | 3 | 0/0/0
283 | 7F000000170 | 7E000000045 | 7G000000853 | IP | 2 | 0/0/0
399 | 7F000000156 | 7E000000046 | 7G000000694 | | 2 | 0/0/0
520 | 7F000000156 | 7E000000046 | 7G000000694 | | 3 | 0/0/0
443 | 7F000000146 | 7E000000047 | 7G000000804 | Lym | 2 | 0/0/0
538 | 7F000000146 | 7E000000047 | 7G000000804 | | 3 | 0/0/0
464 | 7F000000166 | 7E000000049 | 7G000000701 | | 2 | 0/0/0
540 | 7F000000166 | 7E000000049 | 7G000000701 | | 3 | 0/0/0
552 | 7F000000339 | 7E000000053 | 7G000001745 | OS | 3 | 0/0/0
632 | 7F000000339 | 7E000000053 | 7G000001745 | | 3 | 0/0/0
300 | 7F000000158 | 7E000000019 | 7G000000587 | | 3 | 80/40/80
301 | 7F000000158 | 7E000000019 | 7G000000587 | | 3 | 80/40/80
302 | 7F000000208 | 7E000000019 | 7G000001556 | LgA | 3 | 80/40/80
303 | 7F000000118 | 7E000000020 | 7G000000490 | | 3 | 80/40/80
304 | 7F000000118 | 7E000000020 | 7G000000490 | | 3 | 80/40/80
326 | 7F000000149 | 7E000000022 | 7G000001198 | | 3 | 80/40/80
317 | 7F000000149 | 7E000000022 | 7G000001198 | | 3 | 80/40/80
325 | 7F000000149 | 7E000000022 | 7G000001198 | | 3 | 80/40/80
363 | 7F000000126 | 7E000000024 | 7G000000566 | | 3 | 80/40/80
364 | 7F000000126 | 7E000000024 | 7G000000566 | Usp | 3 | 80/40/80
403 | 7F000000127 | 7E000000025 | 7G000000529 | | 3 | 80/40/80
429 | 7F000000127 | 7E000000025 | 7G000000529 | | 3 | 80/40/80
445 | 7F000000244 | 7E000000035 | 7G000000812 | OS | 3 | 80/40/80
430 | 7F000000244 | 7E000000035 | 7G000000812 | OS | 3 | 80/40/80
451 | 7F000000201 | 7E000000038 | 7G000001579 | Sh | 3 | 80/40/80
483 | 7F000000137 | 7E000000039 | 7G000000777 | | 3 | 80/40/80
505 | 7F000000137 | 7E000000039 | 7G000000777 | | 3 | 80/40/80
506 | 7F000000243 | 7E000000041 | 7G000001512 | | 3 | 80/40/80
507 | 7F000000243 | 7E000000041 | 7G000001512 | | 3 | 80/40/80
508 | 7F000000196 | 7E000000042 | 7G000001498 | | 3 | 80/40/80
529 | 7F000000196 | 7E000000042 | 7G000001498 | | 3 | 80/40/80
544 | 7F000000220 | 7E000000043 | 7G000001476 | | 3 | 80/40/80
545 | 7F000000220 | 7E000000043 | 7G000001476 | Sp | 3 | 80/40/80
546 | 7F000000246 | 7E000000048 | 7G000001437 | | 3 | 80/40/80
548 | 7F000000246 | 7E000000048 | 7G000001437 | KA | 3 | 80/40/80
550 | 7F000000246 | 7E000000048 | 7G000001437 | | 3 | 80/40/80
673 | 7F000000246 | 7E000000048 | 7G000001437 | | 3 | 80/40/80
296 | 7F000000157 | 7E000000019 | 7G000000595 | | 3 | 160/80/160
297 | 7F000000157 | 7E000000019 | 7G000000595 | | 3 | 160/80/160
318 | 7F000000145 | 7E000000020 | 7G000000572 | OS | 3 | 160/80/160
319 | 7F000000145 | 7E000000020 | 7G000000572 | HA | 3 | 160/80/160
327 | 7F000000121 | 7E000000022 | 7G000000498 | | 3 | 160/80/160
331 | 7F000000121 | 7E000000022 | 7G000000498 | | 3 | 160/80/160
338 | 7F000000232 | 7E000000022 | 7G000000836 | | 3 | 160/80/160
339 | 7F000000232 | 7E000000022 | 7G000000836 | | 3 | 160/80/160
340 | 7F000000210 | 7E000000025 | 7G000000848 | AA | 3 | 160/80/160
341 | 7F000000210 | 7E000000025 | 7G000000848 | | 3 | 160/80/160
359 | 7F000000224 | 7E000000028 | 7G000000752 | | 3 | 160/80/160
383 | 7F000000224 | 7E000000028 | 7G000000752 | | 3 | 160/80/160
384 | 7F000000200 | 7E000000028 | 7G000001595 | | 3 | 160/80/160
385 | 7F000000190 | 7E000000029 | 7G000000666 | ScC | 3 | 160/80/160
404 | 7F000000190 | 7E000000029 | 7G000000666 | | 3 | 160/80/160
405 | 7F000000215 | 7E000000036 | 7G000001454 | | 3 | 160/80/160
406 | 7F000000215 | 7E000000036 | 7G000001454 | | 3 | 160/80/160
407 | 7F000000233 | 7E000000039 | 7G000001158 | OS Lym | 3 | 160/80/160
408 | 7F000000233 | 7E000000039 | 7G000001158 | | 3 | 160/80/160
435 | 7F000000162 | 7E000000047 | 7G000000653 | | 3 | 160/80/160
425 | 7F000000162 | 7E000000047 | 7G000000653 | | 3 | 160/80/160
436 | 7F000000164 | 7E000000048 | 7G000000740 | MA | 3 | 160/80/160
458 | 7F000000164 | 7E000000048 | 7G000000740 | | 3 | 160/80/160
462 | 7F000000173 | 7E000000048 | 7G000000862 | | 3 | 160/80/160
532 | 7F000000173 | 7E000000048 | 7G000000862 | | 3 | 160/80/160
533 | 7F000000165 | 7E000000049 | 7G000000664 | | 3 | 160/80/160
609 | 7F000000343 | 7E000000055 | 7G000001810 | MA | 3 | 160/80/160
221 | 7F000000216 | 7E000000019 | 7G000000689 | | 2 | 240/120/120
310 | 7F000000216 | 7E000000019 | 7G000000689 | | 3 | 240/120/120
311 | 7F000000117 | 7E000000020 | 7G000000554 | MA | 3 | 240/120/120
224 | 7F000000160 | 7E000000020 | 7G000000602 | 1 | 2 | 240/120/120
329 | 7F000000160 | 7E000000020 | 7G000000602 | Lym | 3 | 240/120/120
345 | 7F000000218 | 7E000000022 | 7G000000658 | | 3 | 240/120/120
225 | 7F000000218 | 7E000000022 | 7G000000658 | | 2 | 240/120/120
346 | 7F000000184 | 7E000000023 | 7G000000616 | | 3 | 240/120/120
347 | 7F000000185 | 7E000000024 | 7G000000784 | | 3 | 240/120/120
228 | 7F000000185 | 7E000000024 | 7G000000784 | | 2 | 240/120/120
369 | 7F000000167 | 7E000000025 | 7G000000581 | Lym | 3 | 240/120/120
229 | 7F000000167 | 7E000000025 | 7G000000581 | | 2 | 240/120/120
244 | 7F000000186 | 7E000000025 | 7G000000746 | | 2 | 240/120/120
370 | 7F000000186 | 7E000000025 | 7G000000746 | | 3 | 240/120/120
371 | 7F000000130 | 7E000000026 | 7G000000557 | | 3 | 240/120/120
245 | 7F000000130 | 7E000000026 | 7G000000557 | | 2 | 240/120/120
372 | 7F000000222 | 7E000000026 | 7G000000619 | | 3 | 240/120/120
246 | 7F000000222 | 7E000000026 | 7G000000619 | | 2 | 240/120/120
373 | 7F000000203 | 7E000000026 | 7G000000820 | | 3 | 240/120/120
247 | 7F000000203 | 7E000000026 | 7G000000820 | | 2 | 240/120/120
387 | 7F000000134 | 7E000000028 | 7G000000514 | | 3 | 240/120/120
418 | 7F000000136 | 7E000000029 | 7G000000505 | | 3 | 240/120/120
248 | 7F000000349 | 7E000000031 | 7G000001757 | | 2 | 240/120/120
419 | 7F000000112 | 7E000000034 | 7G000000717 | | 3 | 240/120/120
258 | 7F000000112 | 7E000000034 | 7G000000717 | | 2 | 240/120/120
259 | 7F000000113 | 7E000000035 | 7G000000773 | | 2 | 240/120/120
420 | 7F000000113 | 7E000000035 | 7G000000773 | | 3 | 240/120/120
447 | 7F000000211 | 7E000000035 | 7G000000843 | | 3 | 240/120/120
260 | 7F000000211 | 7E000000035 | 7G000000843 | | 2 | 240/120/120
448 | 7F000000119 | 7E000000036 | 7G000000706 | OS | 3 | 240/120/120
264 | 7F000000119 | 7E000000036 | 7G000000706 | SbC | 2 | 240/120/120
449 | 7F000000122 | 7E000000037 | 7G000000723 | SfS | 3 | 240/120/120
267 | 7F000000122 | 7E000000037 | 7G000000723 | | 2 | 240/120/120
453 | 7F000000175 | 7E000000037 | 7G000001470 | Lym | 3 | 240/120/120
525 | 7F000000139 | 7E000000038 | 7G000001421 | | 3 | 240/120/120
497 | 7F000000139 | 7E000000038 | 7G000001421 | | 3 | 240/120/120
527 | 7F000000236 | 7E000000039 | 7G000001428 | Ost | 3 | 240/120/120
526 | 7F000000236 | 7E000000039 | 7G000001428 | | 3 | 240/120/120
528 | 7F000000245 | 7E000000039 | 7G000001618 | | 3 | 240/120/120
286 | 7F000000245 | 7E000000039 | 7G000001618 | | 2 | 240/120/120
287 | 7F000000318 | 7E000000041 | 7G000001802 | Lym | 2 | 240/120/120
391 | 7F000000318 | 7E000000041 | 7G000001802 | | 2 | 240/120/120
554 | 7F000000150 | 7E000000043 | 7G000000765 | | 3 | 240/120/120
555 | 7F000000179 | 7E000000043 | 7G000000829 | | 3 | 240/120/120
392 | 7F000000179 | 7E000000043 | 7G000000829 | | 2 | 240/120/120
674 | 7F000000230 | 7E000000043 | 7G000001625 | Sh | 3 | 240/120/120
397 | 7F000000230 | 7E000000043 | 7G000001625 | | 2 | 240/120/120
398 | 7F000000311 | 7E000000049 | 7G000001769 | | 2 | 240/120/120
437 | 7F000000340 | 7E000000053 | 7G000001834 | | 2 | 240/120/120
438 | 7F000000342 | 7E000000055 | 7G000001825 | | 2 | 240/120/120
440 | 7F000000342 | 7E000000055 | 7G000001825 | | 2 | 240/120/120
503 | 7F000000354 | 7E000000056 | 7G000001841 | | 2 | 240/120/120
502 | 7F000000354 | 7E000000056 | 7G000001841 | S | 2 | 240/120/120

a UIN = unique identification number

b Adjacent cells within a column with the same shading share the same UIN number.

c AA = Adrenal cortex adenoma; Ac = Astrocytoma; HA = Harderian gland adenoma; Ip = Intestine, polyp; KA = Renal tubule adenoma; LgA = Lung, adenoma; Lk = Leukemia, granulocytic; Lym = Malignant lymphoma; MA = Mammary gland adenocarcinoma; Mth = Malignant mesothelioma; Oc = Ovary, carcinoma; OL = Ovary, luteoma; OS = Osteosarcoma; Ost = Osteoma; OS Lym = Osteosarcoma + Malignant lymphoma; OTm = Ovary, malignant teratoma; S = Sarcoma; SbC = Skin, basal cell carcinoma; ScC = Skin, squamous cell carcinoma; SfS = Skin, fibrosarcoma; Sh = Sarcoma, histiocytic; Sp = Stomach, papilloma; Up = Uterus, polyp; Usp = Uterus, stomal polyp; US = Uterus, sarcoma

d Duration 1, 2, and 3, designate the 45-week stop-study, 30-week study, and 45-week study, respectively; shading highlights nonconsecutive durations

e AZT dose is presented as mg/kg body weight per day

TABLE G3 Effect of AZT Dose on Survival of Heterozygous F1 p53^+/−^ Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT^a^

| 0/0/0 mg/kg vs. 240/120/240 mg/kg
Male
Hazard Ratio^b^ | 6174.4%
Independence | 4.1 ± 3.2
| P=0.097
Empirical Variance - Naive | 4.1 ± 1.1
| P≤0.001^***^
Correlation within Dam/Litter | 4.1 ± 1.0
| P≤0.001^***^
Correlation within Sire | 4.1 ± 1.1
| P≤0.001^***^
Female
Hazard Ratio | 3.3%
Independence | −3.4 ± 3.2
| P=0.143N
Empirical Variance - Naive | −3.4 ± 1.2
| P=0.002N^**^
Correlation within Dam/Litter | −3.4 ± 1.2
| P=0.002N^**^
Correlation within Sire | −3.4 ± 1.2
| P=0.002N^**^

** Significantly different (P≤0.01) by the Cox (1972) proportional hazard model

*** P≤0.001

a The results are presented for the naive model assuming pup independence, an empirical variance model, an empirical variance model aggregated over litters, and an empirical variance model aggregated over sires. A lower P value in a dosed group is indicated by N.

b The Hazard Ratio represents the treatment group hazard relative to 0/0/0 mg/kg group. The ratio for the 0/0/0 mg/kg group is always 100%.

TABLE G4 Effect of AZT Dose on Survival of Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT^a^

| 0/0/0 mg/kg | 80/40/80 mg/kg | 160/80/160 mg/kg | 240/120/240 mg/kg
Male
Hazard Ratio^b^ | – | 217.1% | 3.1% | 169.4%
Independence | −3.2 ± 3.5 | 0.8 ± 0.7 | −3.5 ± 3.2 | 0.5 ± 0.7
| P=0.180N^c^ | P=0.136 | P=0.139N | P=0.234
Empirical Variance - Naive | −3.2 ± 1.8 | 0.8 ± 0.7 | −3.5 ± 1.2 | 0.5 ± 0.7
| P=0.039N^*^ | P=0.137 | P=0.001N^**^ | P=0.233
Correlation within Dam/Litter | −3.2 ± 1.4 | 0.8 ± 0.7 | −3.5 ± 0.9 | 0.5 ± 0.7
| P=0.013N^*^ | P=0.128 | P≤0.001N^***^ | P=0.235
Correlation within Sire | −3.2 ± 1.4 | 0.8 ± 0.7 | −3.5 ± 0.9 | 0.5 ± 0.8
| P=0.013N^*^ | P=0.135 | P≤0.001N^***^ | P=0.252
Female
Hazard Ratio | – | 130.3% | 96.5% | 202.0%
Independence | 1.1 ± 1.6 | 0.3 ± 0.8 | 0.0 ± 0.8 | 0.7 ± 0.7
| P=0.246 | P=0.364 | P=0.483N | P=0.160
Empirical Variance - Naive | 1.1 ± 1.6 | 0.3 ± 0.8 | 0.0 ± 0.8 | 0.7 ± 0.7
| P=0.244 | P=0.364 | P=0.482N | P=0.158
Correlation within Dam/Litter | 1.1 ± 1.5 | 0.3 ± 0.7 | 0.0 ± 0.8 | 0.7 ± 0.7
| P=0.235 | P=0.349 | P=0.482N | P=0.151
Correlation within Sire | 1.1 ± 1.3 | 0.3 ± 0.7 | 0.0 ± 0.7 | 0.7 ± 0.6
| P=0.196 | P=0.350 | P=0.480N | P=0.135

* Significantly different (P≤0.05) by the Cox (1972) proportional hazard model

** P≤0.01

*** P≤0.001

a The results are presented for the naive model assuming pup independence, an empirical variance model, an empirical variance model aggregated over litters, and an empirical variance model aggregated over sires.

b The Hazard Ratio represents the treatment group hazard relative to the 0/0/0 mg/kg. The ratio for the 0/0/0 mg/kg group is always 100%.

c P values for the 0/0/0 mg/kg group represent linear dose trends and not the Cox estimate which is implicitly zero for this group. A negative trend or a lower P value in a dosed group is indicated by N.

TABLE G5 Effect of AZT Dose on Survival of Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Stop-Study of AZT^a^

| 0/0 mg/kg vs. 240/40 mg/kg
Male
Hazard Ratio^b^ | 293.8%
Independence | 1.1 ± 1.2
| P=0.175
Empirical Variance - Naive | 1.1 ± 1.1
| P=0.173
Correlation within Dam/Litter | 1.1 ± 1.1
| P=0.167
Correlation within Sire | 1.1 ± 1.2
| P=0.178
Female
Hazard Ratio | 306.1%
Independence | 1.1 ± 1.2
| P=0.166
Empirical Variance - Naive | 1.1 ± 1.1
| P=0.164
Correlation within Dam/Litter | 1.1 ± 1.1
| P=0.157
Correlation within Sire | 1.1 ± 1.1
| P=0.159

a The results are presented for the naive model assuming pup independence, an empirical variance model, an empirical variance model aggregated over litters, and an empirical variance model aggregated over sires.

b The Hazard Ratio represents the treatment group hazard relative to the 0/0 mg/kg group. The ratio for the 0/0 mg/kg group is always 100%.

TABLE G6 Litter-adjusted Statistical Analysis of Primary Neoplasms in Male Heterozygous F1 p53^+/−^ Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT

| 0/0/0 mg/kg | 240/120/240 mg/kg
Liver: Hepatocellular Adenoma
Overall rate^a^ | 1/27 (3.7%) | 1/26 (3.8%)
Adjusted rate^b^ | 1/27.0 (3.7%) | 1/22.8 (4.4%)
Terminal rate^c^ | 1/27 (3.7%) | 1/21 (4.8%)
First incidence (days) | 217 (T) | 213 (T)
Poly-3 test^d^ | | 0.722
Litter-adjusted correlation | 0.04
Litter-adjusted Poly-3 rate | 3.8% | 4.5%
Litter-adjusted Poly-3 test | | 0.451
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 3.6% | 4.4%
Sire-adjusted Poly-3 test | | 0.446
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 1/27 (3.7%) | 1/26 (3.8%)
Adjusted rate | 1/27.0 (3.7%) | 1/22.8 (4.4%)
Terminal rate | 1/27 (3.7%) | 1/21 (4.8%)
First incidence (days) | 217 (T) | 213 (T)
Poly-3 test | | 0.722
Litter-adjusted correlation | 0.04
Litter-adjusted Poly-3 rate | 3.8% | 4.5%
Litter-adjusted Poly-3 test | | 0.451
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 3.6% | 4.4%
Sire-adjusted Poly-3 test | | 0.446
All Organs: Malignant Lymphoma
Overall rate | 0/27 (0.0%) | 3/26 (11.5%)
Adjusted rate | 0/27.0 (0.0%) | 3/25.2 (11.9%)
Terminal rate | 0/27 (0.0%) | 0/21 (0.0%)
First incidence (days) | —^e^ | 84
Poly-3 test | | 0.102
Litter-adjusted correlation | −0.21
Litter-adjusted Poly-3 rate | 0.0% | 14.4%
Litter-adjusted Poly-3 test | | 0.005^**^
Sire-adjusted correlation | −0.05
Sire-adjusted Poly-3 rate | 0.0% | 12.0%
Sire-adjusted Poly-3 test | | 0.016^*^
All Organs: Osteosarcoma
Overall rate | 0/27 (0.0%) | 1/26 (3.8%)
Adjusted rate | 0/27.0 (0.0%) | 1/22.8 (4.4%)
Terminal rate | 0/27 (0.0%) | 1/21 (4.8%)
First incidence (days) | — | 213 (T)
Poly-3 test | | 0.467
Litter-adjusted correlation | 0.03
Litter-adjusted Poly-3 rate | 0.0% | 4.5%
Litter-adjusted Poly-3 test | | 0.155
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 0.0% | 4.4%
Sire-adjusted Poly-3 test | | 0.148
All Organs: Benign Neoplasms
Overall rate | 1/27 (3.7%) | 1/26 (3.8%)
Adjusted rate | 1/27.0 (3.7%) | 1/22.8 (4.4%)
Terminal rate | 1/27 (3.7%) | 1/21 (4.8%)
First incidence (days) | 217 (T) | 213 (T)
Poly-3 test | | 0.722
Litter-adjusted correlation | 0.04
Litter-adjusted Poly-3 rate | 3.8% | 4.5%
Litter-adjusted Poly-3 test | | 0.451
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 3.6% | 4.4%
Sire-adjusted Poly-3 test | | 0.446
All Organs: Malignant Neoplasms
Overall rate | 0/27 (0.0%) | 6/26 (23.1%)
Adjusted rate | 0/27.0 (0.0%) | 6/25.2 (23.8%)
Terminal rate | 0/27 (0.0%) | 2/21 (9.5%)
First incidence (days) | — | -84
Poly-3 test | | 0.008^**^
Litter-adjusted correlation | −0.15
Litter-adjusted Poly-3 rate | 0.0% | 23.5%
Litter-adjusted Poly-3 test | | <0.001^***^
Sire-adjusted correlation | −0.04
Sire-adjusted Poly-3 rate | 0.0% | 23.3%
Sire-adjusted Poly-3 test | | 0.001^**^
All Organs: Benign or Malignant Neoplasms
Overall rate | 1/27 (3.7%) | 7/26 (26.9%)
Adjusted rate | 1/27.0 (3.7%) | 7/25.2 (27.8%)
Terminal rate | 1/27 (3.7%) | 3/21 (14.3%)
First incidence (days) | 217 (T) | 84
Poly-3 test | | 0.017^*^
Litter-adjusted correlation | −0.10
Litter-adjusted Poly-3 rate | 3.6% | 27.3%
Litter-adjusted Poly-3 test | | 0.003^**^
Sire-adjusted correlation | −0.12
Sire-adjusted Poly-3 rate | 3.4% | 25.9%
Sire-adjusted Poly-3 test | | 0.002^**^

(T)Terminal kill

* Significantly different (P≤0.05) from the 0/0/0 mg/kg group by the Poly-3 test

** P≤0.01

*** P≤0.001

a Number of neoplasm-bearing animals/number of animals examined microscopically

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg group and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

e Not applicable; no neoplasms in animal group

TABLE G7 Litter-adjusted Statistical Analysis of Primary Neoplasms in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT

| 0/0/0 mg/kg | 80/40/80 mg/kg | 160/80/160 mg/kg | 240/120/240 mg/kg
Liver: Hepatocellular Adenoma
Overall rate^a^ | 3/26 (11.5%) | 2/27 (7.4%) | 6/27 (22.2%) | 9/27 (33.3%)
Adjusted rate^b^ | 3/24.4 (12.3%) | 2/22.8 (8.8%) | 6/27.0 (22.2%) | 9/24.7 (36.5%)
Terminal rate^c^ | 3/24 (12.5%) | 2/21 (9.5%) | 6/27 (22.2%) | 7/22 (31.8%)
First incidence (days) | 321 (T) | 319 (T) | 320 (T) | 228
Poly-3 test^d^ | 0.013^*^ | 0.531N | 0.288 | 0.048^*^
Poly-5 test | 0.013^*^ | 0.536N | 0.293 | 0.047^*^
Litter-adjusted correlation | −0.23
Litter-adjusted Poly-3 rate | 13.8% | 7.2% | 22.8% | 35.9%
Litter-adjusted Poly-3 test | 0.010^*^ | 0.214N | 0.168 | 0.027^*^
Sire-adjusted correlation | 0.04
Sire-adjusted Poly-3 rate | 12.4% | 7.9% | 21.2% | 36.1%
Sire-adjusted Poly-3 test | 0.009^**^ | 0.305N | 0.119 | 0.022^*^
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 3/26 (11.5%) | 3/27 (11.1%) | 6/27 (22.2%) | 9/27 (33.3%)
Adjusted rate | 3/24.4 (12.3%) | 3/22.8 (13.2%) | 6/27.0 (22.2%) | 9/24.7 (36.5%)
Terminal rate | 3/24 (12.5%) | 3/21 (14.3%) | 6/27 (22.2%) | 7/22 (31.8%)
First incidence (days) | 321 (T) | 319 (T) | 320 (T) | 228
Poly-3 test | 0.019^*^ | 0.634 | 0.288 | 0.048^*^
Poly-5 test | 0.019^*^ | 0.629 | 0.293 | 0.047^*^
Litter-adjusted correlation | −0.26
Litter-adjusted Poly-3 rate | 14.0% | 12.0% | 22.9% | 35.8%
Litter-adjusted Poly-3 test | 0.016^*^ | 0.417N | 0.174 | 0.029^*^
Sire-adjusted correlation | 0.10
Sire-adjusted Poly-3 rate | 12.4% | 10.9% | 19.5% | 35.7%
Sire-adjusted Poly-3 test | 0.018^*^ | 0.421N | 0.167 | 0.024^*^
All Organs: Malignant Lymphoma
Overall rate | 1/27 (3.7%) | 2/27 (7.4%) | 1/27 (3.7%) | 1/27 (3.7%)
Adjusted rate | 1/25.4 (3.9%) | 2/23.5 (8.5%) | 1/27.0 (3.7%) | 1/24.7 (4.1%)
Terminal rate | 0/24 (0.0%) | 1/21 (4.8%) | 1/27 (3.7%) | 0/22 (0.0%)
First incidence (days) | 159 | 217 | 321 (T) | 94
Poly-3 test | 0.502N | 0.473 | 0.746N | 0.754
Litter-adjusted correlation | 0.00
Litter-adjusted Poly-3 rate | 3.9% | 8.5% | 3.7% | 4.1%
Litter-adjusted Poly-3 test | 0.402N | 0.258 | 0.482N | 0.492
Sire-adjusted correlation | 0.09
Sire-adjusted Poly-3 rate | 3.5% | 9.0% | 3.5% | 3.8%
Sire-adjusted Poly-3 test | 0.388N | 0.221 | 0.494N | 0.472
All Organs: Osteosarcoma
Overall rate | 2/27 (7.4%) | 0/27 (0.0%) | 0/27 (0.0%) | 0/27 (0.0%)
Adjusted rate | 2/24.5 (8.2%) | 0/22.8 (0.0%) | 0/27.0 (0.0%) | 0/23.7 (0.0%)
Terminal rate | 2/24 (8.3%) | 0/21 (0.0%) | 0/27 (0.0%) | 0/22 (0.0%)
First incidence (days) | 319 (T) | —^e^ | — | —
Poly-3 test | 0.050N^*^ | 0.251N | 0.214N | 0.242N
Litter-adjusted correlation | 0.01
Litter-adjusted Poly-3 rate | 8.2% | 0.0% | 0.0% | 0.0%
Litter-adjusted Poly-3 test | 0.072N | 0.072N | 0.072N | 0.072N
Sire-adjusted correlation | 0.00
Sire-adjusted Poly-3 rate | 8.2% | 0.0% | 0.0% | 0.0%
Sire-adjusted Poly-3 test | 0.067N | 0.067N | 0.067N | 0.067N
All Organs: Benign Neoplasms
Overall rate | 4/27 (14.8%) | 2/27 (7.4%) | 6/27 (22.2%) | 9/27 (33.3%)
Adjusted rate | 4/24.5 (16.3%) | 2/22.8 (8.8%) | 6/27.0 (22.2%) | 9/24.7 (36.5%)
Terminal rate | 4/24 (16.7%) | 2/21 (9.5%) | 6/27 (22.2%) | 7/22 (31.8%)
First incidence (days) | 321 (T) | 319 (T) | 320 (T) | 228
Poly-3 test | 0.031^*^ | 0.367N | 0.430 | 0.099
Litter-adjusted correlation | 0.00
Litter-adjusted Poly-3 rate | 16.4% | 8.8% | 22.2% | 36.5%
Litter-adjusted Poly-3 test | 0.031^*^ | 0.236N | 0.295 | 0.059
Sire-adjusted correlation | −0.07
Sire-adjusted Poly-3 rate | 16.4% | 7.4% | 20.7% | 35.2%
Sire-adjusted Poly-3 test | 0.046^*^ | 0.202N | 0.328 | 0.087
All Organs: Malignant Neoplasms
Overall rate | 4/27 (14.8%) | 6/27 (22.2%) | 1/27 (3.7%) | 3/27 (11.1%)
Adjusted rate | 4/25.4 (15.8%) | 6/24.0 (25.0%) | 1/27.0 (3.7%) | 3/24.7 (12.2%)
Terminal rate | 3/24 (12.5%) | 3/21 (14.3%) | 1/27 (3.7%) | 2/22 (9.1%)
First incidence (days) | 159 | 217 | 321 (T) | 94
Poly-3 test | 0.176N | 0.328 | 0.155N | 0.516N
Litter-adjusted correlation | 0.06
Litter-adjusted Poly-3 rate | 16.0% | 25.0% | 3.7% | 12.3%
Litter-adjusted Poly-3 test | 0.153N | 0.226 | 0.068N | 0.356N
Sire-adjusted correlation | 0.01
Sire-adjusted Poly-3 rate | 15.7% | 25.1% | 3.6% | 12.1%
Sire-adjusted Poly-3 test | 0.140N | 0.223 | 0.031N^*^ | 0.361N
All Organs: Benign or Malignant Neoplasms
Overall rate | 8/27 (29.6%) | 7/27 (25.9%) | 7/27 (25.9%) | 12/27 (44.4%)
Adjusted rate | 8/25.4 (31.5%) | 7/24.0 (29.1%) | 7/27.0 (25.9%) | 12/25.7 (46.8%)
Terminal rate | 7/24 (29.2%) | 4/21 (19.0%) | 7/27 (25.9%) | 9/22 (40.9%)
First incidence (days) | 159 | 217 | 320 (T) | 94
Poly-3 test | 0.185 | 0.550N | 0.444N | 0.205
Litter-adjusted correlation | 0.10
Litter-adjusted Poly-3 rate | 31.1% | 29.6% | 25.6% | 47.1%
Litter-adjusted Poly-3 test | 0.155 | 0.457N | 0.334N | 0.123
Sire-adjusted correlation | 0.02
Sire-adjusted Poly-3 rate | 31.5% | 28.3% | 25.1% | 46.0%
Sire-adjusted Poly-3 test | 0.200 | 0.407N | 0.285N | 0.188

(T)Terminal kill

* Significantly different (P≤0.05) by the Poly-3 test

** P≤0.01

a Number of neoplasm-bearing animals/number of animals examined microscopically

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the 0/0/0 mg/kg group incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg group and that dosed group. The Poly-k test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or lower incidence in a dose group is indicated by N.

e Not applicable; no neoplasms in animal group

TABLE G8 Litter-adjusted Statistical Analysis of Primary Neoplasms in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Stop-Study of AZT

| 0/0 mg/kg | 240/40 mg/kg
Liver: Hepatocellular Adenoma
Overall rate^a^ | 3/24 (12.5%) | 5/25 (20.0%)
Adjusted rate^b^ | 3/23.4 (12.8%) | 5/23.5 (21.3%)
Terminal rate^c^ | 3/23 (13.0%) | 5/22 (22.7%)
First incidence (days) | 317 (T) | 317 (T)
Poly-3 test^d^ | | 0.352
Poly-5 test | | 0.350
Litter-adjusted correlation | −0.17
Litter-adjusted Poly-3 rate | 12.8% | 20.8%
Litter-adjusted Poly-3 test | | 0.212
Sire-adjusted correlation | −0.10
Sire-adjusted Poly-3 rate | 15.2% | 22.3%
Sire-adjusted Poly-3 test | | 0.218
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 3/24 (12.5%) | 7/25 (28.0%)
Adjusted rate | 3/23.4 (12.8%) | 7/23.5 (29.8%)
Terminal rate | 3/23 (13.0%) | 7/22 (31.8%)
First incidence (days) | 317 (T) | 317 (T)
Poly-3 test | | 0.143
Poly-5 test | | 0.141
Litter-adjusted correlation | −0.02
Litter-adjusted Poly-3 rate | 12.8% | 29.8%
Litter-adjusted Poly-3 test | | 0.076
Sire-adjusted correlation | −0.07
Sire-adjusted Poly-3 rate | 12.6% | 29.1%
Sire-adjusted Poly-3 test | | 0.077
All Organs: Malignant Lymphoma
Overall rate | 0/24 (0.0%) | 2/25 (8.0%)
Adjusted rate | 0/23.4 (0.0%) | 2/23.7 (8.5%)
Terminal rate | 0/23 (0.0%) | 1/22 (4.5%)
First incidence (days) | —^e^ | 300
Poly-3 test | | 0.237
Litter-adjusted correlation | 0.77
Litter-adjusted Poly-3 rate | 0.0% | 7.9%
Litter-adjusted Poly-3 test | | 0.148
Sire-adjusted correlation | 0.13
Sire-adjusted Poly-3 rate | | —f
Sire-adjusted Poly-3 test | | —
All Organs: Benign Neoplasms
Overall rate | 6/24 (25.0%) | 5/25 (20.0%)
Adjusted rate | 6/23.4 (25.6%) | 5/23.5 (21.3%)
Terminal rate | 6/23 (26.1%) | 5/22 (22.7%)
First incidence (days) | 317 (T) | 317 (T)
Poly-3 test | | 0.498N
Litter-adjusted correlation | −0.29
Litter-adjusted Poly-3 rate | 26.0% | 20.4%
Litter-adjusted Poly-3 test | | 0.298N
Sire-adjusted correlation | −0.08
Sire-adjusted Poly-3 rate | 25.8% | 21.1%
Sire-adjusted Poly-3 test | | 0.317N
All Organs: Malignant Neoplasms
Overall rate | 1/24 (4.2%) | 5/25 (20.0%)
Adjusted rate | 1/24.0 (4.2%) | 5/24.0 (20.8%)
Terminal rate | 0/23 (0.0%) | 3/22 (13.6%)
First incidence (days) | 240 | 281
Poly-3 test | | 0.093
Litter-adjusted correlation | 0.40
Litter-adjusted Poly-3 rate | 4.0% | 20.2%
Litter-adjusted Poly-3 test | | 0.076
Sire-adjusted correlation | −0.04
Sire-adjusted Poly-3 rate | 4.9% | 21.1%
Sire-adjusted Poly-3 test | | 0.104
All Organs: Benign and Malignant Neoplasms
Overall rate | 7/24 (29.2%) | 10/25 (40.0%)
Adjusted rate | 7/24.0 (29.2%) | 10/24.0 (41.7%)
Terminal rate | 6/23 (26.1%) | 8/22 (36.4%)
First incidence (days) | 240 | 281
Poly-3 test | | 0.276
Litter-adjusted correlation | 0.21
Litter-adjusted Poly-3 rate | 28.7% | 41.8%
Litter-adjusted Poly-3 test | | 0.189
Sire-adjusted correlation | −0.02
Sire-adjusted Poly-3 rate | 29.5% | 41.4%
Sire-adjusted Poly-3 test | | 0.233

(T)Terminal kill

a Number of neoplasm-bearing animals/number of animals examined microscopically

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0 mg/kg group and that dosed group. The Poly-k test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in the dosed group is indicated by N.

e Not applicable; no neoplasms in animal group

f Sire-adjusted analysis produced invalid results

TABLE G9 Litter-adjusted Statistical Analysis of Primary Neoplasms in Female Heterozygous F1 p53^+/−^ Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT

| 0/0/0 mg/kg | 240/120/240 mg/kg
All Organs: Malignant Lymphoma
Overall rate^a^ | 1/27 (3.7%) | 1/26 (3.8%)
Adjusted rate^b^ | 1/25.2 (4.0%) | 1/26.0 (3.8%)
Terminal rate^c^ | 0/24 (0.0%) | 1/26 (3.8%)
First incidence (days) | 192 | 213 (T)
Poly-3 test^d^ | | 0.753N
Litter-adjusted correlation | 0.04
Litter-adjusted Poly-3 rate | 4.0% | 3.9%
Litter-adjusted Poly-3 test | | 0.490N
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 3.9% | 3.8%
Sire-adjusted Poly-3 test | | 0.492N
All Organs: Benign Neoplasms
Overall rate | 2/27 (7.4%) | 0/26 (0.0%)
Adjusted rate | 2/24.9 (8.0%) | 0/26.0 (0.0%)
Terminal rate | 2/24 (8.3%) | 0/26 (0.0%)
First incidence (days) | 211 (T) | —^e^
Poly-3 test | | 0.225N
Litter-adjusted correlation | −0.11
Litter-adjusted Poly-3 rate | 8.2% | 0.0%
Litter-adjusted Poly-3 test | | 0.063N
Sire-adjusted correlation | −0.02
Sire-adjusted Poly-3 rate | 8.0% | 0.0%
Sire-adjusted Poly-3 test | | 0.060N
All Organs: Malignant Neoplasms
Overall rate | 2/27 (7.4%) | 3/26 (11.5%)
Adjusted rate | 2/25.2 (7.9%) | 3/26.0 (11.5%)
Terminal rate | 1/24 (4.2%) | 3/26 (11.5%)
First incidence (days) | 192 | 213 (T)
Poly-3 test | | 0.515
Litter-adjusted correlation | −0.21
Litter-adjusted Poly-3 rate | 8.2% | 11.8%
Litter-adjusted Poly-3 test | | 0.327
Sire-adjusted correlation | −0.12
Sire-adjusted Poly-3 rate | 7.3% | 12.1%
Sire-adjusted Poly-3 test | | 0.279
All Organs: Benign and Malignant Neoplasms
Overall rate | 4/27 (14.8%) | 3/26 (11.5%)
Adjusted rate | 4/25.2 (15.9%) | 3/26.0 (11.5%)
Terminal rate | 3/24 (12.5%) | 3/26 (11.5%)
First incidence (days) | 192 | 213 (T)
Poly-3 test | | 0.482N
Litter-adjusted correlation | −0.34
Litter-adjusted Poly-3 rate | 15.9% | 12.1%
Litter-adjusted Poly-3 test | | 0.344N
Sire-adjusted correlation | −0.12
Sire-adjusted Poly-3 rate | 14.5% | 11.1%
Sire-adjusted Poly-3 test | | 0.353N

(T)Terminal kill

a Number of neoplasm-bearing animals/number of animals examined microscopically

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg group and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in the dosed group is indicated by N.

e Not applicable; no neoplasms in animal group

TABLE G10 Litter-adjusted Statistical Analysis of Primary Neoplasms in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT

| 0/0/0 mg/kg | 80/40/80 mg/kg | 160/80/160 mg/kg | 240/120/240 mg/kg
All Organs: Histiocytic Sarcoma
Overall rate^a^ | 0/26 (0.0%) | 1/27 (3.7%) | 0/27 (0.0%) | 1/27 (3.7%)
Adjusted rate^b^ | 0/24.5 (0.0%) | 1/25.5 (3.9%) | 0/25.1 (0.0%) | 1/24.4 (4.1%)
Terminal rate^c^ | 0/23 (0.0%) | 0/23 (0.0%) | 0/24 (0.0%) | 0/21 (0.0%)
First incidence (days) | —^e^ | 212 | —^f^ | 278
Poly-3 test^d^ | 0.378 | 0.509 | — | 0.500
Litter-adjusted correlation | −0.12
Litter-adjusted Poly-3 rate | 0.0% | 5.0% | 0.0% | 4.6%
Litter-adjusted Poly-3 test | 0.260 | 0.116 | — | 0.141
Sire-adjusted correlation | −0.02
Sire-adjusted Poly-3 rate | 0.0% | 4.2% | 0.1% | 4.1%
Sire-adjusted Poly-3 test | 0.254 | 0.123 | — | 0.144
All Organs: Malignant Lymphoma
Overall rate | 0/26 (0.0%) | 0/27 (0.0%) | 1/27 (3.7%) | 3/27 (11.1%)
Adjusted rate | 0/24.5 (0.0%) | 0/24.8 (0.0%) | 1/25.1 (4.0%) | 3/24.7 (12.2%)
Terminal rate | 0/23 (0.0%) | 0/23 (0.0%) | 1/24 (4.2%) | 2/21 (9.5%)
First incidence (days) | —^e^ | — | 322 (T) | 241
Poly-3 test | 0.020^*^ | — | 0.505 | 0.115
Litter-adjusted correlation | −0.01
Litter-adjusted Poly-3 rate | 0.0% | 0.0% | 4.0% | 12.2%
Litter-adjusted Poly-3 test | 0.023^*^ | — | 0.148 | 0.033^*^
Sire-adjusted correlation | −0.03
Sire-adjusted Poly-3 rate | 0.0% | 0.0% | 4.1% | 12.1%
Sire-adjusted Poly-3 test | 0.018^*^ | — | 0.137 | 0.032^*^
All Organs: Mesothelioma
Overall rate | 1/26 (3.8%) | 0/27 (0.0%) | 0/27 (0.0%) | 0/27 (0.0%)
Adjusted rate | 1/24.7 (4.0%) | 0/24.8 (0.0%) | 0/25.1 (0.0%) | 0/24.1 (0.0%)
Terminal rate | 0/23 (0.0%) | 0/23 (0.0%) | 0/24 (0.0%) | 0/21 (0.0%)
First incidence (days) | 291 | — | — | —
Poly-3 test | 0.186N | 0.499N | 0.497N | 0.506N
Litter-adjusted correlation | 0.00
Litter-adjusted Poly-3 rate | 4.1% | 0.0% | 0.0% | 0.0%
Litter-adjusted Poly-3 test | 0.155N | 0.155N | 0.155N | 0.155N
Sire-adjusted correlation | 0.00
Sire-adjusted Poly-3 rate | 4.1% | 0.0% | 0.0% | 0.0%
Sire-adjusted Poly-3 test | 0.156N | 0.156N | 0.156N | 0.156N
All Organs: Osteosarcoma
Overall rate | 1/26 (3.8%) | 2/27 (7.4%) | 3/27 (11.1%) | 1/27 (3.7%)
Adjusted rate | 1/24.9 (4.0%) | 2/25.2 (7.9%) | 3/25.1 (12.0%) | 1/24.4 (4.1%)
Terminal rate | 0/23 (0.0%) | 1/23 (4.3%) | 3/24 (12.5%) | 0/21 (0.0%)
First incidence (days) | 269 | 282 | 320 (T) | 287
Poly-3 test | 0.486 | 0.504 | 0.305 | 0.756
Litter-adjusted correlation | 0.32
Litter-adjusted Poly-3 rate | 3.2% | 6.5% | 11.6% | 4.3%
Litter-adjusted Poly-3 test | 0.323 | 0.317 | 0.102 | 0.423
Sire-adjusted correlation | 0.07
Sire-adjusted Poly-3 rate | 4.0% | 7.4% | 11.4% | 4.0%
Sire-adjusted Poly-3 test | 0.406 | 0.339 | 0.120 | 0.498N
All Organs: Benign Neoplasms
Overall rate | 1/26 (3.8%) | 4/27 (14.8%) | 2/27 (7.4%) | 1/27 (3.7%)
Adjusted rate | 1/24.5 (4.1%) | 4/24.8 (16.1%) | 2/25.1 (8.0%) | 1/24.1 (4.2%)
Terminal rate | 1/23 (4.3%) | 4/23 (17.4%) | 2/24 (8.3%) | 1/21 (4.8%)
First incidence (days) | 320 (T) | 319 (T) | 322 (T) | 321 (T)
Poly-3 test | 0.452N | 0.177 | 0.509 | 0.757
Litter-adjusted correlation | −0.06
Litter-adjusted Poly-3 rate | 4.0% | 15.6% | 7.8% | 4.4%
Litter-adjusted Poly-3 test | 0.361N | 0.074 | 0.284 | 0.476
Sire-adjusted correlation | −0.05
Sire-adjusted Poly-3 rate | 4.2% | 15.1% | 6.9% | 4.2%
Sire-adjusted Poly-3 test | 0.339N | 0.079 | 0.342 | 0.496
All Organs: Malignant Neopl asms
Overall rate | 3/26 (11.5%) | 3/27 (11.1%) | 6/27 (22.2%) | 7/27 (25.9%)
Adjusted rate | 3/26.0 (11.5%) | 3/25.9 (11.6%) | 6/25.3 (23.7%) | 7/25.6 (27.3%)
Terminal rate | 0/23 (0.0%) | 1/23 (4.3%) | 5/24 (20.8%) | 3/21 (14.3%)
First incidence (days) | 184 | 212 | 298 | 241
Poly-3 test | 0.053 | 0.663 | 0.220 | 0.139
Litter-adjusted correlation | 0.02
Litter-adjusted Poly-3 rate | 11.5% | 11.4% | 23.8% | 27.3%
Litter-adjusted Poly-3 test | 0.036^*^ | 0.494N | 0.107 | 0.066
Sire-adjusted correlation | 0.09
Sire-adjusted Poly-3 rate | 12.5% | 10.4% | 21.3% | 28.3%
Sire-adjusted Poly-3 test | 0.028^*^ | 0.410N | 0.127 | 0.053
All Organs: Benign or Malignant Neoplasms
Overall rate | 4/26 (15.4%) | 7/27 (25.9%) | 8/27 (29.6%) | 8/27 (29.6%)
Adjusted rate | 4/26.0 (15.4%) | 7/25.9 (27.0%) | 8/25.3 (31.6%) | 8/25.6 (31.2%)
Terminal rate | 1/23 (4.3%) | 5/23 (21.7%) | 7/24 (29.2%) | 4/21 (19.0%)
First incidence (days) | 184 | 212 | 298 | 241
Poly-3 test | 0.105 | 0.248 | 0.149 | 0.154
Litter-adjusted correlation | −0.10
Litter-adjusted Poly-3 rate | 15.4% | 27.4% | 30.9% | 31.6%
Litter-adjusted Poly-3 test | 0.067 | 0.123 | 0.099 | 0.067
Sire-adjusted correlation | 0.06
Sire-adjusted Poly-3 rate | 15.8% | 26.5% | 30.9% | 31.8%
Sire-adjusted Poly-3 test | 0.080 | 0.163 | 0.094 | 0.074

(T)Terminal kill

* Significantly different (P≤0.05) from by the Poly-3 test

a Number of neoplasm-bearing animals/number of animals examined microscopically

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the 0/0/0 mg/kg group incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg group and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

e Not applicable; no neoplasms in animal group

f Value of statistic cannot be computed.

TABLE G11 Litter-adjusted Statistical Analysis of Primary Neoplasms in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Stop-Study of AZT

| 0/0 mg/kg | 240/40 mg/kg
All Organs: Granulocytic Leukemia
Overall rate^a^ | 0/26 (0.0%) | 1/26 (3.8%)
Adjusted rate^b^ | 0/25.5 (0.0%) | 1/24.7 (4.1%)
Terminal rate^c^ | 0/25 (0.0%) | 1/23 (4.3%)
First incidence (days) | —^e^ | 320 (T)
Poly-3 test^d^ | | 0.493
Litter-adjusted correlation | 0.02
Litter-adjusted Poly-3 rate | 0.0% | 4.2%
Litter-adjusted Poly-3 test | | 0.158
Sire-adjusted correlation | 0.01
Sire-adjusted Poly-3 rate | 0.0% | 4.2%
Sire-adjusted Poly-3 test | | 0.160
All Organs: Benign Neoplasms
Overall rate | 2/26 (7.7%) | 1/26 (3.8%)
Adjusted rate | 2/25.5 (7.8%) | 1/24.7 (4.1%)
Terminal rate | 2/25 (8.0%) | 1/23 (4.3%)
First incidence (days) | 320 (T) | 318 (T)
Poly-3 test | | 0.512N
Litter-adjusted correlation | −0.11
Litter-adjusted Poly-3 rate | 7.7% | 4.6%
Litter-adjusted Poly-3 test | | 0.314N
Sire-adjusted correlation | −0.08
Sire-adjusted Poly-3 rate | 7.7% | 5.5%
Sire-adjusted Poly-3 test | | 0.368N
All Organs: Malignant Neoplasms
Overall rate | 2/26 (7.7%) | 3/26 (11.5%)
Adjusted rate | 2/26.0 (7.7%) | 3/25.1 (11.9%)
Terminal rate | 1/25 (4.0%) | 2/23 (8.7%)
First incidence (days) | 259 | 260
Poly-3 test | | 0.484
Litter-adjusted correlation | −0.02
Litter-adjusted Poly-3 rate | 7.7% | 11.8%
Litter-adjusted Poly-3 test | | 0.309
Sire-adjusted correlation | 0.03
Sire-adjusted Poly-3 rate | 8.4% | 12.2%
Sire-adjusted Poly-3 test | | 0.319
All Organs: Benign and Malignant Neoplasms
Overall rate | 4/26 (15.4%) | 4/26 (15.4%)
Adjusted rate | 4/26.0 (15.4%) | 4/25.1 (15.9%)
Terminal rate | 3/25 (12.0%) | 3/23 (13.0%)
First incidence (days) | 259 | 260
Poly-3 test | | 0.628
Litter-adjusted correlation | 0.17
Litter-adjusted Poly-3 rate | 15.5% | 16.7%
Litter-adjusted Poly-3 test | | 0.459
Sire-adjusted correlation | 0.01
Sire-adjusted Poly-3 rate | 15.8% | 15.9%
Sire-adjusted Poly-3 test | | 0.495

(T)Terminal kill

a Number of neoplasm-bearing animals/number of animals examined microscopically

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0 mg/kg group and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in the dosed group is indicated by N.

e Not applicable; no neoplasms in animal group

TABLE G12 Litter-adjusted Statistical Analysis of Selected Nonneoplastic Lesions in Male Heterozygous F1 p53^+/−^ Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT

| 0/0/0 mg/kg | 240/120/240 mg/kg
Kidney: Cellular Infiltration
Overall rate^a^ | 7/27 (25.9%) | 2/26 (7.7%)
Adjusted rate^b^ | 7/27.0 (25.9%) | 2/22.8 (8.8%)
Terminal rate^c^ | 7/27 (25.9%) | 2/21 (9.5%)
First incidence (days) | 212 (T) | 213 (T)
Average severity | 1.0 | 1.0
Poly-3 test^d^ | | 0.115N
Litter-adjusted correlation | 0.34
Litter-adjusted Poly-3 rate | 25.5% | 9.6%
Litter-adjusted Poly-3 test | | 0.076N
Sire-adjusted correlation | −0.17
Sire-adjusted Poly-3 rate | 30.0% | 3.7%
Sire-adjusted Poly-3 test | | 0.003N^**^
SW Test^e^ | | 0.040N^*^
Lymph Node (Mesenteric): Hyperplasia
Overall rate | 19/27 (70.4%) | 16/25 (64.0%)
Adjusted rate | 19/27.0 (70.4%) | 16/23.5 (68.1%)
Terminal rate | 19/27 (70.4%) | 15/21 (71.4%)
First incidence (days) | 212 (T) | 125
Average severity | 1.9 | 1.4
Poly-3 test | | 0.551N
Litter-adjusted correlation | 0.04
Litter-adjusted Poly-3 rate | 70.2% | 68.2%
Litter-adjusted Poly-3 test | | 0.439N
Sire-adjusted correlation | 0.02
Sire-adjusted Poly-3 rate | 70.2% | 68.3%
Sire-adjusted Poly-3 test | | 0.431N
SW Test | | 0.045N^*^
Salivary Gland: Cellular Infiltration
Overall rate | 5/27 (18.5%) | 0/26 (0.0%)
Adjusted rate | 5/27.0 (18.5%) | 0/22.8 (0.0%)
Terminal rate | 5/27 (18.5%) | 0/21 (0.0%)
First incidence (days) | 212 (T) | —^f^
Average severity | 1.0 | ^f^
Poly-3 test | | 0.042N^*^
Litter-adjusted correlation | −0.12
Litter-adjusted Poly-3 rate | 18.6% | 0.0%
Litter-adjusted Poly-3 test | | 0.004N^**^
Sire-adjusted correlation | −0.05
Sire-adjusted Poly-3 rate | 18.4% | 0.0%
Sire-adjusted Poly-3 test | | 0.003N^**^
SW Test | | 0.011N^*^

(T)Terminal kill

* Significantly different (P≤0.05) by the Poly-3 test or the SW test.

** P≤0.01

a Number of lesion-bearing animals/number of animals examined microscopically

b Poly-3 estimated lesion incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg group and that dosed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal kill. A lower incidence in the dosed group is indicated by N.

e Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg group and that dosed group by William’s modified Shirley’s test. A lower incidence in the dosed group is indicated by N.

f Not applicable; no lesions in animal group

TABLE G13 Litter-adjusted Statistical Analysis of Selected Nonneoplastic Lesions in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT

| 0/0/0 mg/kg | 80/40/80 mg/kg | 160/80/160 mg/kg | 240/120/240 mg/kg
Brain (Cerebrum): Mineralization
Overall rate^a^ | 4/27 (14.8%) | 1/27 (3.7%) | 2/27 (7.4%) | 0/27 (0.0%)
Adjusted rate^b^ | 4/24.5 (16.3%) | 1/22.8 (4.4%) | 2/27.0 (7.4%) | 0/23.7 (0.0%)
Terminal rate^c^ | 4/24 (16.7%) | 1/21 (4.8%) | 2/27 (7.4%) | 0/22 (0.0%)
First incidence (days) | 320 (T) | 324 (T) | 322 (T) | —^f^
Average severity | 1.0 | 1.0 | 1.0 | —^f^
Poly-3 test^d^ | 0.037N^*^ | 0.195N | 0.289N | 0.058N
Litter-adjusted correlation | 0.00
Litter-adjusted Poly-3 rate | 16.3% | 4.4% | 7.4% | 0.0%
Litter-adjusted Poly-3 test | 0.027N^*^ | 0.085N | 0.164N | 0.016N^*^
Sire-adjusted correlation | 0.02
Sire-adjusted Poly-3 rate | 16.3% | 4.5% | 7.5% | 0.0%
Sire-adjusted Poly-3 test | 0.045N^*^ | 0.105N | 0.192N | 0.029N^*^
JT/SW Test^e^ | 0.028N^*^ | 0.081N | 0.136N | 0.016N^*^
Large Intestine (Cecum): Hyperplasia
Overall rate | 0/26 (0.0%) | 2/26 (7.7%) | 2/27 (7.4%) | 3/25 (12.0%)
Adjusted rate | 0/24.4 (0.0%) | 2/22.8 (8.8%) | 2/27.0 (7.4%) | 3/23.0 (13.0%)
Terminal rate | 0/24 (0.0%) | 2/21 (9.5%) | 2/27 (7.4%) | 3/22 (13.6%)
First incidence (days) | – | 319 (T) | 321 (T) | 321 (T)
Average severity | – | 2.5 | 2.0 | 2.0
Poly-3 test | 0.080 | 0.220 | 0.259 | 0.103
Litter-adjusted correlation | −0.08
Litter-adjusted Poly-3 rate | 0.0% | 8.8% | 7.5% | 12.9%
Litter-adjusted Poly-3 test | 0.048^*^ | 0.060 | 0.062 | 0.034^*^
Sire-adjusted correlation | −0.03
Sire-adjusted Poly-3 rate | 0.0% | 8.7% | 7.5% | 13.6%
Sire-adjusted Poly-3 test | 0.029^*^ | 0.062 | 0.062 | 0.019^*^
JT/SW Test | 0.059 | 0.077 | 0.127 | 0.056
Kidney: Cellular Infiltration
Overall rate | 6/26 (23.1%) | 11/27 (40.7%) | 6/27 (22.2%) | 4/26 (15.4%)
Adjusted rate | 6/24.4 (24.6%) | 11/23.5 (46.8%) | 6/27.0 (22.2%) | 4/23.7 (16.9%)
Terminal rate | 6/24 (25.0%) | 10/21 (47.6%) | 6/27 (22.2%) | 4/22 (18.2%)
First incidence (days) | 318 (T) | 217 | 320 (T) | 318 (T)
Average severity | 1.0 | 1.0 | 1.0 | 1.3
Poly-3 test | 0.151N | 0.095 | 0.550N | 0.382N
Litter-adjusted correlation | −0.14
Litter-adjusted Poly-3 rate | 24.3% | 46.7% | 22.6% | 17.1%
Litter-adjusted Poly-3 test | 0.103N | 0.050 | 0.435N | 0.261N
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 24.6% | 47.0% | 22.5% | 17.2%
Sire-adjusted Poly-3 test | 0.130N | 0.034^*^ | 0.422N | 0.275N
JT/SW Test | 0.155N | 0.914N | 0.554N | 0.373N
Liver: Cytoplasmic Vacuolization
Overall rate | 20/26 (76.9%) | 17/27 (63.0%) | 23/27 (85.2%) | 13/27 (48.1%)
Adjusted rate | 20/24.4 (82.1%) | 17/22.8 (74.6%) | 23/27.0 (85.2%) | 13/23.7 (54.9%)
Terminal rate | 20/24 (83.3%) | 17/21 (81.0%) | 23/27 (85.2%) | 13/22 (59.1%)
First incidence (days) | 318 (T) | 317 (T) | 318 (T) | 318 (T)
Average severity | 1.6 | 1.8 | 1.5 | 1.5
Poly-3 test | 0.052N | 0.392N | 0.530 | 0.036N^*^
Litter-adjusted correlation | 0.10
Litter-adjusted Poly-3 rate | 82.0% | 75.0% | 85.3% | 55.3%
Litter-adjusted Poly-3 test | 0.039N^*^ | 0.297N | 0.366 | 0.017N^*^
Sire-adjusted correlation | −0.04
Sire-adjusted Poly-3 rate | 81.5% | 73.5% | 85.5% | 54.8%
Sire-adjusted Poly-3 test | 0.042N^*^ | 0.245N | 0.341 | 0.014N^*^
JT/SW Test | 0.022N^*^ | 0.343N | 0.525N | 0.012N^*^
Preputial Gland: Degeneration
Overall rate | 0/27 (0.0%) | 0/26 (0.0%) | 0/27 (0.0%) | 3/26 (11.5%)
Adjusted rate | 0/24.5 (0.0%) | 0/22.8 (0.0%) | 0/27.0 (0.0%) | 3/24.7 (12.2%)
Terminal rate | 0/24 (0.0%) | 0/21 (0.0%) | 0/27 (0.0%) | 2/22 (9.1%)
First incidence (days) | — | — | — | 94
Average severity | — | — | — | 3.0
Poly-3 test | 0.017^*^ | —^g^ | — | 0.115
Litter-adjusted correlation | 0.01
Litter-adjusted Poly-3 rate | 0.0% | 0.0% | 0.0% | 12.2%
Litter-adjusted Poly-3 test | 0.033^*^ | — | — | 0.033^*^
Sire-adjusted correlation | 0.04
Sire-adjusted Poly-3 rate | — | — | — | —
Sire-adjusted Poly-3 test | — | — | — | —
JT/SW Test | 0.009^**^ | 0.500 | 0.583 | 0.007^**^

(T)Terminal kill

* Significantly different (P≤0.05) by the Poly-3 test or the JT/SW test

** P≤0.01

a Number of lesion-bearing animals/number of animals examined microscopically

b Poly-3 estimated lesion incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the 0/0/0 mg/kg group incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg group and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

e Beneath the 0/0/0 mg/kg group incidence is the P value associated with the Jonckheere/Terpstra monotonic trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg group and that dosed group by William’s modified Shirley’s test. A negative trend or a lower incidence in a dose group is indicated by N.

f Not applicable; no lesions in animal group

g Value of statistic cannot be computed.

TABLE G14 Litter-adjusted Statistical Analysis of Selected Nonneoplastic Lesions in Male Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Stop-Study of AZT

| 0/0 mg/kg | 240/40 mg/kg
Liver: Cytoplasmic Vacuolization
Overall rate^a^ | 23/24 (95.8%) | 18/25 (72.0%)
Adjusted rate^b^ | 23/23.4 (98.2%) | 18/23.5 (76.7%)
Terminal rate^c^ | 23/23 (100.0%) | 18/22 (81.8%)
First incidence (days) | 294 (T) | 317 (T)
Average severity | 1.7 | 1.6
Poly-3 test^d^ | | 0.026N^*^
Litter-adjusted correlation | 0.27
Litter-adjusted Poly-3 rate | 98.6% | 77.4%
Litter-adjusted Poly-3 test | | 0.022N^*^
Sire-adjusted correlation | −0.10
Sire-adjusted Poly-3 rate | 96.3% | 74.4%
Sire-adjusted Poly-3 test | | 0.009N^**^
SW Test^e^ | | 0.043N^*^

(T)Terminal kill

* Significantly different (P≤0.05) by the Poly-3 test or SW test

** P≤0.01

a Number of lesion-bearing animals/number of animals examined microscopically

b Poly-3 estimated lesion incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0 mg/kg group and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in the dosed group is indicated by N.

e Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0 mg/kg group and that dosed group by William’s modified Shirley’s test. A lower incidence in the dosed group is indicated by N.

TABLE G15 Litter-adjusted Statistical Analysis of Selected Nonneoplastic Lesions in Female Heterozygous F1 p53^+/−^ Mice in the 30-Week In Utero/Postnatal Gavage Study of AZT

| 0/0/0 mg/kg
Large Intestine (Cecum): Hyperplasia
Overall rate^a^ | 0/26 (0.0%) | 2/26 (7.7%)
Adjusted rate^b^ | 0/24.7 (0.0%) | 2/26.0 (7.7%)
Terminal rate^c^ | 0/24 (0.0%) | 2/26 (7.7%)
First incidence (days) | —^f^ | 214 (T)
Average severity | —^f^ | 2.0
Poly-3 test^d^ | | 0.247
Litter-adjusted correlation | −0.41
Litter-adjusted Poly-3 rate | 0.0% | 11.2%
Litter-adjusted Poly-3 test | | 0.042^*^
Sire-adjusted correlation | −0.06
Sire-adjusted Poly-3 rate | 0.1% | 7.9%
Sire-adjusted Poly-3 test | | 0.060
SW Test^e^ | | 0.077
Kidney: Cellular Infiltration
Overall rate | 8/26 (30.8%) | 3/26 (11.5%)
Adjusted rate | 8/24.7 (32.4%) | 3/26.0 (11.5%)
Terminal rate | 8/24 (33.3%) | 3/26 (11.5%)
First incidence (days) | 212 (T) | 213 (T)
Average severity | 1.1 | 1.0
Poly-3 test | | 0.070N
Litter-adjusted correlation | 0.12
Litter-adjusted Poly-3 rate | 31.5% | 11.8%
Litter-adjusted Poly-3 test | | 0.042N^*^
Sire-adjusted correlation | −0.04
Sire-adjusted Poly-3 rate | 33.3% | 11.6%
Sire-adjusted Poly-3 test | | 0.004N^**^
SW Test | | 0.043N^*^
Salivary Gland: Cellular Infiltration
Overall rate | 14/26 (53.8%) | 7/26 (26.9%)
Adjusted rate | 14/24.7 (56.7%) | 7/26.0 (26.9%)
Terminal rate | 14/24 (58.3%) | 7/26 (26.9%)
First incidence (days) | 211 (T) | 213 (T)
Average severity | 1.1 | 1.1
Poly-3 test | | 0.028N^*^
Litter-adjusted correlation | −0.29
Litter-adjusted Poly-3 rate | 57.3% | 26.0%
Litter-adjusted Poly-3 test | | 0.006N^**^
Sire-adjusted correlation | −0.10
Sire-adjusted Poly-3 rate | 55.5% | 26.8%
Sire-adjusted Poly-3 test | | 0.016N^*^
SW Test | | 0.031N^*^

(T)Terminal kill

* Significantly different (P≤0.05) by the Poly-3 test or SW test

** P≤0.01

a Number of lesion-bearing animals/number of animals examined microscopically

b Poly-3 estimated lesion incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg group and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in the dosed group is indicated by N.

e Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg group and that dosed group by William’s modified Shirley’s test. A lower incidence in the dosed group is indicated by N.

f Not applicable, no lesions in animal group

TABLE G16 Litter-adjusted Statistical Analysis of Selected Nonneoplastic Lesions in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Study of AZT

| 0/0/0 mg/kg | 80/40/80 mg/kg | 160/80/160 mg/kg | 240/120/240 mg/kg
Adrenal Cortex: Subscapular Hyperplasia
Overall rate^a^ | 25/26 (96.2%) | 25/27 (92.6%) | 27/27 (100.0%) | 24/26 (92.3%)
Adjusted rate^b^ | 25/26.0 (96.2%) | 25/25.7 (97.5%) | 27/27.0 (100.0%) | 24/24.7 (97.2%)
Terminal rate^c^ | 22/23 (95.7%) | 23/23 (100.0%) | 24/24 (100.0%) | 21/21 (100.0%)
First incidence (days) | 184 | 212 | 162 | 274
Average severity | 1.0 | 1.2 | 1.2 | 1.2
Poly-3 test^d^ | 0.432 | 0.710 | 0.492 | 0.727
Litter-adjusted correlation | −0.07
Litter-adjusted Poly-3 rate | 95.9% | 97.2% | 100% | 97.2%
Litter-adjusted Poly-3 test | 0.322 | 0.390 | 0.144 | 0.392
Sire-adjusted correlation | −0.03
Sire-adjusted Poly-3 rate | 96.1% | 97.3% | 100% | 97.2%
Sire-adjusted Poly-3 test | 0.332 | 0.389 | 0.146 | 0.402
JT/SW Test^6^ | 0.108 | 0.153 | 0.030^*^,^f^ | 0.096
Bone Marrow: Myeloid Cell Hyperplasia
Overall rate | 0/26 (0.0%) | 0/26 (0.0%) | 4/26 (15.4%) | 1/26 (3.8%)
Adjusted rate | 0/24.5 (0.0%) | 0/24.8 (0.0%) | 4/25.8 (15.5%) | 1/24.6 (4.1%)
Terminal rate | 0/23 (0.0%) | 0/23 (0.0%) | 3/24 (12.5%) | 0/21 (0.0%)
First incidence (days) | —^g^ | — | 185 | 50
Average severity | —^g^ | — | 2.5 | 2.0
Poly-3 test | 0.103 | —^h^ | 0.061 | 0.501
Litter-adjusted correlation | −0.08
Litter-adjusted Poly-3 rate | 0.0% | 0.0% | 15.6% | 4.0%
Litter-adjusted Poly-3 test | 0.020^*^ | — | 0.008^**^ | 0.154
Sire-adjusted correlation | −0.01
Sire-adjusted Poly-3 rate | 0.0% | 0.0% | 15.6% | 4.1%
Sire-adjusted Poly-3 test | 0.019^*^ | — | 0.013^*^ | 0.139
JT/SW Test | 0.079 | 0.500 | 0.007^**^,^f^ | 0.066
Brain (Cerebrum): Mineralization
Overall rate | 0/26 (0.0%) | 1/27 (3.7%) | 4/27 (14.8%) | 2/27 (7.4%)
Adjusted rate | 0/24.5 (0.0%) | 1/24.8 (4.0%) | 4/25.1 (15.9%) | 2/24.1 (8.3%)
Terminal rate | 0/23 (0.0%) | 1/23 (4.3%) | 4/24 (16.7%) | 2/21 (9.5%)
First incidence (days) | — | 322 (T) | 321 (T) | 321 (T)
Average severity | — | 1.0 | 1.0 | 1.0
Poly-3 test | 0.073 | 0.503 | 0.058 | 0.231
Litter-adjusted correlation | −0.13
Litter-adjusted Poly-3 rate | 0.0% | 3.8% | 16.1% | 8.6%
Litter-adjusted Poly-3 test | 0.020^*^ | 0.151 | 0.007^**^ | 0.064
Sire-adjusted correlation | −0.07
Sire-adjusted Poly-3 rate | 0.0% | 4.6% | 15.6% | 7.9%
Sire-adjusted Poly-3 test | 0.021^*^ | 0.109 | 0.002^**^ | 0.065
JT/SW Test | 0.062 | 0.163 | 0.015^*^,^f^ | 0.064
Kidney: Cellular Infiltration
Overall rate | 9/26 (34.6%) | 6/27 (22.2%) | 5/27 (18.5%) | 4/27 (14.8%)
Adjusted rate | 9/24.5 (36.8%) | 6/24.8 (24.2%) | 5/25.1 (19.9%) | 4/24.5 (16.4%)
Terminal rate | 9/23 (39.1%) | 6/23 (26.1%) | 5/24 (20.8%) | 3/21 (14.3%)
First incidence (days) | 320 (T) | 319 (T) | 320 (T) | 274
Average severity | 1.1 | 1.2 | 1.0 | 1.0
Poly-3 test | 0.056N | 0.258N | 0.158N | 0.095N
Litter-adjusted correlation | −0.04
Litter-adjusted Poly-3 rate | 36.9% | 23.5% | 20.0% | 16.4%
Litter-adjusted Poly-3 test | 0.034N^*^ | 0.129N | 0.084N | 0.033N^*^
Sire-adjusted correlation | 0.06
Sire-adjusted Poly-3 rate | 36.7% | 26.8% | 20.5% | 16.4%
Sire-adjusted Poly-3 test | 0.014N^*^ | 0.175N | 0.085N | 0.026N^*^
JT/SW Test | 0.038N^*^ | 0.171N | 0.098N | 0.048N^*^
Liver: Tension Lipidosis
Overall rate | 3/26 (11.5%) | 5/27 (18.5%) | 7/27 (25.9%) | 4/27 (14.8%)
Adjusted rate | 3/24.5 (12.3%) | 5/25.2 (19.9%) | 7/25.1 (27.9%) | 4/24.1 (16.6%)
Terminal rate | 3/23 (13.0%) | 4/23 (17.4%) | 7/24 (29.2%) | 4/21 (19.0%)
First incidence (days) | 319 (T) | 282 | 320 (T) | 318 (T)
Average severity | 1.0 | 1.6 | 1.1 | 1.0
Poly-3 test | 0.307 | 0.367 | 0.154 | 0.491
Litter-adjusted correlation | −0.17
Litter-adjusted Poly-3 rate | 11.7% | 17.9% | 28.0% | 16.1%
Litter-adjusted Poly-3 test | 0.229 | 0.260 | 0.047^*^ | 0.328
Sire-adjusted correlation | −0.07
Sire-adjusted Poly-3 rate | 11.8% | 21.9% | 27.3% | 16.3%
Sire-adjusted Poly-3 test | 0.294 | 0.149 | 0.070 | 0.335
JT/SW Test | 0.339 | 0.203 | 0.110 | 0.258
Liver: Cytoplasmic Vacuolization
Overall rate | 6/26 (23.1%) | 4/27 (14.8%) | 3/27 (11.1%) | 10/27 (37.0%)
Adjusted rate | 6/24.5 (24.5%) | 4/24.8 (16.1%) | 3/25.3 (11.9%) | 10/24.5 (40.9%)
Terminal rate | 6/23 (26.1%) | 4/23 (17.4%) | 2/24 (8.3%) | 9/21 (42.9%)
First incidence (days) | 320 (T) | 317 (T) | 298 | 274
Average severity | 1.2 | 1.0 | 1.3 | 1.0
Poly-3 test | 0.150 | 0.354N | 0.215N | 0.179
Litter-adjusted correlation | −0.11
Litter-adjusted Poly-3 rate | 24.8% | 15.5% | 11.5% | 40.2%
Litter-adjusted Poly-3 test | 0.147 | 0.184N | 0.092N | 0.119
Sire-adjusted correlation | −0.00
Sire-adjusted Poly-3 rate | 24.5% | 16.0% | 11.8% | 40.9%
Sire-adjusted Poly-3 test | 0.121 | 0.213N | 0.102N | 0.104
JT/SW Test | 0.152 | 0.792 | 0.906 | 0.163
Pancreas: Cellular Infiltration
Overall rate | 0/26 (0.0%) | 0/27 (0.0%) | 1/27 (3.7%) | 3/26 (11.5%)
Adjusted rate | 0/24.5 (0.0%) | 0/24.8 (0.0%) | 1/25.1 (4.0%) | 3/23.4 (12.8%)
Terminal rate | 0/23 (0.0%) | 0/23 (0.0%) | 1/24 (4.2%) | 3/21 (14.3%)
First incidence (days) | — | — | 322 (T) | 321 (T)
Average severity | — | — | 1.0 | 1.0
Poly-3 test | 0.018^*^ | — | 0.505 | 0.106
Litter-adjusted correlation | −0.06
Litter-adjusted Poly-3 rate | 0.0% | 0.0% | 4.0% | 13.0%
Litter-adjusted Poly-3 test | 0.017^*^ | — | 0.148 | 0.025^*^
Sire-adjusted correlation | −0.02
Sire-adjusted Poly-3 rate | 0.0% | 0.0% | 3.9% | 12.9%
Sire-adjusted Poly-3 test | 0.015^*^ | — | 0.154 | 0.025^*^
JT/SW Test | 0.011^*^ | 0.500 | 0.135 | 0.017^*^
Salivary Gland: Cellular Infiltration
Overall rate | 15/26 (57.7%) | 14/27 (51.9%) | 10/26 (38.5%) | 10/27 (37.0%)
Adjusted rate | 15/24.9 (60.2%) | 14/24.9 (56.2%) | 10/24.3 (41.1%) | 10/24.7 (40.4%)
Terminal rate | 14/23 (60.9%) | 13/23 (56.5%) | 10/24 (41.7%) | 8/21 (38.1%)
First incidence (days) | 269 | 312 | 320 (T) | 274
Average severity | 1.2 | 1.1 | 1.3 | 1.0
Poly-3 test | 0.058N | 0.498N | 0.145N | 0.131N
Litter-adjusted correlation | 0.07
Litter-adjusted Poly-3 rate | 59.9% | 56.6% | 41.0% | 40.8%
Litter-adjusted Poly-3 test | 0.052N | 0.410N | 0.084N | 0.089N
Sire-adjusted correlation | 0.01
Sire-adjusted Poly-3 rate | 60.2% | 56.3% | 41.3% | 40.5%
Sire-adjusted Poly-3 test | 0.080N | 0.399N | 0.091N | 0.124N
JT/SW Test | 0.032N^*^ | 0.250N | 0.134N | 0.049N^*^

(T)Terminal kill

* Significantly different (P≤0.05) by the Poly-3 test or the JT/SW test

** P≤0.01

a Number of lesion-bearing animals/number of animals examined microscopically

b Poly-3 estimated lesion incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the 0/0/0 mg/kg group incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg group and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

e Beneath the 0/0/0 mg/kg group incidence is the P value associated with the Jonckheere/Terpstra monotonic trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0/0 mg/kg group and that dosed group by William’s modified Shirley’s test. A negative trend or lower incidence in a dose group is indicated by N.

f The P value from the William’s modified Shirley’s test was significant, but the test violated the monotonic constraint.

g Not applicable, no lesions in animal group

h Value of statistic cannot be computed.

TABLE G17 Litter-adjusted Statistical Analysis of Selected Nonneoplastic Lesions in Female Heterozygous F1 p53^+/−^ Mice in the 45-Week In Utero/Postnatal Gavage Stop-Study of AZT

| 0/0 mg/kg | 240/40 mg/kg
Large Intestine (Cecum): Hyperplasia
Overall rate^a^ | 3/25 (12.0%) | 0/26 (0.0%)
Adjusted rate^b^ | 3/25.0 (12.0%) | 0/24.7 (0.0%)
Terminal rate^c^ | 3/25 (12.0%) | 0/23 (0.0%)
First incidence (days) | 318 (T) | —^f^
Average severity | 2.0 | —^f^
Poly-3 test^d^ | | 0.116N
Litter-adjusted correlation | −0.07
Litter-adjusted Poly-3 rate | 12.0% | 0.0%
Litter-adjusted Poly-3 test | | 0.024N^*^
Sire-adjusted correlation | −0.11
Sire-adjusted Poly-3 rate | 15.1% | 0.4%
Sire-adjusted Poly-3 test | | <0.001N^***^
SW Test^e^ | | 0.036N^*^
Liver: Cytoplasmic Vacuolization
Overall rate | 12/25 (48.0%) | 6/26 (23.1%)
Adjusted rate | 12/25.0 (48.0%) | 6/25.3 (23.7%)
Terminal rate | 12/25 (48.0%) | 5/23 (21.7%)
First incidence (days) | 317 (T) | 231
Average severity | 1.0 | 1.0
Poly-3 test | | 0.064N
Litter-adjusted correlation | 0.04
Litter-adjusted Poly-3 rate | 48.4% | 23.6%
Litter-adjusted Poly-3 test | | 0.031N^*^
Sire-adjusted correlation | 0.21
Sire-adjusted Poly-3 rate | 54.2% | 22.6%
Sire-adjusted Poly-3 test | | 0.002N^**^
SW Test | | 0.033N^*^

(T)Terminal kill

* Significantly different (P≤0.05) by the Poly-3 test or SW test

** P≤0.01

*** P≤0.01

a Number of lesion-bearing animals/number of animals examined microscopically

b Poly-3 estimated lesion incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the dosed group incidence are P values corresponding to pairwise comparisons between the 0/0 mg/kg group and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in the dosed group is indicated by N.

e Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the 0/0 mg/kg group and that dosed group by William’s modified Shirley’s test. A lower incidence in the dosed group is indicated by N.

f Not applicable; no lesions in animal group